# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization of Tris(chloropropyl) Phosphate

An isomeric mixture of tris(chloropropyl) phosphate (TCPP) was obtained from Albemarle (Orangeburg, SC) in two lots (101 and 134). Lot 101 was used in the 3-month rat and mouse studies. Lot 134 and a portion of lot 101 were blended to form lot M072911NP, which was used in the 2-year rat and mouse studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at MRIGlobal (Kansas City, MO) for the study laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of the TCPP studies are on file at the National Institute of Environmental Health Sciences.

The original drum of lot 101 was homogenized by blending the top, middle, and bottom portions of the drum for 10 to 15 minutes. After homogenization, all of lot 101 was transferred into 80 oz amber, glass, narrow-mouth containers, capped using a Teflon^®^-lined lid, and sealed with white sealing tape under inert gas. All bulk containers were stored at room temperature. The purity of lot 101 was reevaluated once before, during, and after the 3-month studies and determined to be statistically similar to a frozen reference sample of the same lot.

Equal portions of lots 101 and 134 were mixed using a dual head peristaltic pump and Food and Drug Administration Norprene^®^ pump tubing combined with manual transfer. Lot 134 was filtered through the filter cartridge before mixing to remove particulate material present due to drum corrosion. The homogenized material (lot M072911NP) was delivered directly into two new, pre-cleaned, 55-gallon stainless-steel drums. Final homogenization was achieved by blending all portions of each 55-gallon drum (top, middle, bottom) with an air-driven stirrer at slow speed to prevent entrapment of air. Homogeneity between the two drums of lot M072911NP was confirmed and reported previously.^35^ The bulk test article was stored with an inert gas headspace at room temperature. The purity of lot M072911NP was reevaluated six times at time points before, during, and after the 2-year studies and was determined to be statistically similar to a frozen reference sample of the same lot at each reanalysis.

Lot 101 was identified as TCPP using proton (^1^H) nuclear magnetic resonance (NMR) and gas chromatography (GC) with mass spectrometry (MS) detection prior to the 3-month studies. Before the 2-year studies, all three lots (101, 134, and M072911NP) of the test chemical (clear, colorless, oily liquids) were identified as TCPP using ^1^H and carbon-13 (^13^C) NMR spectroscopy. In addition, lots 101 and M072911NP were identified as TCPP using infrared (IR) and ultraviolet-visible (UV/Vis) spectroscopy, GC/MS detection, and measurement of density. IR (Figure A-1), ^1^H NMR (Figure A-2), ^13^C NMR (Figure A-3), and UV/Vis (Figure A-4) spectra were consistent with the structure of TCPP. GC/MS identified one major peak and two isomer peaks for lot 101 before the 3-month studies (Table A-1, System B), and one major peak with three isomer peaks for lot M072911NP before the 2-year studies (Table A-1, System C). The major peak for both lots was identified as tris(1-chloro-2-propyl) phosphate (isomer 1, CASRN 13674-84-5) by comparison with a literature spectrum.^114^ The three other isomers in lot M072911NP were identified as bis(2-chloro-1-methylethyl) 2-chloropropyl phosphate (isomer 2, CASRN 76025-08-6), bis(2-chloropropyl) 2-chloroisopropyl phosphate (isomer 3, CASRN 76649-15-5), and tris(2-chloropropyl) phosphate (isomer 4, CASRN 6145-73-9) by comparing fragmentation patterns to structures of known isomers (Table 1, Table 2). The relative density of TCPP was determined to be 1.2936 ± 0.0004 (sd, standard deviation) at 21.0°C for lot 101 and 1.2959 ± 0.0001 (sd) at 21.5°C for lot M072911NP.

The moisture content as determined by Karl Fischer titration, the acid number, and the ester value were evaluated before the 3-month studies for lot 101 and before the 2-year studies for lot M072911NP. Acid number and ester value were determined for lots 101 and M072911NP using titration with standardized sodium hydroxide (approximately 0.001 N) and hydrochloric acid (approximately 0.5 N), respectively.

Analyses were conducted for lots 101 and 134 to ensure their acceptability before they were combined to form lot M072911NP, which was then used in the 2-year studies. These analyses included purity profiles of lots 101 and 134; elemental analysis of lot 101 for carbon, hydrogen, nitrogen, and chlorine conducted by ICON Development Services (Whitesboro, NY); and octonol:water partition coefficients (log P) for the two largest peaks in the profile of lot 101. After lots 101 and 134 were combined, the purity profile, elemental composition, and log P were determined for the combined lot, M072911NP.

For lot 101, Karl Fischer titration indicated a water content of 0.0997% ± 0.0019 (sd). Elemental analyses for carbon, hydrogen, nitrogen, and chlorine (33.02%, 5.64%, 0.14%, and 31.92%, respectively) were within 2% of theoretical values for TCPP. GC with flame ionization detection (FID) analysis (Table A-1, System E) detected four TCPP peaks with a combined relative area of 95.94%. Ten additional, unidentified impurities were present at concentrations of ≥0.05%. The largest peak in this analysis constituted 64.77% of the total peak area, and log P values for the two largest peaks in this profile were determined to be 2.69 and 2.74, respectively (Table A-1, System D). The average acid number for lot 101 was determined to be 0.011 ± 0.000 (sd) potassium hydroxide (KOH)/g, and the average ester value was calculated to be 104.7 mg KOH/g. The overall purity of lot 101 was determined to be approximately 95%.

For lot 134, the GC/FID (Table A-1, System F) purity profile detected four TCPP peaks with a combined relative area of 98.79% and three reportable impurities ≥0.05% of the total peak area. The largest peak constituted 71.33% of the total peak area. ^1^H NMR and ^13^C NMR spectra of lot 134 were consistent with the anticipated structure of TCPP. Coupled with the purity analysis, these results indicated that lot 134 was suitable for blending with lot 101 to constitute lot M072911NP.

Lot M072911NP was determined to contain 0.039% water by Karl Fischer titration. Elemental analyses for carbon, hydrogen, nitrogen, and chlorine (33.01%, 5.58%, 0.10%, and 32.10%, respectively) were within 2% of the theoretical values for TCPP. GC/FID detected four TCPP peaks (Figure A-5) accounting for a combined relative area of 97.24% using System F and 97.71% using System G (Table A-1). Eight additional, unidentified impurities with peak areas ≥0.05% were present in lot M072911NP. Low-level impurity determination was attempted to identify four minor impurities using an alternate GC/MS system (Table A-1, System H). The impurities could not be identified using National Institute of Standards and Technology (NIST) library spectra; however, they each appeared to have some structural similarities to the TCPP isomers. The major peak in this analysis constituted 68.06%–68.35% of the total peak area, and log P values for the two largest peaks in this profile were determined to be 2.59 and 2.65, respectively (Table A-1, System D). The average acid number for lot M072911NP was determined to be 0.067 ± 0.006 (sd) mg KOH/g, and the average ester value was calculated to be 105.85 mg KOH/g. Additionally, the extinction coefficient (Є_max_) at 280 nm of lot M072911NP was calculated using absorbance values obtained from UV-Vis spectroscopy with a 1% solution of TCPP in methanol. The average Є_max_ was calculated as 3.8 ± 1.3 (sd). The overall purity of lot M072911NP was determined to be ≥97%. A summary of these analyses is given in Table 2.

Accelerated stability studies of lot 101 were conducted by the analytical chemistry laboratory using GC/FID and TCPP-1 (tris[1-chloro-2-propyl] phosphate; TCIPP) as the marker (Table A-1, System F). A single vial was stored at refrigerated (approximately 5°C), room (approximately 25°C), and elevated (approximately 60°C) temperatures for 2 weeks, then analyzed for purity relative to a frozen sample (approximately −20°C). Stability of the bulk chemical was confirmed for at least 2 weeks when stored in glass vials sealed with Teflon-lined crimp caps at temperatures up to 60°C.

## A.2 Preparation and Analysis of Dose Formulations

The base diet was meal feed purchased from Zeigler Brothers, Inc. (Gardners, PA). The 3-month rat study used NIH-07 feed (one lot milled June 2009) in addition to NTP-2000 feed (four lots milled July–October 2009). The 3-month mouse study used NTP-2000 feed (four lots milled July–October 2009). The 2-year rat study used NIH-07 feed (two lots milled September and October 2011) in addition to NTP-2000 feed (24 lots milled October 2011–October 2013). The 2-year mouse study used only NTP-2000 feed (24 lots milled August 2011–September 2013). Other than the analyses performed to determine the suitability of each lot used for feeding the animals, no further feed analysis was performed.

Dose formulations for the 3-month studies were prepared monthly by thoroughly mixing TCPP with feed (Table A-2). For the rat study, dose formulations were prepared with lot 101 at concentrations of 0, 2,500, 5,000, 10,000, 20,000, and 40,000 ppm in NIH-07 feed (July 23 and August 12, 2009) and at concentrations of 0, 2,500, 5,000, 10,000, 20,000 ppm in NTP-2000 feed (August 25, September 22, October 21, and November 18, 2009). For the mouse study, dose formulations were prepared with lot 101 at concentrations of 0, 1,250, 2,500, 5,000, 10,000 and 20,000 ppm in NTP-2000 feed (August 25, September 22, October 21, and November 18, 2009). Dose formulations for the 2-year studies were prepared monthly by thoroughly mixing TCPP with feed (Table A-3). For the rat study, dose formulations were prepared with lot M072911NP at concentrations of 0, 2,500, 5,000, 10,000, and 20,000 ppm in NIH-07 feed (October 18, November 7, and November 18, 2011) and in NTP-2000 feed (27 formulations; November 2011–November 2013). For the 2-year mouse study, formulations were prepared with lot M072911NP at concentrations of 0, 1,250, 2,500, 5,000, and 10,000 ppm in NTP-2000 feed (27 formulations; October 2011–October 2013).

Formulation development studies were conducted by the analytical laboratory MRIGlobal (Kansas City, MO) with a lot (M063008NP; Albemarle) separate from those used for the 3-month and 2-year studies. Formulations were analyzed using GC/FID (Table A-1, System I) and TCPP-1 as the marker. Homogeneity of TCPP in NIH-07 and NTP-2000 feed at 3,040 ppm and 50,000 ppm was tested, and all formulations analyzed were determined to be homogenous and of appropriate concentrations, with relative standard deviations ranging from 0.8% to 1.5%. A 7-day simulated dosing study was conducted on a 3,000 ppm TCPP formulation in NIH-07 and NTP-2000 feed spiked with rodent urine and feces stored in a stainless-steel hopper, at approximately 25°C and 50% relative humidity, and with a 12-hour daily light cycle. The results indicated a loss of ≤5% of TCPP in the formulation after 7 days. Stability studies were conducted on a 3,000 ppm dose formulation of TCPP, using TCPP-1 as the marker, in NIH-07 and NTP-2000 feeds. Test article stability was measured after 42 days at room (approximately 25ºC), refrigerated (approximately 5ºC), and frozen (approximately −20ºC) temperatures. In both feeds, it was concluded that TCPP formulation could be stored up to 14 days under frozen temperatures with no significant loss and up to 42 days frozen with ≤4.4% loss of TCPP. For all studies, dose formulations prepared in NIH-07 and NTP-2000 feed were stored frozen (−15ºC to −30ºC) in sealed containers protected from light and were used within 42 days after preparation.

Before the 3-month studies, the study laboratory conducted homogeneity studies of the 2,500 and 40,000 ppm dose formulations in 25 kg NIH-07 batch sizes and 1,250 and 40,000 ppm dose formulations in 25 kg NTP-2000 batch sizes using GC/FID (Table A-1, System J). Additional homogeneity studies of lot M072911NP at the 2,500 and 20,000 ppm dose formulations in 65 kg NIH-07 batch sizes and the 1,250 and 20,000 ppm dose formulations in 84 kg NTP-2000 batch sizes were performed before the 2-year studies by the study laboratory using GC/FID (Table A-1, System J). All formulations were determined to be homogenous and of appropriate concentration.

For the 3-month studies, periodic analyses of the preadministration dose formulations of TCPP were conducted by the study laboratory every 1 to 2 months to determine purity, whereas postadministration (animal room) samples were analyzed every month (Table A-4, Table A-5) using GC/FID (Table A-1, System K). All preadministration dose formulations for rats and mice were within 10% of the target concentrations. For the 3-month rat study, the postadministration feeder samples from the 2,500, 5,000, and 10,000 ppm formulations prepared on September 22, 2009, were 17.3%, 12.5%, and 13.4% below the target concentrations, respectively. Additionally, the feeder sample from the 2,500 ppm formulation prepared on November 18, 2009, was 10.1% below the target concentration. For the 3-month mouse study, postadministration feeder samples from the 1,250, 2,500, and 5,000 ppm formulations and the bucket sample from the 1,250 ppm formulation prepared on September 22, 2009, were 14.9%, 13.1%, 10.9%, and 11.2% below the target concentrations, respectively. All other postadministration values were within 10% of the target concentrations for the 3-month studies in rats and mice.

For the 2-year studies, periodic analyses of the preadministration dose formulations of TCPP were conducted by the study laboratory every 1 to 3 months to determine purity, whereas postadministration (animal room) samples were analyzed every 1 to 7 months (Table A-6, Table A-7) using GC/FID (Table A-1, System K). All preadministration dose formulations for rats and mice were within 10% of the target concentrations. For the 2-year rat study, the postadministration barrel samples from the 2,500 and 5,000 ppm formulations prepared on January 2, 2013, were 16.0% and 10.3% below the target concentrations, respectively. All other postadministration values were within 10% of the target concentrations for the 2-year studies in rats and mice.

Table A-1 Gas Chromatography Systems Used in the Three-month and Two-year Feed Studies of Tris(chloropropyl) Phosphate

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Mass spectrometry (EI) | Agilent HP-5 (30 m × 0.32 mm, 1.0 μm film thickness) | Helium at 2.0 mL/minute | 170°C for 0 minutes, then 0.5°C/minute to 198°C, no hold
System B
Mass spectrometry (EI) | Agilent DB-5MS (30 m × 0.32 mm, 1.0 μm film thickness) | Helium at 3.5 mL/minute | 170°C for 0 minutes, then 0.5°C/minute to 198°C, no hold
System C
Mass spectrometry (EI) | RTX-5 with Integra Guard (30 m × 0.25 mm, 0.10 μm film thickness) | Helium at 2.0 mL/minute | 160°C for 5 minutes, then 1°C/minute to 180°C, held for 45 minutes
System D
Flame ionization (300ºC) | Agilent DB-5 (30 m × 0.53 mm ID, 1.5 µm film thickness) | Helium at 10.0 mL/minute | 160°C for 5 minutes, then 1°C/minute to 180°C, held for 5 minutes
System E
Flame ionization (300°C) | J&W DB-5 (30 m × 0.53 mm ID, 1.5 µm film thickness) | Helium at 10.0 mL/minute | 170°C for 10 minutes, then 0.5°C/minute to 180°C, held for 10 minutes, then 10°C/minute to 200°C, no hold
System F
Flame ionization (300ºC) | J&W Scientific DB-5 (30 m × 0.53 mm ID, 1.5 µm film thickness) | Helium at 10.0 mL/minute | 160°C for 5 minutes, then 1°C/minute to 180°C, held for 15 minutes
System G
Flame ionization (300ºC) | J&W Scientific DB-Wax (30 m × 0.53 mm ID, 1.0 μm film thickness) | Helium at 10.0 mL/minute | 200°C for 5 minutes, then 1°C/minute to 230°C, held for 15 minutes
System H
Mass spectrometry (EI) | RTX-5 with Integra Guard (30 m x 0.25 mm, 0.10 μm film thickness) | Helium at 2.0 mL/minute for 50 minutes, then 2.0 mL/minute to 10 mL/minute, held for 22 minutes | 160°C for 5 minutes, then 1°C/minute to 180°C, held for 25 minutes, then 10°C/minute to 300°C, held for 10 minutes
System I
Flame ionization (300°C) | J&W Scientific DB-5 (30 m × 0.53 mm ID, 1.5 µm film thickness) | Helium at 10.0 mL/minute | 160°C for 5 minutes, then 1°C/minute to 180°C, held for 5 minutes
System J
Flame ionization (300ºC) | Restek RTX-5 (30 m × 0.53 mm ID, 1.5 μm film thickness) | Helium at 10.0 mL/minute | 160°C for 5 minutes, then 1°C/minute to 180°C, held for 7 minutes
System K
Flame ionization (300ºC) | Restek RTX-5 (30 m × 0.53 mm ID, 1.5 μm film thickness) | Helium at 10.0 mL/minute | 160°C for 5 minutes, then 1°C/minute to 180°C, held for 5 minutes, then 5°C/minute to 230°C, no hold

EI = electron impact; ID = internal diameter.

Table A-2 Preparation and Storage of Dose Formulations Administered to Rats and Mice in the Three-month Feed Studies of Tris(chloropropyl) Phosphate

Preparation
A concentrated premixed stock was made by first weighing a specified amount of untreated feed in a stainless-steel weighing container, weighing a specified amount of test article in a separate weighing container, and then transferring the weighed test article and a small portion of the weighed untreated premix feed into the mixing bowl of a Hobart mixer. The test article and the untreated feed were stirred thoroughly while small amounts of untreated feed were added continually until the mixture appeared to be slightly damp. The weighing container holding the test article was “rinsed” at least three times with more untreated premix feed, which was transferred into the mixing bowl. An amount of untreated premix feed was added to the mixing bowl that equaled the approximate amount of weighed test article. The mixture was stirred with a spatula, if needed, until the mixing paddle on the Hobart mixer was able to rotate. With the mixer at a setting of 2 or lower, untreated premix feed was added in equal portions until all of the premix feed had been incorporated with the test article. The mixture was stirred for roughly 5 minutes longer to ensure thorough mixing. To prepare the dose formulations, approximately half of the required untreated feed for each formulation concentration was added to a Patterson-Kelley 3-ft^3^ twin shell blender until it was distributed evenly. The premixed stock was then added to the blender and distributed evenly over the feed. The stock container was “rinsed” at least three times with additional untreated feed, and the “rinse” was added to the blender. The remaining untreated feed required to reach the desired formulation concentration was added to the blender evenly over the premix, the blender was sealed, and the formulation was mixed for ~15 minutes with the intensifier bar on. The dose formulations were prepared monthly in this manner.
Chemical Lot Number
101
Maximum Storage Time
41 days (NIH-07); 42 days (NTP-2000)
Storage Conditions
Stored in sealed, plastic bag-lined buckets at −15°C to −30°C
Study Laboratory
Battelle (Columbus, OH)

Table A-3 Preparation and Storage of Dose Formulations Administered to Rats and Mice in the Two-year Feed Studies of Tris(chloropropyl) Phosphate

Preparation
A concentrated premixed stock was made by first weighing a specified amount of untreated feed in a stainless-steel weighing container, weighing a specified amount of test article in a separate weighing container, and then transferring the weighed test article and a small portion of the weighed untreated premix feed into the mixing bowl of a Hobart mixer. The test article and the untreated feed were stirred thoroughly while small amounts of untreated feed were added continually until the mixture appeared to be slightly damp. The weighing container holding the test article was “rinsed” at least three times with more untreated premix feed, which was transferred into the mixing bowl. An amount of untreated premix feed was added to the mixing bowl that equaled the approximate amount of weighed test article. The mixture was stirred with a spatula, if needed, until the mixing paddle on the Hobart mixer was able to rotate. With the mixer at a setting of 2 or lower, untreated premix feed was added in equal portions until all of the premix feed had been incorporated with the test article. The mixture was stirred for roughly 5 minutes longer to ensure thorough mixing. To prepare the dose formulations, approximately half of the required untreated feed for each formulation concentration was added to a Patterson-Kelley 3-ft^3^ twin shell blender until it was distributed evenly. The premixed stock was then added to the blender and distributed evenly over the feed. The stock container was “rinsed” at least three times with additional untreated feed, and the “rinse” was added to the blender. The remaining untreated feed required to reach the desired formulation concentration was added to the blender evenly over the premix, the blender was sealed, and the formulation was mixed for ~15 minutes with the intensifier bar on. The dose formulations were prepared monthly in this manner.
Chemical Lot Number
M072911NP
Maximum Storage Time
42 days
Storage Conditions
Stored in plastic bags within sealed plastic barrels at −15°C to −30°C
Study Laboratory
Battelle (Columbus, OH)

Table A-4 Results of Analyses of Dose Formulations Administered to Rats in the Perinatal and Three-month Feed Study of Tris(chloropropyl) Phosphate

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
July 23, 2009 | July 29, 2009 | 0 | BLOQ | NA
| | 2,500 | 2,520 ± 92.9 | 0.9
| | 5,000 | 5,070 ± 125.0 | 1.5
| | 10,000 | 10,300 ± 305.5 | 3.3
| | 20,000 | 20,000 ± 0.0 | 0.0
| | 40,000^b^ | 40,200 ± 288.7 | 0.6
August 25, 2009 | August 27, 2009 | 0 | BLOQ | NA
| | 2,500 | 2,580 ± 20.8 | 3.1
| | 5,000 | 5,300 ± 60.8 | 5.4
| | 10,000 | 10,100 ± 115.5 | 1.3
| | 20,000 | 20,000 ± 152.8 | 0.2
September 22, 2009 | September 25, 2009 | 0 | BLOQ | NA
| | 2,500 | 2,440 ± 26.5 | −2.4
| | 5,000 | 5,030 ± NA^c^ | 0.6
| | 10,000 | 10,500 ± 839 | 5.3
| | 20,000 | 20,000 ± 231 | −0.2
November 18, 2009 | November 20, 2009 | 0 | BLOQ | NA
| | 2,500 | 2,510 ± 104.4 | 0.4
| | 5,000 | 5,160 ± 234.4 | 3.3
| | 10,000 | 9,760 ± 118.5 | −2.4
| | 20,000 | 19,700 ± 793.7 | −1.5
Animal Room Samples
July 23, 2009 | September 3, 2009 (feeder) | 0 | BLOQ | NA
| | 2,500 | 2,370 ± 17.3 | −5.2
| | 5,000 | 4,840 ± 30.6 | −3.1
| | 10,000 | 9,600 ± 64.3 | −3.9
| | 20,000 | 19,600 ± 200.0 | −2.0
| | 40,000^b^ | NA | NA
July 23, 2009 | September 3, 2009 (bucket) | 0 | BLOQ | NA
| | 2,500 | 2,530 ± NA^c^ | 1.2
| | 5,000 | 4,970 ± 26.5 | −0.6
| | 10,000 | 10,000 ± 202.1 | −0.3
| | 20,000 | 19,600 ± 57.7 | −2.2
| | 40,000 | 39,100 ± 300.0 | −2.3
August 25, 2009 | October 9, 2009 (feeder) | 0 | BLOQ | NA
| | 2,500 | 2,340 ± 25.2 | −6.3
| | 5,000 | 4,750 ± 5.8 | −4.9
| | 10,000 | 9,340 ± 76.4 | −6.6
| | 20,000 | 18,600 ± 152.8 | −6.8
August 25, 2009 | October 9, 2009 (bucket) | 0 | BLOQ | NA
| | 2,500 | 2,450 ± 15.3 | −1.9
| | 5,000 | 4,980 ± 15.3 | −0.3
| | 10,000 | 9,760 ± 49.3 | −2.4
| | 20,000 | 19,700 ± 288.7 | −1.3
September 22, 2009 | November 6, 2009 (feeder) | 0 | BLOQ | NA
| | 2,500 | 2,070 ± 20.8 | −17.3
| | 5,000 | 4,370 ± 66.6 | −12.5
| | 10,000 | 8,660 ± 198.6 | −13.5
| | 20,000 | 18,200 ± 260.6 | −9.0
September 22, 2009 | November 6, 2009 (bucket) | 0 | BLOQ | NA
| | 2,500 | 2,280 ± 20.8 | −8.7
| | 5,000 | 4,820 ± 10.0 | −3.6
| | 10,000 | 9,370 ± 253.8 | −6.3
| | 20,000 | 19,600 ± 351.2 | −2.2
November 18, 2009 | December 18, 2009 (feeder) | 0 | BLOQ | NA
| | 2,500 | 2,250 ± 5.8 | −10.1
| | 5,000 | 4,580 ± 20.0 | −8.4
| | 10,000 | 9,260 ± 55.1 | −7.4
| | 20,000 | 19,300 ± 360.6 | −3.5
November 18, 2009 | December 18, 2009 (bucket) | 0 | BLOQ | NA
| | 2,500 | 2,390 ± 30.0 | −4.4
| | 5,000 | 4,830 ± 10.0 | −3.4
| | 10,000 | 9,850 ± 92.4 | −1.5
| | 20,000 | 20,100 ± 1,006.6 | 0.3

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Data shown are mean ± nonrounded standard deviation.

^b^ All dams in the 40,000 ppm group were either found dead or euthanized moribund on or before gestation day 13; no feeder samples were gathered for postadministration analysis.

^c^ Duplicate samples analyzed, precision of duplicates is 1.0 for these replicates.

Table A-5 Results of Analyses of Dose Formulations Administered to Mice in the Three-month Feed Study of Tris(chloropropyl) Phosphate

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
August 25, 2009 | August 27, 2009 | 0 | BLOQ | NA
| | 1,250 | 1,310 ± 15.3 | 4.5
| | 2,500 | 2,580 ± 20.8 | 3.1
| | 5,000 | 5,300 ± 60.8 | 5.4
| | 10,000 | 10,100 ± 115.5 | 1.3
| | 20,000 | 20,000 ± 152.8 | 0.2
September 22, 2009 | September 25, 2009 | 0 | BLOQ | NA
| | 1,250 | 1,250 ± 32.1 | 0.3
| | 2,500 | 2,440 ± 26.5 | −2.4
| | 5,000 | 5,030 ± NA^b^ | 0.6
| | 10,000 | 10,500 ± 839 | 5.3
| | 20,000 | 20,000 ± 231 | −0.2
November 18, 2009 | November 20, 2009 | 0 | BLOQ | NA
| | 1,250 | 1,340 ± 25.2 | 6.9
| | 2,500 | 2,510 ± 104.4 | 0.4
| | 5,000 | 5,160 ± 234.4 | 3.3
| | 10,000 | 9,760 ± 118.5 | −2.4
| | 20,000 | 19,700 ± 793.7 | −1.5
Animal Room Samples
August 25, 2009 | October 9, 2009 (feeder) | 0 | BLOQ | NA
| | 1,250 | 1,260 ± 35.1 | 1.1
| | 2,500 | 2,410 ± 10.0 | −3.6
| | 5,000 | 5,010 ± 30.6 | 0.1
| | 10,000 | 9,980 ± 125.8 | −0.2
| | 20,000 | 19,200 ± 57.7 | −3.8
August 25, 2009 | October 9, 2009 (bucket) | 0 | BLOQ | NA
| | 1,250 | 1,250 ± 15.3 | −0.3
| | 2,500 | 2,490 ± 20.8 | −0.5
| | 5,000 | 5,010 ± 11.5 | 0.1
| | 10,000 | 9,940 ± 55.1 | −0.6
| | 20,000 | 20,100 ± 173.2 | 0.5
September 22, 2009 | November 6, 2009 (feeder) | 0 | BLOQ | NA
| | 1,250 | 1,060 ± 6 | −14.9
| | 2,500 | 2,170 ± 123 | −13.1
| | 5,000 | 4,460 ± 40 | −10.9
| | 10,000 | 9,340 ± 242 | −6.6
| | 20,000 | 18,900 ± 954 | −5.5
September 22, 2009 | November 6, 2009 (bucket) | 0 | BLOQ | NA
| | 1,250 | 1,110 ± 10 | −11.2
| | 2,500 | 2,300 ± 67 | −8.1
| | 5,000 | 4,690 ± 74 | −6.3
| | 10,000 | 9,530 ± 197 | −4.7
| | 20,000 | 19,400 ± 115 | −3.2
November 18, 2009 | December 18, 2009 (feeder) | 0 | BLOQ | NA
| | 1,250 | 1,160 ± 20.8 | −6.9
| | 2,500 | 2,360 ± 86.2 | −5.7
| | 5,000 | 4,880 ± 134.3 | −2.5
| | 10,000 | 9,830 ± 378.6 | −1.7
| | 20,000 | 19,200 ± 776.7 | −3.8
November 18, 2009 | December 18, 2009 (bucket) | 0 | BLOQ | NA
| | 1,250 | 1,190 ± 20.8 | −4.5
| | 2,500 | 2,400 ± 20.0 | −4.0
| | 5,000 | 4,870 ± 23.1 | −2.7
| | 10,000 | 9,970 ± 60.8 | −0.3
| | 20,000 | 19,400 ± 351.2 | −3.2

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Data shown are mean ± nonrounded standard deviation.

^b^ Duplicate samples analyzed, precision of duplicates is 1.0 for these replicates.

Table A-6 Results of Analyses of Dose Formulations Administered to Rats in the Perinatal and Two-year Feed Study of Tris(chloropropyl) Phosphate

Date Prepared | Date Analyzed^a^ | Target Concentration (ppm)^b^ | Determined Concentration (ppm)^c^ | Difference from Target (%)
October 18, 2011 | October 18, 2011 | 0 | BLOQ | NA
| | 2,500 | 2,460 ± 10 | −1.6
| | 5,000 | 5,000 ± 20 | 0.0
| | 10,000 | 10,000 ± 100 | 0.1
| | 20,000 | 20,100 ± 100 | 0.5
November 10, 2011 | November 11, 2011 | 0 | BLOQ | NA
| | 2,500 | 2,480 ± 10 | −0.7
| | 2,500 | 2,490 ± 40 | −0.5
| | 5,000 | 4,950 ± 70 | −1.1
| | 5,000 | 5,120 ± 120 | 2.3
| | 10,000 | 9,990 ± 90 | −0.1
| | 10,000 | 10,200 ± 300 | 1.8
| | 20,000 | 20,100 ± 200 | 0.7
| | 20,000 | 20,200 ± 300 | 1.2
January 31, 2012 | February 2, 2012 | 0 | BLOQ | NA
| | 2,500 | 2,490 ± 10 | −0.4
| | 2,500 | 2,500 ± 10 | 0.1
| | 5,000 | 5,050 ± 80 | 0.9
| | 5,000 | 4,980 ± 20 | −0.5
| | 10,000 | 9,860 ± 40 | −1.4
| | 10,000 | 9,890 ± 10 | −1.1
| | 20,000 | 19,800 ± 200 | −1.0
| | 20,000 | 19,700 ± 300 | −1.3
March 28, 2012 | March 29, 2012 | 0 | BLOQ | NA
| | 2,500 | 2,480 ± 0 | −0.8
| | 2,500 | 2,500 ± 60 | 0.0
| | 5,000 | 4,920 ± 20 | −1.6
| | 5,000 | 4,950 ± 70 | −0.9
| | 10,000 | 9,970 ± 20 | −0.3
| | 10,000 | 9,900 ± 40 | −1.0
| | 20,000 | 19,900 ± 100 | −0.5
| | 20,000 | 19,800 ± 0 | −1.0
June 19, 2012 | June 20, 2012 | 0 | BLOQ | NA
| | 2,500 | 2,370 ± 30 | −5.2
| | 2,500 | 2,380 ± 30 | −4.7
| | 5,000 | 4,850 ± 20 | −3.1
| | 5,000 | 4,820 ± 40 | −3.6
| | 10,000 | 9,640 ± 30 | −3.6
| | 10,000 | 9,680 ± 60 | −3.2
| | 20,000 | 19,400 ± 200 | −2.8
| | 20,000 | 19,200 ± 200 | −4.2
August 14, 2012 | August 14, 2012 | 0 | BLOQ | NA
| | 2,500 | 2,380 ± 100 | −4.7
| | 2,500 | 2,490 ± 20 | −0.3
| | 5,000 | 5,050 ± 20 | 1.1
| | 5,000 | 5,020 ± 30 | 0.3
| | 10,000 | 10,200 ± 100 | 2.3
| | 10,000 | 10,200 ± 100 | 1.7
| | 20,000 | 20,800 ± 200 | 3.8
| | 20,000 | 20,200 ± 200 | 1.0
November 8, 2012 | November 8, 2012 | 0 | BLOQ | NA
| | 2,500 | 2,510 ± 10 | 0.3
| | 2,500 | 2,490 ± 10 | −0.4
| | 5,000 | 4,960 ± 10 | −0.8
| | 5,000 | 4,950 ± 20 | −1.1
| | 10,000 | 10,000 ± 200 | 0.2
| | 10,000 | 9,930 ± 150 | −0.7
| | 20,000 | 19,700 ± 100 | −1.7
| | 20,000 | 19,600 ± 100 | −1.8
January 2, 2013 | January 4, 2013 | 0 | BLOQ | NA
| | 2,500 | 2,500 ± 10 | 0.1
| | 2,500 | 2,510 ± 10 | 0.5
| | 5,000 | 5,000 ± 10 | −0.1
| | 5,000 | 5,020 ± 0 | 0.4
| | 10,000 | 10,100 ± 100 | 0.5
| | 10,000 | 10,100 ± 100 | 0.7
| | 20,000 | 20,400 ± 600 | 1.8
| | 20,000 | 20,000 ± 200 | −0.2
March 26, 2013 | March 27, 2013 | 0 | BLOQ | NA
| | 2,500 | 2,550 ± 10 | 1.9
| | 2,500 | 2,560 ± 10 | 2.5
| | 5,000 | 4,990 ± 40 | −0.2
| | 5,000 | 5,020 ± 20 | 0.4
| | 10,000 | 10,200 ± 200 | 2.0
| | 10,000 | 9,990 ± 90 | −0.1
| | 20,000 | 19,900 ± 100 | −0.5
| | 20,000 | 19,800 ± 100 | −0.8
May 22, 2013 | May 23, 2013 | 0 | BLOQ | NA
| | 2,500 | 2,560 ± 20 | 2.3
| | 2,500 | 2,580 ± 110 | 3.1
| | 5,000 | 5,080 ± 20 | 1.5
| | 5,000 | 4,980 ± 10 | −0.3
| | 10,000 | 10,100 ± 100 | 0.8
| | 10,000 | 10,100 ± 100 | 0.7
| | 20,000 | 20,000 ± 100 | −0.2
| | 20,000 | 20,700 ± 500 | 3.3
August 15, 2013 | August 15, 2013 | 0 | BLOQ | NA
| | 2,500 | 2,530 ± 0 | 1.2
| | 2,500 | 2,530 ± 30 | 1.1
| | 5,000 | 4,970 ± 30 | −0.6
| | 5,000 | 4,960 ± 30 | −0.7
| | 10,000 | 9,970 ± 30 | −0.3
| | 10,000 | 9,980 ± 30 | −0.2
| | 20,000 | 19,800 ± 300 | −1.0
| | 20,000 | 19,700 ± 400 | −1.7
October 16, 2013 | October 15, 2013 | 0 | BLOQ | NA
| | 2,500 | 2,560 ± 20 | 2.5
| | 2,500 | 2,550 ± 20 | 2.1
| | 5,000 | 5,000 ± 80 | 0.1
| | 5,000 | 5,000 ± 10 | 0.0
| | 10,000 | 10,000 ± 100 | 0.2
| | 10,000 | 9,950 ± 50 | −0.5
| | 20,000 | 19,900 ± 100 | −0.5
| | 20,000 | 19,900 ± 200 | −0.3
Animal Room Samples
October 18, 2011 | November 21, 2011 (feeder) | 0 | BLOQ | NA
| | 2,500 | 2,480 ± 30 | −0.9
| | 5,000 | 4,930 ± 50 | −1.5
| | 10,000 | 9,950 ± 130 | −0.5
| | 20,000 | 20,000 ± 300 | 0.0
October 18, 2011 | November 21, 2011 (barrel) | 0 | BLOQ | NA
| | 2,500 | 2,490 ± 20 | −0.5
| | 5,000 | 4,990 ± 30 | −0.2
| | 10,000 | 10,000 ± 100 | 0.2
| | 20,000 | 20,100 ± 100 | 0.5
November 10, 2011 | December 20, 2011 (feeder) | 0 | BLOQ | NA
| | 2,500 | 2,350 ± 20 | −6.1
| | 5,000 | 4,740 ± 10 | −5.3
| | 10,000 | 9,320 ± 170 | −6.8
| | 20,000 | 18,200 ± 100 | −8.8
November 10, 2011 | December 20, 2011 (barrel) | 0 | BLOQ | NA
| | 2,500 | 2,470 ± 30 | −1.1
| | 5,000 | 5,000 ± 90 | −0.1
| | 10,000 | 10,600 ± 600 | 6.0
| | 20,000 | 20,300 ± 800 | 1.5
June 19, 2012 | July 31, 2012 (feeder) | 0 | BLOQ | NA
| | 2,500 | 2,390 ± 20 | −4.5
| | 5,000 | 5,000 ± 10 | 0.0
| | 10,000 | 10,000 ± 100 | 0.0
| | 20,000 | 20,600 ± 300 | 3.0
June 19, 2012 | July 31, 2012 (barrel) | 0 | BLOQ | NA
| | 2,500 | 2,560 ± 20 | 2.5
| | 5,000 | 4,700 ± 40 | −5.9
| | 10,000 | 9,310 ± 100 | −6.9
| | 20,000 | 19,000 ± 200 | −4.8
January 2, 2013 | February 14, 2013 (feeder) | 0 | BLOQ | NA
| | 2,500 | 2,100 ± 50 | −16.0
| | 5,000 | 4,490 ± 170 | −10.3
| | 10,000 | 9,400 ± 40 | −6.0
| | 20,000 | 19,400 ± 100 | −2.8
January 2, 2013 | February 14, 2013 (barrel) | 0 | BLOQ | NA
| | 2,500 | 2,450 ± 20 | −2.0
| | 5,000 | 4,950 ± 20 | −1.0
| | 10,000 | 9,960 ± 50 | −0.4
| | 20,000 | 19,900 ± 100 | −0.7
August 15, 2013 | September 24, 2013 (feeder) | 0 | BLOQ | NA
| | 2,500 | 2,400 ± 20 | −4.0
| | 5,000 | 4,700 ± 40 | −6.1
| | 10,000 | 9,800 ± 100 | −2.0
| | 20,000 | 19,200 ± 300 | −3.8
August 15, 2013 | September 24, 2013 (barrel) | 0 | BLOQ | NA
| | 2,500 | 2,520 ± 10 | 0.7
| | 5,000 | 4,970 ± 20 | −0.7
| | 10,000 | 9,780 ± 70 | −2.2
| | 20,000 | 18,900 ± 100 | −5.3

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Date first chromatograms were acquired, which may precede the sample collection.

^b^ Preadministration individual batches were analyzed separately.

^c^ Data shown are mean ± standard deviation.

Table A-7 Results of Analyses of Dose Formulations Administered to Mice in the Two-year Feed Study of Tris(chloropropyl) Phosphate

Date Prepared | Date Analyzed^a^ | Target Concentration (ppm)^b^ | Determined Concentration (ppm)^c^ | Difference from Target (%)
October 11, 2011 | October 11, 2011 | 0 | BLOQ | NA
| | 1,250 | 1,270 ± 10 | 1.3
| | 2,500 | 2,500 ± 10 | 0.0
| | 5,000 | 4,960 ± 40 | −0.9
| | 10,000 | 9,960 ± 120 | −0.4
November 10, 2011 | November 11, 2011 | 0 | BLOQ | NA
| | 1,250 | 1,250 ± 20 | 0.3
| | 2,500 | 2,480 ± 10 | −0.7
| | 2,500 | 2,490 ± 40 | −0.5
| | 5,000 | 4,950 ± 70 | −1.1
| | 5,000 | 5,120 ± 120 | 2.3
| | 10,000 | 9,990 ± 90 | −0.1
| | 10,000 | 10,200 ± 300 | 1.8
January 31, 2012 | February 2, 2012 | 0 | BLOQ | NA
| | 1,250 | 1,260 ± 10 | 0.5
| | 2,500 | 2,490 ± 10 | −0.4
| | 2,500 | 2,500 ± 10 | 0.1
| | 5,000 | 5,050 ± 80 | 0.9
| | 5,000 | 4,980 ± 20 | −0.5
| | 10,000 | 9,860 ± 40 | −1.4
| | 10,000 | 9,890 ± 10 | −1.1
March 28, 2012 | March 29, 2012 | 0 | BLOQ | NA
| | 1,250 | 1,210 ± 10 | −2.9
| | 2,500 | 2,480 ± 0 | −0.8
| | 2,500 | 2,500 ± 60 | 0.0
| | 5,000 | 4,920 ± 20 | −1.6
| | 5,000 | 4,950 ± 70 | −0.9
| | 10,000 | 9,970 ± 20 | −0.3
| | 10,000 | 9,900 ± 40 | −1.0
June 19, 2012 | June 20, 2012 | 0 | BLOQ | NA
| | 1,250 | 1,170 ± 10 | −6.7
| | 2,500 | 2,370 ± 30 | −5.2
| | 2,500 | 2,380 ± 30 | −4.7
| | 5,000 | 4,850 ± 20 | −3.1
| | 5,000 | 4,820 ± 40 | −3.6
| | 10,000 | 9,640 ± 30 | −3.6
| | 10,000 | 9,680 ± 60 | −3.2
August 14, 2012 | August 14, 2012 | 0 | BLOQ | NA
| | 1,250 | 1,210 ± 10 | −3.2
| | 2,500 | 2,380 ± 100 | −4.7
| | 2,500 | 2,490 ± 20 | −0.3
| | 5,000 | 5,050 ± 20 | 1.1
| | 5,000 | 5,020 ± 30 | 0.3
| | 10,000 | 10,200 ± 100 | 2.3
| | 10,000 | 10,200 ± 100 | 1.7
November 8, 2012 | November 8, 2012 | 0 | BLOQ | NA
| | 1,250 | 1,260 ± 20 | 0.5
| | 2,500 | 2,510 ± 10 | 0.3
| | 2,500 | 2,490 ± 10 | −0.4
| | 5,000 | 4,960 ± 10 | −0.8
| | 5,000 | 4,950 ± 20 | −1.1
| | 10,000 | 10,000 ± 200 | 0.2
| | 10,000 | 9,930 ± 150 | −0.7
January 2, 2013 | January 4, 2013 | 0 | BLOQ | NA
| | 1,250 | 1,260 ± 10 | 0.5
| | 2,500 | 2,500 ± 10 | 0.1
| | 2,500 | 2,510 ± 10 | 0.5
| | 5,000 | 5,000 ± 10 | −0.1
| | 5,000 | 5,020 ± 0 | 0.4
| | 10,000 | 10,100 ± 100 | 0.5
| | 10,000 | 10,100 ± 100 | 0.7
March 26, 2013 | March 27, 2013 | 0 | BLOQ | NA
| | 1,250 | 1,320 ± 10 | 5.6
| | 2,500 | 2,550 ± 10 | 1.9
| | 2,500 | 2,560 ± 10 | 2.5
| | 5,000 | 4,990 ± 40 | −0.2
| | 5,000 | 5,020 ± 20 | 0.4
| | 10,000 | 10,200 ± 200 | 2.0
| | 10,000 | 9,990 ± 90 | −0.1
May 22, 2013 | May 23, 2013 | 0 | BLOQ | NA
| | 1,250 | 1,330 ± 10 | 6.1
| | 2,500 | 2,560 ± 20 | 2.3
| | 2,500 | 2,580 ± 110 | 3.1
| | 5,000 | 5,080 ± 20 | 1.5
| | 5,000 | 4,980 ± 10 | −0.3
| | 10,000 | 10,100 ± 100 | 0.8
| | 10,000 | 10,100 ± 100 | 0.7
August 15, 2013 | August 15, 2013 | 0 | BLOQ | NA
| | 1,250 | 1,280 ± 10 | 2.7
| | 2,500 | 2,530 ± 0 | 1.2
| | 2,500 | 2,530 ± 30 | 1.1
| | 5,000 | 4,970 ± 30 | −0.6
| | 5,000 | 4,960 ± 30 | −0.7
| | 10,000 | 9,970 ± 30 | −0.3
| | 10,000 | 9,980 ± 30 | −0.2
October 16, 2013 | October 15, 2013 | 0 | BLOQ | NA
| | 1,250 | 1,310 ± 0 | 4.8
| | 2,500 | 2,560 ± 20 | 2.5
| | 2,500 | 2,550 ± 20 | 2.1
| | 5,000 | 5,000 ± 80 | 0.1
| | 5,000 | 5,000 ± 10 | 0.0
| | 10,000 | 10,000 ± 100 | 0.2
| | 10,000 | 9,950 ± 50 | −0.5
Animal Room Samples
October 11, 2011 | November 22, 2011 (feeder) | 0 | BLOQ | NA
| | 1,250 | 1,150 ± 10 | −8.3
| | 2,500 | 2,320 ± 10 | −7.1
| | 5,000 | 4,570 ± 110 | −8.5
| | 10,000 | 9,180 ± 20 | −8.2
October 11, 2011 | November 22, 2011 (barrel) | 0 | BLOQ | NA
| | 1,250 | 1,190 ± 20 | −4.5
| | 2,500 | 2,430 ± 20 | −2.9
| | 5,000 | 4,970 ± 100 | −0.6
| | 10,000 | 9,780 ± 30 | −2.2
November 10, 2011 | December 20, 2011 (feeder) | 0 | BLOQ | NA
| | 1,250 | 1,210 ± 10 | −3.5
| | 2,500 | 2,410 ± 20 | −3.7
| | 5,000 | 4,810 ± 10 | −3.8
| | 10,000 | 9,010 ± 60 | −9.9
November 10, 2011 | December 20, 2011 (barrel) | 0 | BLOQ | NA
| | 1,250 | 1,260 ± 10 | 0.5
| | 2,500 | 2,470 ± 30 | −1.1
| | 5,000 | 5,000 ± 90 | −0.1
| | 10,000 | 10,600 ± 600 | 6.0
June 19, 2012 | July 31, 2012 (feeder) | 0 | BLOQ | NA
| | 1,250 | 1,290 ± 10 | 2.9
| | 2,500 | 2,470 ± 10 | −1.2
| | 5,000 | 4,890 ± 50 | −2.2
| | 10,000 | 9,430 ± 80 | −5.7
June 19, 2012 | July 31, 2012 (barrel) | 0 | BLOQ | NA
| | 1,250 | 1,290 ± 10 | 2.9
| | 2,500 | 2,560 ± 20 | 2.5
| | 5,000 | 4,700 ± 40 | −5.9
| | 10,000 | 9,310 ± 100 | −6.9
January 2, 2013 | February 14, 2013 (feeder) | 0 | BLOQ | NA
| | 1,250 | 1,170 ± 20 | −6.4
| | 2,500 | 2,450 ± 10 | −2.0
| | 5,000 | 4,930 ± 10 | −1.3
| | 10,000 | 9,380 ± 70 | −6.2
January 2, 2013 | February 14, 2013 (barrel) | 0 | BLOQ | NA
| | 1,250 | 1,210 ± 10 | −3.5
| | 2,500 | 2,450 ± 20 | −2.0
| | 5,000 | 4,950 ± 20 | −1.0
| | 10,000 | 9,960 ± 50 | −0.4
August 15, 2013 | September 24, 2013 (feeder) | 0 | BLOQ | NA
| | 1,250 | 1,250 ± 10 | −0.3
| | 2,500 | 2,420 ± 10 | −3.1
| | 5,000 | 4,790 ± 60 | −4.1
| | 10,000 | 9,510 ± 70 | −4.9
August 15, 2013 | September 24, 2013 (barrel) | 0 | BLOQ | NA
| | 1,250 | 1,220 ± 30 | −2.1
| | 2,500 | 2,520 ± 10 | 0.7
| | 5,000 | 4,970 ± 20 | −0.7
| | 10,000 | 9,780 ± 70 | −2.2

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Date first chromatograms were acquired, which may precede the sample collection.

^b^ Preadministration individual batches were analyzed separately.

^c^ Data shown are mean ± standard deviation.

Figure A-1

Infrared Absorption Spectrum of Tris(chloropropyl) Phosphate (Lot M072911NP)

Figure A-2

^1^H Nuclear Magnetic Resonance Spectrum of Tris(chloropropyl) Phosphate (Lot M072911NP)

Figure A-3

^13^C Nuclear Magnetic Resonance Spectrum of Tris(chloropropyl) Phosphate (Lot M072911NP)

Figure A-4

Ultraviolet/Visible Spectrum of Tris(chloropropyl) Phosphate (Lot M072911NP)

Figure A-5

Gas Chromatogram of Tris(chloropropyl) Phosphate (Lot M072911NP)