# Overview

Phthalates are plasticizers used to provide flexibility in products composed of polyvinyl chloride plastic or vinyl chloride resins. Studies have shown that in utero and early life phthalate exposure can result in adverse reproductive, developmental, and potentially carcinogenic effects. The National Toxicology Program therefore initiated a broad-based program of work to provide toxicity data and a cancer hazard assessment for lifetime exposure to environmental phthalates. Data generated from this program are intended to facilitate cumulative and aggregate risk characterization efforts for multiple phthalates, including di(2-ethylhexyl) phthalate (DEHP), di-n-butyl phthalate, and di-isobutyl phthalate.

Previous carcinogenicity assessments of phthalates did not include perinatal exposure (gestation and lactation), whereas human exposure studies indicate that there is lifetime exposure to some phthalates. Thus, whether developmental exposure would alter lifetime DEHP-associated carcinogenic risk is unknown. Exposure during these critical periods of development and growth might be relevant for the evaluation of lifetime toxicological and carcinogenic risk.

The two 2-year toxicity and carcinogenicity studies described in this technical report were conducted to assess whether perinatal exposure would alter lifetime DEHP-associated carcinogenic risk. Specifically, the goal of the studies was to evaluate whether exposure to DEHP during the perinatal period would influence the pattern, dose response, incidence, or severity of the carcinogenic or noncarcinogenic response in rats relative to chronic exposure that does not include this critical period of development and growth.