# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-601

Report Series: NTP Technical Report Series

Report Series Number: 601

Official citation: National Toxicology Program (NTP). 2021. NTP technical report on the toxicology and carcinogenesis studies of di(2-ethylhexyl) phthalate (CASRN 117-81-7) administered in feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats. Research Triangle Park, NC: National Toxicology Program. Technical Report 601.