# Peer Review

The National Toxicology Program (NTP) convened a virtual external ad hoc panel to peer review the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of Di(2-ethylhexyl) Phthalate (CASRN 117-81-7) Administered in Feed to Sprague Dawley Hsd:Sprague Dawley^®^ SD^®^) Rats on April 2, 2021. NTP announced the peer-review meeting in the Federal Register (86 FR. 9947. February 17, 2021). The public could view the proceedings online and opportunities were provided for submission of written and oral public comments. The selection of panel members and conduct of the peer review were in accordance with federal policies and regulations. The panel was charged to:

1. Review and evaluate the scientific and technical elements of each study and its presentation.
2. Determine whether each study’s experimental design, conduct, and findings support the NTP’s conclusions regarding the conditions of each study.

NTP carefully considered the panel’s recommendations in finalizing the report. The peer-review report is provided in Appendix G. Other meeting materials are available on the NTP website (https://ntp.niehs.nih.gov/go/meeting).

## Peer Reviewers

- Gabriele Ludewig, Ph.D., Chairperson
  Professor, Department of Occupational and Environmental Health, College of Public Health
  University of Iowa
  Iowa City, Iowa, USA
- Tracie Bunton, D.V.M., Ph.D.
  Founder
  Eicarte LLC: Pharmaceutical Preclinical Toxicology and Pathology Consultancy
  Gettysburg, Pennsylvania, USA
- Michael Elwell, D.V.M., Ph.D.
  Consultant, Toxicologic Pathology
  APEX TOXPATH, LLC
  Apex, North Carolina, USA
- Charles Mahrt, D.V.M., Ph.D.
  Flagship Biosciences (Retired)
  Broomfield, Colorado, USA
- Daniel Spade, Ph.D.
  Assistant Professor, Department of Pathology and Laboratory Medicine
  Brown University
  Providence, Rhode Island, USA
- John Pierce Wise, Sr., Ph.D.
  Professor, Department of Pharmacology and Toxicology
  University of Louisville
  Louisville, Kentucky, USA