# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  C.R. Blystone, Ph.D., Co-Study Scientist
  T.D. Hubbard, Ph.D., Co-Study Scientist
  S.A. Elmore, D.V.M., M.S., Study Pathologist
  M.F. Cesta, D.V.M., Ph.D.
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  P.M. Foster, Ph.D. (Retired)
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D. (Retired)
  B.S. McIntyre, Ph.D.
  F.M. Parham, Ph.D.
  G.K. Roberts, Ph.D.
  V.G. Robinson, M.S.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  A.T.D. Watson, Ph.D.
  K.L. Witt, M.S.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Battelle, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  C.A. Granville, Ph.D.
  D.Y. Vasconcelos, D.V.M., Ph.D.
- Conducted prestart chemistry activities and dose formulations
  B.L. Burback, Ph.D.
  D.A. Contos, M.S.
  N.L. South, B.S.
- RTI International, Research Triangle Park, North Carolina, USA
  Conducted preliminary chemistry activities, dose formulations, and biological sample chemistry analyses
  R.A. Fernando, Ph.D., Principal Investigator
  J.C. Blake, B.A., Deputy Principal Investigator
  S.D. Cooper, M.S.
  J. Gilliam, B.S.
  J. Lieause, M.S.
  M. Silinski, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review
  T.A. Crabbs, D.V.M.
  M. Gruebbel, D.V.M., Ph.D.
  G.A. Willson, B.V.M.S.
- Coordinated NTP Pathology Working Groups on perinatal and postweaning rats (Study 1) (May 10, 2018) and on postweaning-only rats (Study 2) (September 29, 2016)
  T.A. Crabbs, D.V.M. (Study 1)
  G.A. Willson, B.V.M.S. (Study 2)
- Coordinated NTP Pathology Peer Review on brain glial cell proliferative lesions in rats (Study 1 and Study 2) (April 18, 2016)
  M. Gruebbel, D.V.M., Ph.D.
- Coordinated NTP Pathology Peer Review on brain granular cell proliferative lesions and head/neck schwannomas/sarcomas in rats (Study 1 and Study 2) (April 18, 2016)
  M. Gruebbel, D.V.M., Ph.D.
- ASRC Federal, Research Triangle Park, North Carolina, USA
  Prepared data for report
  P. Brown, B.S.
  H. Gong, M.S.
  C. Martini, B.S.
  C. Myers, M.S.
  N. Sayers, B.S.
  M. Shaw, B.S.
  R. Whittlesey, M.S.