# References

1 National Center for Biotechnology Information (NCBI). PubChem Compound Summary: Bis(2-ethylhexyl) phthalate, CID 8343. Bethesda, MD: National Center for Biotechnology Information. https://pubchem.ncbi.nlm.nih.gov/compound/Bis_2-ethylhexyl_-phthalate
2 National Institute for Occupational Safety and Health (NIOSH). NIOSH pocket guide to chemical hazards, di-sec octyl phthalate. U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2019. https://www.cdc.gov/niosh/npg/npgd0236.html
3 U.S. Environmental Protection Agency (USEPA). CompTox Chemistry Dashboard: Di(2-ethylhexyl) phthalate 117-81-7 | DTXSID5020607. https://comptox.epa.gov/dashboard/DTXSID5020607
4 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for di(2-ethylhexyl)phthalate (DEHP). Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service; 2019.
5 U.S. Environmental Protection Agency (USEPA). Chemical data reporting (2012 and 2016 public CDR database). Washington, DC: U.S. Environmental Protection Agency, Office of Pollution Prevention and Toxics; 2017.
6 Toxics Use Reduction Institute (TURI). Five chemicals alternatives reduction study. Final report. Chapter 7. DEHP. Lowell, MA: The Massachusetts Toxics Use Reduction Institute, University of Massachusetts Lowell; 2005. https://www.turi.org/TURI_Publications/TURI_Methods_Policy_Reports/Five_Chemicals_Alternatives_Assessment_Study._2006
7 European Commission (EC). Bis(2-ethylhexyl)phthalate (DEHP) – Summary risk assessment report. Ispra (VA), Italy: European Chemicals Bureau, Institute for Health and Consumer Protection, Toxicology and Chemical Substance (TCS); 2008. EUR 23384EN/2.
8 Latini G, Ferri M, Chiellini F. Materials degradation in PVC medical devices, DEHP leaching and neonatal outcomes. Curr Med Chem. 2010; 17(26):2979–2989. 10.2174/092986710792064992 20858177
9 Bouattour Y, Wasiak M, Bernard L, Pinguet J, Richard D, Le Rouzo-Grèves M, Dhifallah I, Lambert C, Pereira B, Chennell P, et al. Quantification of bis(2-ethylhexyl) phthalate released by medical devices during respiratory assistance and estimation of patient exposure. Chemosphere. 2020; 255:126978. 10.1016/j.chemosphere.2020.126978 32417514
10 International Programme on Chemical Safety (IPCS). Environmental Health Criteria 131: Diethylhexyl phthalate. 1992.
11 Serrano SE, Braun J, Trasande L, Dills R, Sathyanarayana S. Phthalates and diet: A review of the food monitoring and epidemiology data. Environ Health. 2014; 13(1):43. 10.1186/1476-069X-13-43 24894065
12 Clark K, Cousins IT, Mackay D. Assessment of critical exposure pathways. In: Staples CA, editor. The Handbook of Environmental Chemistry. New York: Springer-Verlag; 2003. p. 227–262.
13 National Toxicology Program (NTP). NTP-CERHR monograph on the potential human reproductive and developmental effects of di (2-ethylhexyl) phthalate (DEHP). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2006.
14 Fromme H, Lahrz T, Piloty M, Gebhart H, Oddoy A, Ruden H. Occurrence of phthalates and musk fragrances in indoor air and dust from apartments and kindergartens in Berlin (Germany). Indoor Air. 2004; 14(3):188–195. 10.1111/j.1600-0668.2004.00223.x 15104786
15 Centers for Disease Control and Prevention (CDC). Fourth national report on human exposure to environmental chemicals. Updated tables, January 2019, volume one. Atlanta, GA: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention; 2019. https://www.cdc.gov/exposurereport/pdf/FourthReport_UpdatedTables_Volume1_Jan2019-508.pdf
16 Wambaugh JF, Wang A, Dionisio KL, Frame A, Egeghy P, Judson R, Setzer RW. High throughput heuristics for prioritizing human exposure to environmental chemicals. Environ Sci Technol. 2014; 48(21):12760–12767. 10.1021/es503583j 25343693
17 Dirven HA, van den Broek PH, Arends AM, Nordkamp HH, de Lepper AJ, Henderson PT, Jongeneelen FJ. Metabolites of the plasticizer di(2-ethylhexyl)phthalate in urine samples of workers in polyvinylchloride processing industries. Int Arch Occup Environ Health. 1993; 64(8):549–554. 10.1007/BF00517699 8314612
18 Nielsen J, Akesson B, Skerfving S. Phthalate ester exposure—air levels and health of workers processing polyvinylchloride. Am Ind Hyg Assoc J. 1985; 46(11):643–647. 10.1080/15298668591395463 4072908
19 Hines CJ, Hopf NBN, Deddens JA, Silva MJ, Calafat AM. Estimated daily intake of phthalates in occupationally exposed groups. J Expo Sci Environ Epidemiol. 2011; 21(2):133–141. 10.1038/jes.2009.62 20010977
20 Hines CJ, Nilsen Hopf NB, Deddens JA, Calafat AM, Silva MJ, Grote AA, Sammons DL. Urinary phthalate metabolite concentrations among workers in selected industries: A pilot biomonitoring study. Ann Occup Hyg. 2009; 53(1):1–17. 18948546
21 Fong JP, Lee FJ, Lu IS, Uang SN, Lee CC. Estimating the contribution of inhalation exposure to di-2-ethylhexyl phthalate (DEHP) for PVC production workers, using personal air sampling and urinary metabolite monitoring. Int J Hyg Environ Health. 2014; 217(1):102–109. 10.1016/j.ijheh.2013.04.002 23665067
22 Wang W, Xu X, Fan CQ. Health hazard assessment of occupationally di-(2-ethylhexyl)-phthalate-exposed workers in China. Chemosphere. 2015; 120:37–44. 10.1016/j.chemosphere.2014.05.053 24974312
23 Ginsberg G, Ginsberg J, Foos B. Approaches to children’s exposure assessment: Case study with diethylhexylphthalate (DEHP). Int J Environ Res Public Health. 2016; 13(7). 10.3390/ijerph13070670 27376320
24 Zhu J, Phillips SP, Feng YL, Yang X. Phthalate esters in human milk: Concentration variations over a 6-month postpartum time. Environ Sci Technol. 2006; 40(17):5276–5281. 10.1021/es060356w 16999099
25 Swedish National Chemicals Inspectorate (KEMI). Risk Assessment - bis(2-ethylhexyl) phthalate (CAS-No.: 117-81-7). 2000.
26 Silva MJ, Reidy JA, Herbert AR, Preau JL Jr, Needham LL, Calafat AM. Detection of phthalate metabolites in human amniotic fluid. Bull Environ Contam Toxicol. 2004; 72(6):1226–1231. 10.1007/s00128-004-0374-4 15362453
27 U.S. Food and Drug Administration (FDA). Safety assessment of di(2-ethylhexyl)phthalate (DEHP) released from PVC medical devices. Rockville, MD; 2001.
28 Den Braver-Sewradj SP, Piersma A, Hessel EVS. An update on the hazard of and exposure to diethyl hexyl phthalate (DEHP) alternatives used in medical devices. Crit Rev Toxicol. 2020; 50(8):650–672. 10.1080/10408444.2020.1816896 33006299
29 Tickner JA, Schettler T, Guidotti T, McCally M, Rossi M. Health risks posed by use of Di-2-ethylhexyl phthalate (DEHP) in PVC medical devices: A critical review. Am J Ind Med. 2001; 39(1):100–111. 10.1002/1097-0274(200101)39:1<100::aid-ajim10>3.0.co;2-q
30 110th U.S. Congress. Consumer Product Safety Improvement Act of 2008. 2008.
31 Code of Federal Regulations (CFR). 2017; 17(Part 1307).
32 Code of Federal Regulations (CFR). 2001; 21(Part 177, Subpart B, Section 177.1010).
33 Code of Federal Regulations (CFR). 2001; 21(Part 177, Subpart B, Section 177.1200).
34 Carpenter CP, Weil CS, Smyth HF Jr. Chronic oral toxicity of di-(2-ethylhexyl) phthalate of rats, guinea pigs, and dogs. AMA Arch Ind Hyg Occup Med. 1953; 8(3):219–226. 13079323
35 U.S. Environmental Protection Agency (USEPA). Integrated Risk Information System (IRIS), chemical assessment summary, di(2-ethylhexyl)phthalate; CASRN 117-81-7. Washington D.C.: U.S. Environmental Protection Agency, National Center for Environmental Assessment; 1987. https://cfpub.epa.gov/ncea/iris/iris_documents/documents/subst/0014_summary.pdf#nameddest=rfd
36 U.S. Environmental Protection Agency (USEPA). National Primary Drinking Water Regulations: Phthalate, di(2-Ethylhexyl). Washington, D.C.: Office of Water; 1995.
37 Occupational Safety and Health Administration (OSHA). Recommendations for consideration by the U.S. Secretary of Labor on the Adoption and use of occupational exposure limits by federal agencies. Occupational Safety and Health Administration, Federal Advisory Council on Occupational Safety and Health; 2012. https://www.osha.gov/dep/facosh/Exhibit_9b.pdf
38 Lake BG, Gray TJ, Foster JR, Stubberfield CR, Gangolli SD. Comparative studies on di-(2-ethylhexyl) phthalate-induced hepatic peroxisome proliferation in the rat and hamster. Toxicol Appl Pharmacol. 1984; 72(1):46–60. 10.1016/0041-008X(84)90248-5 6710484
39 Albro PW. Absorption, metabolism, and excretion of di(2-ethylhexyl) phthalate by rats and mice. Environ Health Perspect. 1986; 65:293–298. 3086077
40 Albro PW, Corbett JT, Schroeder JL, Jordan S, Matthews HB. Pharmacokinetics, interactions with macromolecules and species differences in metabolism of DEHP. Environ Health Perspect. 1982; 45:19–25. 10.1289/ehp.824519 7140694
41 Rhodes C, Orton TC, Pratt IS, Batten PL, Bratt H, Jackson SJ, Elcombe CR. Comparative pharmacokinetics and subacute toxicity of di(2-ethylhexyl) phthalate (DEHP) in rats and marmosets: Extrapolation of effects in rodents to man. Environ Health Perspect. 1986; 65:299–307. 3086078
42 Pollack GM, Li RC, Ermer JC, Shen DD. Effects of route of administration and repetitive dosing on the disposition kinetics of di(2-ethylhexyl) phthalate and its mono-de-esterified metabolite in rats. Toxicol Appl Pharmacol. 1985; 79(2):246–256. 10.1016/0041-008X(85)90346-1 4002226
43 Daniel JW, Bratt H. The absorption, metabolism and tissue distribution of di(2-ethylhexyl)phthalate in rats. Toxicology. 1974; 2(1):51–65. 10.1016/0300-483X(74)90042-0 4823738
44 Elsisi AE, Carter DE, Sipes IG. Dermal absorption of phthalate diesters in rats. Fundam Appl Toxicol. 1989; 12(1):70–77. 10.1016/0272-0590(89)90063-8 2925020
45 Tanaka A, Adachi T, Takahashi T, Yamaha T. Biochemical studies on phthalic esters I. Elimination, distribution and metabolism of di-(2-ethylhexyl)phthalate in rats. Toxicology. 1975; 4(2):253–264. 10.1016/0300-483X(75)90105-5 1154425
46 Ikeda GJ, Sapienza PP, Couvillion JL, Farber TM, van Loon EJ. Comparative distribution, excretion and metabolism of di-(2-ethylhexyl) phthalate in rats, dogs and miniature pigs. Food Cosmet Toxicol. 1980; 18(6):637–642. 10.1016/S0015-6264(80)80012-5 7203310
47 Chu I, Villeneuve DC, Secours V, Franklin C, Rock G, Viau A. Metabolism and tissue distribution of mono-2-ethylhexyl phthalate in the rat. Drug Metab Dispos. 1978; 6(2):146–149. 26529
48 Lindgren A, Lindquist NG, Lyden A, Olsson T, Ullberg S. A whole body autoradiographic study on the distribution of 14C-labelled di-(2-ethylhexyl)phthalate in mice. Toxicology. 1982; 23(2-3):149–158. 10.1016/0300-483X(82)90094-4 6810506
49 Oishi S. Effects of phthalic acid esters on testicular mitochondrial functions in the rat. Arch Toxicol. 1990; 64(2):143–147. 10.1007/BF01974400 2350233
50 Sjöberg P, Bondesson U, Kjellen L, Lindquist NG, Montin G, Ploen L. Kinetics of di-(2-ethylhexyl) phthalate in immature and mature rats and effect on testis. Acta Pharmacol Toxicol (Copenh). 1985; 56(1):30–37. 10.1111/j.1600-0773.1985.tb01249.x 3976401
51 Teirlynck OA, Belpaire F. Disposition of orally administered di-(2-ethylhexyl) phthalate and mono-(2-ethylhexyl) phthalate in the rat. Arch Toxicol. 1985; 57(4):226–230. 10.1007/BF00324782 4091646
52 Singh AR, Lawrence WH, Autian J. Maternal-fetal transfer of 14C-di-2-ethylhexyl phthalate and 14C-diethyl phthalate in rats. J Pharm Sci. 1975; 64(8):1347–1350. 10.1002/jps.2600640819 1151708
53 Srivastava S, Awasthi VK, Srivastava SP, Seth PK. Biochemical alterations in rat fetal liver following in utero exposure to di(2-ethylhexyl)phthalate (DEHP). Indian J Exp Biol. 1989; 27(10):885–888. 2635147
54 Dostal LA, Weaver RP, Schwetz BA. Transfer of di(2-ethylhexyl) phthalate through rat milk and effects on milk composition and the mammary gland. Toxicol Appl Pharmacol. 1987; 91(3):315–325. 10.1016/0041-008X(87)90054-8 2892284
55 Sjöberg P, Lindqvist NG, Ploen L. Age-dependent response of the rat testes to di(2-ethylhexyl) phthalate. Environ Health Perspect. 1986; 65:237–242. 3709447
56 Egestad B, Green G, Sjöberg P, Klasson-Wehler E, Gustafsson J. Chromatographic fractionation and analysis by mass spectrometry of conjugated metabolites of bis(2-ethylhexyl)phthalate in urine. J Chromatogr B Biomed Appl. 1996; 677(1):99–109. 10.1016/0378-4347(95)00439-4 8925107
57 Egestad B, Sjöberg P. Glucosidation as a new conjugation pathway for metabolites of bis(2-ethylhexyl) phthalate. Drug Metab Dispos. 1992; 20(3):470–472. 1355727
58 Peck CC, Albro PW. Toxic potential of the plasticizer di(2-ethylhexyl) phthalate in the context of its disposition and metabolism in primates and man. Environ Health Perspect. 1982; 45:11–17. 10.1289/ehp.824511 7140682
59 Koch HM, Bolt HM, Di Angerer J. (2-ethylhexyl)phthalate (DEHP) metabolites in human urine and serum after a single oral dose of deuterium-labelled DEHP. Arch Toxicol. 2004; 78(3):123–130. 10.1007/s00204-003-0522-3 14576974
60 Koch HM, Bolt HM, Preuss R, Angerer J. New metabolites of di(2-ethylhexyl)phthalate (DEHP) in human urine and serum after single oral doses of deuterium-labelled DEHP. Arch Toxicol. 2005; 79(7):367–376. 10.1007/s00204-004-0642-4 15700144
61 Silva MJ, Samandar E, Preau JL Jr, Needham LL, Calafat AM. Urinary oxidative metabolites of di(2-ethylhexyl) phthalate in humans. Toxicology. 2006; 219(1-3):22–32. 10.1016/j.tox.2005.10.018 16332407
62 Kato K, Silva MJ, Reidy JA, Hurtz D 3rd, Malek NA, Needham LL, Nakazawa H, Barr DB, Calafat AM. Mono(2-ethyl-5-hydroxyhexyl) phthalate and mono-(2-ethyl-5-oxohexyl) phthalate as biomarkers for human exposure assessment to di-(2-ethylhexyl) phthalate. Environ Health Perspect. 2004; 112(3):327–330. 10.1289/ehp.6663 14998748
63 U.S. Consumer Product Safety Commission (CPSC). Toxicity review of DEHP. 2010. https://www.cpsc.gov/s3fs-public/ToxicityReviewOfDEHP.pdf
64 Shaffer CB, Carpenter CP, Smyth HF Jr. Acute and subacute toxicity of di(2-ethylhexyl) phthalate with note upon its metabolism. J Ind Hyg Toxicol. 1945; 27(5):130–135.
65 Shibko SI, Blumenthal H. Toxicology of phthalic acid esters used in food-packaging material. Environ Health Perspect. 1973; 3:131–137. 10.1289/ehp.7303131 4704561
66 Lawrence WH, Malik M, Turner JE, Singh AR, Autian J. A toxicological investigation of some acute, short-term, and chronic effects of administering di-2-ethylhexyl phthalate (DEHP) and other phthalate esters. Environ Res. 1975; 9(1):1–11. 10.1016/0013-9351(75)90043-2 1122902
67 Krauskopf LG. Studies on the toxicity of phthalates via ingestion. Environ Health Perspect. 1973; 3:61–72. 10.1289/ehp.730361 4735798
68 Dostal LA, Jenkins WL, Schwetz BA. Hepatic peroxisome proliferation and hypolipidemic effects of di(2-ethylhexyl)phthalate in neonatal and adult rats. Toxicol Appl Pharmacol. 1987; 87(1):81–90. 10.1016/0041-008X(87)90086-X 3798454
69 National Toxicology Program (NTP). NTP technical report on the carcinogenesis bioassay of di(2-ethylhexyl)phthalate (CAS No. 117-81-7) in F344 rats and B6C3F1 mice (feed study). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 1982. NTP Technical Report No. 217. https://ntp.niehs.nih.gov/publications/reports/tr/200s/tr217/index.html?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tr217abs
70 Crocker JF, Safe SH, Acott P. Effects of chronic phthalate exposure on the kidney. J Toxicol Environ Health. 1988; 23(4):433–444. 10.1080/15287398809531126 3361614
71 Moore MR. Oncogenicity study in rats with di(2-ethylhexyl)phthalate including ancillary hepatocellular proliferation and biochemical analyses. Corning Hazleton Incorporated (CHV); 1996.
72 Moore MR. Oncogenicity study in mice with Di (2-ethylhexyl)phthalate including ancillary hepatocellular proliferation and biochemical analyses. Corning Hazleton Incorporated (CHV); 1997.
73 International Agency for Research on Cancer (IARC). Evaluation of Carcinogenic Risks to Humans: Some Industrial Chemicals. Lyon, France; 2000.
74 Ward JM, Peters JM, Perella CM, Gonzalez FJ. Receptor and nonreceptor-mediated organ-specific toxicity of di(2-ethylhexyl)phthalate (DEHP) in peroxisome proliferator-activated receptor alpha-null mice. Toxicol Pathol. 1998; 26(2):240–246. 10.1177/019262339802600208 9547862
75 Maloney EK, Waxman DJ. Trans-activation of PPARalpha and PPARgamma by structurally diverse environmental chemicals. Toxicol Appl Pharmacol. 1999; 161(2):209–218. 10.1006/taap.1999.8809 10581215
76 Dostal LA, Chapin RE, Stefanski SA, Harris MW, Schwetz BA. Testicular toxicity and reduced Sertoli cell numbers in neonatal rats by di(2-ethylhexyl)phthalate and the recovery of fertility as adults. Toxicol Appl Pharmacol. 1988; 95(1):104–121. 10.1016/S0041-008X(88)80012-7 3413790
77 Gray TJ, Butterworth KR. Testicular atrophy produced by phthalate esters. Arch Toxicol Suppl. 1980; 4:452–455. 10.1007/978-3-642-67729-8_106 6776936
78 Gray TJ, Gangolli SD. Aspects of the testicular toxicity of phthalate esters. Environ Health Perspect. 1986; 65:229–235. 3709446
79 Lamb JC 4th, Chapin RE, Teague J, Lawton AD, Reel JR. Reproductive effects of four phthalic acid esters in the mouse. Toxicol Appl Pharmacol. 1987; 88(2):255–269. 10.1016/0041-008X(87)90011-1 3564043
80 Parmar D, Srivastava SP, Singh GB, Seth PK. Testicular toxicity of Di(2-ethylhexyl)phthalate in developing rats. Vet Hum Toxicol. 1995; 37(4):310–313. 8540215
81 Poon R, Lecavalier P, Mueller R, Valli VE, Procter BG, Chu I. Subchronic oral toxicity of di-n-octyl phthalate and di(2-Ethylhexyl) phthalate in the rat. Food Chem Toxicol. 1997; 35(2):225–239. 10.1016/S0278-6915(96)00064-6 9146736
82 Sjöberg P, Bondesson U, Gray TJ, Ploen L. Effects of di-(2-ethylhexyl) phthalate and five of its metabolites on rat testis in vivo and in in vitro. Acta Pharmacol Toxicol (Copenh). 1986; 58(3):225–233. 10.1111/j.1600-0773.1986.tb00098.x 3716815
83 Chapin RE, Gray TJ, Phelps JL, Dutton SL. The effects of mono-(2-ethylhexyl)-phthalate on rat Sertoli cell-enriched primary cultures. Toxicol Appl Pharmacol. 1988; 92(3):467–479. 10.1016/0041-008X(88)90186-X 3353991
84 Svechnikov K, Svechnikova I, Söder O. Inhibitory effects of mono-ethylhexyl phthalate on steroidogenesis in immature and adult rat Leydig cells in vitro. Reprod Toxicol. 2008; 25(4):485–490. 10.1016/j.reprotox.2008.05.057 18583092
85 Parmar D, Srivastava SP, Singh GB, Seth PK. Effect of testosterone on the testicular atrophy caused by di(2-ethylhexyl)phthalate (DEHP). Toxicol Lett. 1987; 36(3):297–308. 10.1016/0378-4274(87)90199-8 2884757
86 David RM, Moore MR, Finney DC, Guest D. Chronic toxicity of di(2-ethylhexyl)phthalate in rats. Toxicol Sci. 2000; 55(2):433–443. 10.1093/toxsci/55.2.433 10828276
87 Pugh G Jr, Isenberg JS, Kamendulis LM, Ackley DC, Clare LJ, Brown R, Lington AW, Smith JH, Klaunig JE. Effects of di-isononyl phthalate, di-2-ethylhexyl phthalate, and clofibrate in cynomolgus monkeys. Toxicol Sci. 2000; 56(1):181–188. 10.1093/toxsci/56.1.181 10869467
88 Davis BJ, Maronpot RR, Heindel JJ. Di-(2-ethylhexyl) phthalate suppresses estradiol and ovulation in cycling rats. Toxicol Appl Pharmacol. 1994; 128(2):216–223. 10.1006/taap.1994.1200 7940536
89 Ritter EJ, Scott WJ Jr, Randall JL, Ritter JM. Teratogenicity of di(2-ethylhexyl) phthalate, 2-ethylhexanol, 2-ethylhexanoic acid, and valproic acid, and potentiation by caffeine. Teratology. 1987; 35(1):41–46. 10.1002/tera.1420350107 3105103
90 Tyl RW, Price CJ, Marr MC, Kimmel CA. Developmental toxicity evaluation of dietary di(2-ethylhexyl)phthalate in Fischer 344 rats and CD-1 mice. Fundam Appl Toxicol. 1988; 10(3):395–412. 10.1016/0272-0590(88)90286-2 3371580
91 George F, Wilson J. Gonads and ducts in mammals. In: The Physiology of Reproduction. 1994. p. 3–28.
92 Byskov AG, Hoyer PE. Embryology of mammalian gonads and ducts. In: Knobil E, Neill JD, editors. The Physiology of Reproduction. New York: Raven Press; 1994. p. 487–539.
93 Parks LG, Ostby JS, Lambright CR, Abbott BD, Klinefelter GR, Barlow NJ, Gray LE Jr. The plasticizer diethylhexyl phthalate induces malformations by decreasing fetal testosterone synthesis during sexual differentiation in the male rat. Toxicol Sci. 2000; 58(2):339–349. 10.1093/toxsci/58.2.339 11099646
94 Kay VR, Bloom MS, Foster WG. Reproductive and developmental effects of phthalate diesters in males. Crit Rev Toxicol. 2014; 44(6):467–498. 10.3109/10408444.2013.875983 24903855
95 Gray LE Jr, Ostby J, Furr J, Price M, Veeramachaneni DN, Parks L. Perinatal exposure to the phthalates DEHP, BBP, and DINP, but not DEP, DMP, or DOTP, alters sexual differentiation of the male rat. Toxicol Sci. 2000; 58(2):350–365. 10.1093/toxsci/58.2.350 11099647
96 Wolf C, Lambright C, Mann P, Price M, Cooper RL, Ostby J, Gray LE Jr. Administration of potentially antiandrogenic pesticides (procymidone, linuron, iprodione, chlozolinate, p, p′-DDE, and ketoconazole) and toxic substances (dibutyl-and diethylhexyl phthalate, PCB 169, and ethane dimethane sulphonate) during sexual differentiation produces diverse profiles of reproductive malformations in the male rat. Toxicol Ind Health. 1999; 15(1-2):94–118. 10.1177/074823379901500109 10188194
97 Foster PM, Mylchreest E, Gaido KW, Sar M. Effects of phthalate esters on the developing reproductive tract of male rats. Hum Reprod Update. 2001; 7(3):231–235. 10.1093/humupd/7.3.231 11392369
98 Arcadi FA, Costa C, Imperatore C, Marchese A, Rapisarda A, Salemi M, Trimarchi GR, Costa G. Oral toxicity of bis(2-ethylhexyl) phthalate during pregnancy and suckling in the Long-Evans rat. Food Chem Toxicol. 1998; 36(11):963–970. 10.1016/S0278-6915(98)00065-9 9771559
99 Foster PM. Disruption of reproductive development in male rat offspring following in utero exposure to phthalate esters. Int J Androl. 2006; 29(1):140–147, discussion 181–145. 10.1111/j.1365-2605.2005.00563.x 16102138
100 National Toxicology Program (NTP). Diethylhexylphthalate: Multigenerational reproductive assessment by continuous breeding when administered to Sprague-Dawley rats in the diet. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2004.
101 Duty SM, Calafat AM, Silva MJ, Brock JW, Ryan L, Chen Z, Overstreet J, Hauser R. The relationship between environmental exposure to phthalates and computer-aided sperm analysis motion parameters. J Androl. 2004; 25(2):293–302. 10.1002/j.1939-4640.2004.tb02790.x 14760016
102 Duty SM, Calafat AM, Silva MJ, Ryan L, Hauser R. Phthalate exposure and reproductive hormones in adult men. Hum Reprod. 2005; 20(3):604–610. 10.1093/humrep/deh656 15591081
103 Duty SM, Silva MJ, Barr DB, Brock JW, Ryan L, Chen Z, Herrick RF, Christiani DC, Hauser R. Phthalate exposure and human semen parameters. Epidemiology. 2003; 14(3):269–277. 10.1097/01.EDE.0000059950.11836.16 12859026
104 Duty SM, Singh NP, Silva MJ, Barr DB, Brock JW, Ryan L, Herrick RF, Christiani DC, Hauser R. The relationship between environmental exposures to phthalates and DNA damage in human sperm using the neutral comet assay. Environ Health Perspect. 2003; 111(9):1164–1169. 10.1289/ehp.5756 12842768
105 Hauser R, Williams P, Altshul L, Calafat AM. Evidence of interaction between polychlorinated biphenyls and phthalates in relation to human sperm motility. Environ Health Perspect. 2005; 113(4):425–430. 10.1289/ehp.7305 15811833
106 Swan SH. Environmental phthalate exposure in relation to reproductive outcomes and other health endpoints in humans. Environ Res. 2008; 108(2):177–184. 10.1016/j.envres.2008.08.007 18949837
107 Swan SH, Main KM, Liu F, Stewart SL, Kruse RL, Calafat AM, Mao CS, Redmon JB, Ternand CL, Sullivan S, et al. Decrease in anogenital distance among male infants with prenatal phthalate exposure. Environ Health Perspect. 2005; 113(8):1056–1061. 10.1289/ehp.8100 16079079
108 Sharpe RM, Skakkebaek NE. Testicular dysgenesis syndrome: Mechanistic insights and potential new downstream effects. Fertil Steril. 2008; 89(2 Suppl):e33–e38. 10.1016/j.fertnstert.2007.12.026 18308057
109 Skakkebæk NE, Rajpert-De Meyts E, Main KM. Testicular dysgenesis syndrome: An increasingly common developmental disorder with environmental aspects. Hum Reprod. 2001; 16(5):972–978. 10.1093/humrep/16.5.972 11331648
110 Larsen ST, Hansen JS, Thygesen P, Begtrup M, Poulsen OM, Nielsen GD. Adjuvant and immuno-suppressive effect of six monophthalates in a subcutaneous injection model with BALB/c mice. Toxicology. 2001; 169(1):37–51. 10.1016/S0300-483X(01)00484-X 11696408
111 Badr MZ, Shnyra A, Zoubine M, Norkin M, Herndon B, Quinn T, Miranda RN, Cunningham ML, Molteni A. Phthalate-induced liver protection against deleterious effects of the Th1 response: A potentially serious health hazard. PPAR Res. 2007; 2007:49671. 10.1155/2007/49671 18566640
112 Larsen ST, Nielsen GD. The adjuvant effect of di-(2-ethylhexyl) phthalate is mediated through a PPARalpha-independent mechanism. Toxicol Lett. 2007; 170(3):223–228. 10.1016/j.toxlet.2007.03.009 17462839
113 Tonk EC, Verhoef A, Gremmer ER, van Loveren H, Piersma AH. Relative sensitivity of developmental and immune parameters in juvenile versus adult male rats after exposure to di(2-ethylhexyl) phthalate. Toxicol Appl Pharmacol. 2012; 260(1):48–57. 10.1016/j.taap.2012.01.018 22310177
114 Piepenbrink MS, Hussain I, Marsh JA, Dietert RR. Developmental immunotoxicology of di-(2-ethylhexyl)phthalate (DEHP): Age-based assessment in the female rat. J Immunotoxicol. 2005; 2(1):21–31. 10.1080/15363750490429435 18958656
115 Butala JH, David RM, Gans G, McKee RH, Guo TL, Peachee VL, White KL Jr. Phthalate treatment does not influence levels of IgE or Th2 cytokines in B6C3F1 mice. Toxicology. 2004; 201(1-3):77–85. 10.1016/j.tox.2004.04.004 15297022
116 Hansen JS, Larsen ST, Poulsen LK, Nielsen GD. Adjuvant effects of inhaled mono-2-ethylhexyl phthalate in BALB/cJ mice. Toxicology. 2007; 232(1-2):79–88. 10.1016/j.tox.2006.12.011 17241728
117 Larsen ST, Hansen JS, Hammer M, Alarie Y, Nielsen GD. Effects of mono-2-ethylhexyl phthalate on the respiratory tract in BALB/c mice. Hum Exp Toxicol. 2004; 23(11):537–545. 10.1191/0960327104ht486oa 15625780
118 Jaakkola JJ, Knight TL. The role of exposure to phthalates from polyvinyl chloride products in the development of asthma and allergies: A systematic review and meta-analysis. Environ Health Perspect. 2008; 116(7):845–853. 10.1289/ehp.10846 18629304
119 Nielsen J, Fahraeus C, Bensryd I, Akesson B, Welinder H, Linden K, Skerfving S. Small airways function in workers processing polyvinylchloride. Int Arch Occup Environ Health. 1989; 61(7):427–430. 10.1007/BF00386474 2777385
120 Jaakkola JJ, Ieromnimon A, Jaakkola MS. Interior surface materials and asthma in adults: A population-based incident case-control study. Am J Epidemiol. 2006; 164(8):742–749. 10.1093/aje/kwj249 16877535
121 Bornehag CG, Sundell J, Weschler CJ, Sigsgaard T, Lundgren B, Hasselgren M, Hagerhed-Engman L. The association between asthma and allergic symptoms in children and phthalates in house dust: A nested case-control study. Environ Health Perspect. 2004; 112(14):1393–1397. 10.1289/ehp.7187 15471731
122 Kolarik B, Naydenov K, Larsson M, Bornehag CG, Sundell J. The association between phthalates in dust and allergic diseases among Bulgarian children. Environ Health Perspect. 2008; 116(1):98–103. 10.1289/ehp.10498 18197306
123 Kluwe WM, McConnell EE, Huff JE, Haseman JK, Douglas JF, Hartwell WV. Carcinogenicity testing of phthalate esters and related compounds by the National Toxicology Program and the National Cancer Institute. Environ Health Perspect. 1982; 45:129–133. 10.1289/ehp.8245129 7140685
124 David RM, Moore MR, Cifone MA, Finney DC, Guest D. Chronic peroxisome proliferation and hepatomegaly associated with the hepatocellular tumorigenesis of di(2-ethylhexyl)phthalate and the effects of recovery. Toxicol Sci. 1999; 50(2):195–205. 10.1093/toxsci/50.2.195 10478855
125 David RM, Moore MR, Finney DC, Guest D. Chronic toxicity of di(2-ethylhexyl)phthalate in mice. Toxicol Sci. 2000; 58(2):377–385. 10.1093/toxsci/58.2.377 11099649
126 Voss C, Zerban H, Bannasch P, Berger MR. Lifelong exposure to di-(2-ethylhexyl)-phthalate induces tumors in liver and testes of Sprague-Dawley rats. Toxicology. 2005; 206(3):359–371. 10.1016/j.tox.2004.07.016 15588926
127 Klaunig JE, Babich MA, Baetcke KP, Cook JC, Corton JC, David RM, DeLuca JG, Lai DY, McKee RH, Peters JM, et al. PPARalpha agonist-induced rodent tumors: Modes of action and human relevance. Crit Rev Toxicol. 2003; 33(6):655–780. 10.1080/713608372 14727734
128 National Toxicology Program (NTP). Report on Carcinogens, Fourteenth Edition. Research Triangle Park: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2016. https://ntp.niehs.nih.gov/go/roc14
129 Grosse Y, Baan R, Secretan-Lauby B, El Ghissassi F, Bouvard V, Benbrahim-Tallaa L, Guha N, Islami F, Galichet L, Straif K, et al. Carcinogenicity of chemicals in industrial and consumer products, food contaminants and flavourings, and water chlorination byproducts. Lancet Oncol. 2011; 12(4):328–329. 10.1016/S1470-2045(11)70088-2 21598447
130 Ito Y, Yamanoshita O, Asaeda N, Tagawa Y, Lee CH, Aoyama T, Ichihara G, Furuhashi K, Kamijima M, Gonzalez FJ, et al. Di(2-ethylhexyl)phthalate induces hepatic tumorigenesis through a peroxisome proliferator-activated receptor alpha-independent pathway. J Occup Health. 2007; 49(3):172–182. 10.1539/joh.49.172 17575397
131 Morimura K, Cheung C, Ward JM, Reddy JK, Gonzalez FJ. Differential susceptibility of mice humanized for peroxisome proliferator-activated receptor alpha to Wy-14,643-induced liver tumorigenesis. Carcinogenesis. 2006; 27(5):1074–1080. 10.1093/carcin/bgi329 16377806
132 Yang Q, Ito S, Gonzalez FJ. Hepatocyte-restricted constitutive activation of PPAR alpha induces hepatoproliferation but not hepatocarcinogenesis. Carcinogenesis. 2007; 28(6):1171–1177. 10.1093/carcin/bgm046 17331954
133 López-Carrillo L, Hernández-Ramírez RU, Calafat AM, Torres-Sánchez L, Galván-Portillo M, Needham LL, Ruiz-Ramos R, Cebrián ME. Exposure to phthalates and breast cancer risk in northern Mexico. Environ Health Perspect. 2010; 118(4):539–544. 10.1289/ehp.0901091 20368132
134 Hagmar L, Akesson B, Nielsen J, Andersson C, Lindén K, Attewell R, Möller T. Mortality and cancer morbidity in workers exposed to low levels of vinyl chloride monomer at a polyvinyl chloride processing plant. Am J Ind Med. 1990; 17(5):553–565. 10.1002/ajim.4700170502 2337081
135 Hardell L, Ohlson CG, Fredrikson M. Occupational exposure to polyvinyl chloride as a risk factor for testicular cancer evaluated in a case-control study. Int J Cancer. 1997; 73(6):828–830. 10.1002/(sici)1097-0215(19971210)73:6<828::aid-ijc10>3.0.co;2-0
136 Ohlson CG, Hardell L. Testicular cancer and occupational exposures with a focus on xenoestrogens in polyvinyl chloride plastics. Chemosphere. 2000; 40(9-11):1277–1282. 10.1016/S0045-6535(99)00380-X 10739073
137 Hansen J. Risk for testicular cancer after occupational exposure to plastics. Int J Cancer. 1999; 82(6):911–912. 10.1002/(sici)1097-0215(19990909)82:6%3c911::aid-ijc23%3e3.0.co;2-o
138 Hardell L, Malmqvist N, Ohlson CG, Westberg H, Eriksson M. Testicular cancer and occupational exposure to polyvinyl chloride plastics: A case-control study. Int J Cancer. 2004; 109(3):425–429. 10.1002/ijc.11709 14961582
139 Westberg HB, Hardell LO, Malmqvist N, Ohlson CG, Axelson O. On the use of different measures of exposure-experiences from a case-control study on testicular cancer and PVC exposure. J Occup Environ Hyg. 2005; 2(7):351–356. 10.1080/15459620590969046 16020098
140 Selenskas S, Teta MJ, Vitale JN. Pancreatic cancer among workers processing synthetic resins. Am J Ind Med. 1995; 28(3):385–398. 10.1002/ajim.4700280308 7485192
141 Huber WW, Grasl-Kraupp B, Schulte-Hermann R. Hepatocarcinogenic potential of di(2-ethylhexyl)phthalate in rodents and its implications on human risk. Crit Rev Toxicol. 1996; 26(4):365–481. 10.3109/10408449609048302 8817083
142 International Agency for Research on Cancer (IARC). IARC monographs on the evaluation of the carcinogenic risk of chemicals to humans. Some industrial chemicals and dyestuffs. Lyon, France; 1982.
143 Caldwell JC. DEHP: Genotoxicity and potential carcinogenic mechanisms—A review. Mutat Res. 2012; 751(2):82–157. 10.1016/j.mrrev.2012.03.001 22484601
144 Tomita I, Nakamura Y, Aoki N, Inui N. Mutagenic/carcinogenic potential of DEHP and MEHP. Environ Health Perspect. 1982; 45:119–125. 10.1289/ehp.8245119 6814903
145 Chang YJ, Tseng CY, Lin PY, Chuang YC, Chao MW. Acute exposure to DEHP metabolite, MEHP cause genotoxicity, mutagenesis and carcinogenicity in mammalian Chinese hamster ovary cells. Carcinogenesis. 2017; 38(3):336–345. 10.1093/carcin/bgx009 28426879
146 Erkekoglu P, Rachidi W, Yuzugullu OG, Giray B, Favier A, Ozturk M, Hincal F. Evaluation of cytotoxicity and oxidative DNA damaging effects of di(2-ethylhexyl)-phthalate (DEHP) and mono(2-ethylhexyl)-phthalate (MEHP) on MA-10 Leydig cells and protection by selenium. Toxicol Appl Pharmacol. 2010; 248(1):52–62. 10.1016/j.taap.2010.07.016 20659492
147 Erkekoğlu P, Rachidi W, De Rosa V, Giray B, Favier A, Hincal F. Protective effect of selenium supplementation on the genotoxicity of di(2-ethylhexyl)phthalate and mono(2-ethylhexyl)phthalate treatment in LNCaP cells. Free Radic Biol Med. 2010; 49(4):559–566. 10.1016/j.freeradbiomed.2010.04.038 20466057
148 Park SY, Choi J. Cytotoxicity, genotoxicity and ecotoxicity assay using human cell and environmental species for the screening of the risk from pollutant exposure. Environ Int. 2007; 33(6):817–822. 10.1016/j.envint.2007.03.014 17499852
149 Zeiger E, Haworth S, Mortelmans K, Speck W. Mutagenicity testing of di(2-ethylhexyl)phthalate and related chemicals in Salmonella. Environ Mutagen. 1985; 7(2):213–232. 10.1002/em.2860070209 3971959
150 Zeiger E, Haworth S. Tests with a preincubation modification of the Salmonella/microsome assay. In: Ashby J, de Serres FJ, editors. Progress in Mutation Research: Evaluation of short-term tests for carcinogens: Report of the International Programme on Chemical Safety’s Collaborative Study on In Vitro Assays. Elsevier. 1985. p. 187–199.
151 Myhr B, Bowers L, Caspary WJ. Assays for the induction of gene mutations at the thymidine kinase locus in L5178Y mouse lymphoma cells in culture. In: Ashby J, de Serres FJ, editors. Progress in Mutation Research: Evaluation of short-term tests for carcinogens: Report of the International Programme on Chemical Safety’s Collaborative Study on In Vitro Assays. Elsevier Science Publisher. 1985. p. 555–568.
152 Simon VF, Kauhanen K, Tardiff RG. Mutagenic activity of chemicals identified in drinking water In: Scott D, Bridges BA, Sobels FH, editors. Progress in Genetic Toxicology: Proceedings of the Second International Conference on Environmental Mutagens. Elsevier; 1977. p. 249–258.
153 Gulati DK, Witt K, Anderson B, Zeiger E, Shelby MD. Chromosome aberration and sister chromatid exchange tests in Chinese hamster ovary cells in vitro III: Results with 27 chemicals. Environ Mol Mutagen. 1989; 13(2):133–193. 10.1002/em.2850130208 2917552
154 Stenchever MA, Allen MA, Jerominski L, Petersen RV. Effects of bis(2-ethylhexyl) phthalate on chromosomes of human leukocytes and human fetal lung cells. J Pharm Sci. 1976; 65(11):1648–1651. 10.1002/jps.2600651121 993999
155 Abe S, Sasaki M. Chromosome aberrations and sister chromatid exchanges in Chinese hamster cells exposed to various chemicals. J Natl Cancer Inst. 1977; 58(6):1635–1641. 10.1093/jnci/58.6.1635 864744
156 Ishidate M Jr, Odashima S. Chromosome tests with 134 compounds on Chinese hamster cells in vitro—a screening for chemical carcinogens. Mutat Res. 1977; 48(3-4):337–353. 10.1016/0027-5107(77)90177-4 876270
157 Phillips BJ, James TEB, Gangoli SD. Genotoxicity studies of di(2-ethylhexyl)phthalate and its metabolites in CHO cells. Mutat Res. 1982; 102(3):297–304. 10.1016/0165-1218(82)90139-2 6890626
158 Yoon JS, Mason JM, Valencia R, Woodruff RC, Zimmering S. Chemical mutagenesis testing in Drosophila. IV. Results of 45 coded compounds tested for the National Toxicology Program. Environ Mutagen. 1985; 7(3):349–367. 10.1002/em.2860070310 3930235
159 Zimmering S, Mason JM, Valencia R. Chemical mutagenesis testing in Drosophila. VII. Results of 22 coded compounds tested in larval feeding experiments. Environ Mol Mutagen. 1989; 14(4):245–251. 10.1002/em.2850140406 2583131
160 Kitamoto S, Matsuyama R, Uematsu Y, Ogata K, Ota M, Yamada T, Miyata K, Kimura J, Funabashi H, Saito K. Genotoxicity evaluation of benzene, di(2-ethylhexyl) phthalate, and trisodium ethylenediamine tetraacetic acid monohydrate using a combined rat comet/micronucleus assays. Mutat Res Genet Toxicol Environ Mutagen. 2015; 786-788:137–143. 10.1016/j.mrgentox.2015.05.002 26212304
161 Akagi J-I, Toyoda T, Cho Y-M, Mizuta Y, Nohmi T, Nishikawa A, Ogawa K. Validation study of the combined repeated-dose toxicity and genotoxicity assay using gpt delta rats. Cancer Sci. 2015; 106(5):529–541. 10.1111/cas.12634 25683344
162 Kanki K, Nishikawa A, Masumura K, Umemura T, Imazawa T, Kitamura Y, Nohmi T, Hirose M. In vivo mutational analysis of liver DNA in gpt delta transgenic rats treated with the hepatocarcinogens N-nitrosopyrrolidine, 2-amino-3-methylimidazo[4,5-f]quinoline, and di(2-ethylhexyl)phthalate. Mol Carcinog. 2005; 42(1):9–17. 10.1002/mc.20061 15486947
163 Smith-Oliver T, Butterworth BE. Correlation of the carcinogenic potential of di(2-ethylhexyl)phthalate (DEHP) with induced hyperplasia rather than with genotoxic activity. Mutat Res. 1987; 188(1):21–28. 10.1016/0165-1218(87)90110-8 3574334
164 Singh AR, Lawrence WH, Autian J. Mutagenic and antifertility sensitivities of mice to di-2-ethylhexyl phthalate (DEHP) and dimethoxyethyl phthalate (DMEP). Toxicol Appl Pharmacol. 1974; 29(1):35–46. 10.1016/0041-008X(74)90159-8 4283679
165 Jäckh R, Rhodes C, Grasso P, Carter JT. Genotoxicity studies on di-(2-ethylhexyl) phthalate and adipate and toxicity studies on di-(2-ethylhexyl) phthalate in the rat and marmoset. Food Chem Toxicol. 1984; 22(2):151–155. 10.1016/0278-6915(84)90096-6 6421684
166 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
167 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
168 McConnell EE, Solleveld HA, Swenberg JA, Boorman GA. Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986; 76(2):283–289. 3456066
169 U.S. Environmental Protection Agency (USEPA). Benchmark Dose Software (BMDS). Version 3.1.2.; 2020. https://www.epa.gov/bmds
170 U.S. Environmental Protection Agency (USEPA). Benchmark dose software (BMDS) version 3.1.1. user guide EPA/600/R-18/310. July 2019. 2019.
171 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
172 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690. 10.1093/biomet/62.3.679
173 Cox DR. Regression models and life‐tables. J R Stat Soc Series B Stat Methodol. 1972; 34(2):187–202.
174 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
175 Piegorsch W, Bailer A. Statistics for Environmental Biology and Toxicology: Section 6.3.2. London, UK: Chapman and Hall; 1997.
176 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
177 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
178 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
179 Nam JM. A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987; 43(3):701–705. 10.2307/2532006 3663825
180 Rao JN, Scott AJ. A simple method for the analysis of clustered binary data. Biometrics. 1992; 48(2):577–585. 10.2307/2532311 1637980
181 Fung KY, Krewski D, Rao JN, Scott AJ. Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994; 14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
182 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
183 Dixon W, Massey F. Introduction to Statistical Analysis. New York, NY: McGraw Hill Book Company Inc; 1957. 10.2307/2332898
184 Tukey J. Easy summaries – numerical and graphical. Exploratory Data Analysis. Reading, MA: Addison-Wesley; 1977. p. 43–44.
185 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
186 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
187 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
188 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
189 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
190 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
191 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
192 Hsu JC. The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168. 10.1080/10618600.1992.10477011
193 Haseman JK. Data analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995; 21(1):52–59, discussion 81–56. 10.1006/rtph.1995.1009 7784636
194 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
195 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200. 10.1177/009286159202600210
196 Code of Federal Regulations (CFR). 21(Part 58).
197 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Cold Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
198 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67:233–241. 7021938
199 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA, Flamm WG, Lorentzen RJ, editors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing Co. Inc; 1985. p. 13–59.
200 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the US NTP. Mutat Res. 1991; 257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
201 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F(1) mice from short-term, prechronic, and chronic studies of the NTP carcinogenesis bioassay program. Environ Mol Mutagen. 2000; 36(3):163–194. 10.1002/1098-2280(2000)36:3<163::AID-EM1>3.0.CO;2-P 11044899
202 National Toxicology Program (NTP). TR-601: Technical report pathology tables and curves pathology tables, survival and growth curves from NTP long term, genetic toxicology, and bench mark dose analyses of neoplastic lesions studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2020. 10.22427/NTP-DATA-TR-601
203 Araki A, Mitsui T, Miyashita C, Nakajima T, Naito H, Ito S, Sasaki S, Cho K, Ikeno T, Nonomura K, et al. Association between maternal exposure to di(2-ethylhexyl) phthalate and reproductive hormone levels in fetal blood: The Hokkaido study on environment and children’s health. PLoS One. 2014; 9(10):e109039. 10.1371/journal.pone.0109039 25296284
204 Latini G, De Felice C, Presta G, Del Vecchio A, Paris I, Ruggieri F, Mazzeo P. Exposure to di(2-ethylhexyl)phthalate in humans during pregnancy. Biol Neonate. 2003; 83(1):22–24. 10.1159/000067012 12566679
205 Li X, Sun H, Yao Y, Zhao Z, Qin X, Duan Y, Wang L. Distribution of phthalate metabolites between paired maternal–fetal samples. Environ Sci Technol. 2018; 52(11):6626–6635. 10.1021/acs.est.8b00838 29754483
206 Mose T, Knudsen LE, Hedegaard M, Mortensen GK. Transplacental transfer of monomethyl phthalate and mono(2-ethylhexyl) phthalate in a human placenta perfusion system. Int J Toxicol. 2007; 26(3):221–229. 10.1080/10915810701352721 17564903
207 Dalgaard M, Østergaard G, Lam HR, Hansen EV, Ladefoged O. Toxicity study of di(2-ethylhexyl)phthalate (DEHP) in combination with acetone in rats. Pharmacol Toxicol. 2000; 86(2):92–100. 10.1034/j.1600-0773.2000.d01-17.x 10728921
208 Dalsenter PR, Santana GM, Grande SW, Andrade AJ, Araujo SL. Phthalate affect the reproductive function and sexual behavior of male Wistar rats. Hum Exp Toxicol. 2006; 25(6):297–303. 10.1191/0960327105ht624oa 16866186
209 Pocar P, Fiandanese N, Secchi C, Berrini A, Fischer B, Schmidt JS, Schaedlich K, Borromeo V. Exposure to di(2-ethyl-hexyl) phthalate (DEHP) in utero and during lactation causes long-term pituitary-gonadal axis disruption in male and female mouse offspring. Endocrinology. 2012; 153(2):937–948. 10.1210/en.2011-1450 22147016
210 National Toxicology Program (NTP). Diethylhexylphthalate: Multigenerational reproductive assessment by continuous breeding when administered to Sprague-Dawley rats in the diet. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2005. PB2005107575.
211 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of perfluorooctanoic acid (CASRN 335-67-1) administered in feed to Sprague Dawley (Hsd:Sprague Dawley® SD®) rats. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2020. NTP Technical Report No. 598. https://ntp.niehs.nih.gov/publications/reports/tr/500s/tr598/index.html?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tr598abs
212 Rusyn I, Corton JC. Mechanistic considerations for human relevance of cancer hazard of di(2-ethylhexyl) phthalate. Mutat Res. 2012; 750(2):141–158. 10.1016/j.mrrev.2011.12.004 22198209
213 National Toxicology Program (NTP). NTP toxicology and carcinogenesis studies of butyl benzyl phthalate (CAS No. 85-68-7) in F334/N rats (Feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 1997. NTP Technical Report No. 458. https://ntp.niehs.nih.gov/publications/reports/tr/400s/tr458/index.html?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tr458abs
214 Biegel LB, Hurtt ME, Frame SR, O’Connor JC, Cook JC. Mechanisms of extrahepatic tumor induction by peroxisome proliferators in male CD rats. Toxicol Sci. 2001; 60(1):44–55. 10.1093/toxsci/60.1.44 11222872
215 Bell RH Jr, Kuhlmann ET, Jensen RT, Longnecker DS. Overexpression of cholecystokinin receptors in azaserine-induced neoplasms of the rat pancreas. Cancer Res. 1992; 52(12):3295–3299. 1596887
216 Longnecker DS. Interface between adaptive and neoplastic growth in the pancreas. Gut. 1987; 28(Suppl):253–258. 10.1136/gut.28.Suppl.253 3319812
217 Povoski SP, Zhou W, Longnecker DS, Roebuck BD, Bell RH Jr. Stimulation of growth of azaserine-induced putative preneoplastic lesions in rat pancreas is mediated specifically by way of cholecystokinin-A receptors. Cancer Res. 1993; 53(17):3925–3929. 8358719
218 Gray LE, Foster PMD. Significance of experimental studies for assessing adverse effects of endocrine-disrupting chemicals. Pure Appl Chem. 2003; 75(11-12):2125–2141. 10.1351/pac200375112125
219 Gray LE Jr, Furr J, Tatum-Gibbs KR, Lambright C, Sampson H, Hannas BR, Wilson VS, Hotchkiss A, Foster PM. Establishing the “biological relevance” of dipentyl phthalate reductions in fetal rat testosterone production and plasma and testis testosterone levels. Toxicol Sci. 2016; 149(1):178–191. 10.1093/toxsci/kfv224 26454885
220 Howdeshell KL, Furr J, Lambright CR, Rider CV, Wilson VS, Gray LE Jr. Cumulative effects of dibutyl phthalate and diethylhexyl phthalate on male rat reproductive tract development: Altered fetal steroid hormones and genes. Toxicol Sci. 2007; 99(1):190–202. 10.1093/toxsci/kfm069 17400582
221 Borch J, Axelstad M, Vinggaard AM, Dalgaard M. Diisobutyl phthalate has comparable anti-androgenic effects to di-n-butyl phthalate in fetal rat testis. Toxicol Lett. 2006; 163(3):183–190. 10.1016/j.toxlet.2005.10.020 16458459
222 Welsh M, Saunders PTK, Fisken M, Scott HM, Hutchison GR, Smith LB, Sharpe RM. Identification in rats of a programming window for reproductive tract masculinization, disruption of which leads to hypospadias and cryptorchidism. J Clin Invest. 2008; 118(4):1479–1490. 10.1172/JCI34241 18340380
223 Nef S, Parada LF. Cryptorchidism in mice mutant for Insl3. Nat Genet. 1999; 22(3):295–299. 10.1038/10364 10391220
224 Zimmermann S, Steding G, Emmen JMA, Brinkmann AO, Nayernia K, Holstein AF, Engel W, Adham IM. Targeted disruption of the Insl3 gene causes bilateral cryptorchidism. Mol Endocrinol. 1999; 13(5):681–691. 10.1210/mend.13.5.0272 10319319
225 Wilson VS, Lambright C, Furr J, Ostby J, Wood C, Held G, Gray LE. Phthalate ester-induced gubernacular lesions are associated with reduced insl3 gene expression in the fetal rat testis. Toxicol Lett. 2004; 146(3):207–215. 10.1016/j.toxlet.2003.09.012 14687758
226 Barlow NJ, McIntyre BS, Foster PMD. Male reproductive tract lesions at 6, 12, and 18 months of age following in utero exposure to di(n-butyl) phthalate. Toxicol Pathol. 2004; 32(1):79–90. 10.1080/01926230490265894 14713552
227 Furr JR, Lambright CS, Wilson VS, Foster PM, Gray LE Jr. A short-term in vivo screen using fetal testosterone production, a key event in the phthalate adverse outcome pathway, to predict disruption of sexual differentiation. Toxicol Sci. 2014; 140(2):403–424. 10.1093/toxsci/kfu081 24798384
228 Fisher JS, Macpherson S, Marchetti N, Sharpe RM. Human ‘testicular dysgenesis syndrome’: A possible model using in-utero exposure of the rat to dibutyl phthalate. Hum Reprod. 2003; 18(7):1383–1394. 10.1093/humrep/deg273 12832361
229 van den Driesche S, Kilcoyne KR, Wagner I, Rebourcet D, Boyle A, Mitchell R, McKinnell C, Macpherson S, Donat R, Shukla CJ, et al. Experimentally induced testicular dysgenesis syndrome originates in the masculinization programming window. JCI Insight. 2017; 2(6):e91204. 10.1172/jci.insight.91204 28352662
230 Sohval AR. Testicular dysgenesis as an etiologic factor in cryptorchidism. J Urol. 1954; 72(4):693–702. 10.1016/S0022-5347(17)67649-3 13202269
231 Sohval AR. Testicular dysgenesis in relation to neoplasm of the testicle. J Urol. 1956; 75(2):285–291. 10.1016/S0022-5347(17)66809-5 13296128
232 Hoei-Hansen CE, Holm M, Rajpert-De Meyts E, Skakkebaek NE. Histological evidence of testicular dysgenesis in contralateral biopsies from 218 patients with testicular germ cell cancer. J Pathol. 2003; 200(3):370–374. 10.1002/path.1372 12845633
233 Gray TJB, Butterworth KR, Gaunt IF, Grasso P, Gangolli SD. Short-term toxicity study of di-(2-ethylhexyl) phthalate in rats. Food Cosmet Toxicol. 1977; 15(5):389–399. 10.1016/S0015-6264(77)80003-5 598790
234 Clegg ED, Cook JC, Chapin RE, Foster PM, Daston GP. Leydig cell hyperplasia and adenoma formation: Mechanisms and relevance to humans. Reprod Toxicol. 1997; 11(1):107–121. 10.1016/S0890-6238(96)00203-1 9138629
235 Cook JC, Klinefelter GR, Hardisty JF, Sharpe RM, Foster PM. Rodent Leydig cell tumorigenesis: A review of the physiology, pathology, mechanisms, and relevance to humans. Crit Rev Toxicol. 1999; 29(2):169–261. 10.1080/10408449991349203 10213111
236 Creasy D, Bube A, de Rijk E, Kandori H, Kuwahara M, Masson R, Nolte T, Reams R, Regan K, Rehm S, et al. Proliferative and nonproliferative lesions of the rat and mouse male reproductive system. Toxicol Pathol. 2012; 40(6 Suppl):40S–121S. 10.1177/0192623312454337 22949412
237 Wei Z, Song L, Wei J, Chen T, Chen J, Lin Y, Xia W, Xu B, Li X, Chen X, et al. Maternal exposure to di-(2-ethylhexyl)phthalate alters kidney development through the renin-angiotensin system in offspring. Toxicol Lett. 2012; 212(2):212–221. 10.1016/j.toxlet.2012.05.023 22677342
238 Khorana AA, Fine RL. Pancreatic cancer and thromboembolic disease. Lancet Oncol. 2004; 5(11):655–663. 10.1016/S1470-2045(04)01606-7 15522652
239 Kamijo Y, Hora K, Nakajima T, Kono K, Takahashi K, Ito Y, Higuchi M, Kiyosawa K, Shigematsu H, Gonzalez FJ, et al. Peroxisome proliferator-activated receptor alpha protects against glomerulonephritis induced by long-term exposure to the plasticizer di-(2-ethylhexyl)phthalate. J Am Soc Nephrol. 2007; 18(1):176–188. 10.1681/ASN.2006060597 17135395
240 Organisation for Economic Co-operation and Development (OECD). OECD guidelines for testing of chemicals. Test guideline 479. Test no. 479: Genetic toxicology: In vitro sister chromatid exchange assay in mammalian cells. 2014. https://www.oecd-ilibrary.org/environment/test-no-479-genetic-toxicology-in-vitro-sister-chromatid-exchange-assay-in-mammalian-cells_9789264071384-en
241 McFee AF, Lowe KW, San Sebastian JR. Improved sister-chromatid differentiation using paraffin-coated bromodeoxyuridine tablets in mice. Mutat Res. 1983; 119(1):83–88. 10.1016/0165-7992(83)90042-8 6823230
242 McFee AF, Tice RR, Shelby MD. In vivo cytogenetic activity of diphenylhydantoin in mice. Mutat Res. 1992; 278(1):61–68. 10.1016/0165-1218(92)90286-9 1370120
243 Shelby MD, Gulati DK, Tice RR, Wojciechowski JP. Results of tests for micronuclei and chromosomal aberrations in mouse bone marrow cells with the human carcinogens 4-aminobiphenyl, treosulphan, and melphalan. Environ Mol Mutagen. 1989; 13(4):339–342. 10.1002/em.2850130410 2737185
244 Margolin BH, Resnick MA, Rimpo JY, Archer P, Galloway SM, Bloom AD, Zeiger E. Statistical analyses for in vitro cytogenetic assays using Chinese hamster ovary cells. Environ Mutagen. 1986; 8(2):183–204. 10.1002/em.2860080203 3698942
245 MacGregor JT, Wehr CM, Henika PR, Shelby MD. The in vivo erythrocyte micronucleus test: Measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990; 14(3):513–522. 10.1016/0272-0590(90)90255-I 2111256