# Discussion

Di(2-ethylhexyl) phthalate (DEHP) is a plasticizer to which humans are exposed, as evidenced by detection of DEHP metabolites in serum and urine samples. The presence of DEHP metabolites in human amniotic fluid samples shows exposure occurs in utero. Rodent studies report that DEHP produces adverse effects on the developing male rat reproductive tract and induces hepatic, pancreatic, and testicular neoplasms. Prior to the current studies, data were insufficient to assess whether developmental exposure would alter lifetime DEHP carcinogenic risk. To address this knowledge gap, the National Toxicology Program (NTP) conducted two 2-year bioassays with DEHP administered in feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats to evaluate whether neoplasm incidence during lifetime exposure that included the perinatal period (gestation and lactation) would increase the incidence of neoplasms or lead to the appearance of different neoplasm types relative to chronic exposure initiated in early adulthood.

In the perinatal and postweaning study (Study 1), exposure was associated with significantly decreased maternal mean body weights during gestation and lactation in the 10,000 ppm group compared to the control group, with the magnitude of the effect increasing throughout the perinatal period. This effect was attributed to significantly decreased body weight gain during gestation, likely in part due to cumulative effects of reduced maternal feed consumption (g/animal/day) throughout the gestation and lactation period in the 10,000 ppm group.

Estimated DEHP intake increased in proportion to exposure concentration, with the exception of 10,000 ppm dams during lactation (lactation days [LDs] 1–14), for which significantly decreased feed consumption resulted in a less-than-proportional higher intake. In gestation day (GD) 18 dams, the mean concentration of the DEHP metabolite, mono(2-ethylhexyl) phthalate (MEHP), increased with exposure concentration although the increase was more than proportional (63-fold increase in plasma concentration versus 30-fold increase in DEHP intake [mg DEHP/kg body weight/day or mg/kg/day] during gestation from lowest [300 ppm] to highest [10,000 ppm] exposure groups). Amniotic fluid and fetus concentrations of MEHP increased 23- and 46-fold, respectively, from the lowest to highest exposure groups (300 to 10,000 ppm). Gestational transfer of MEHP from the dam to the fetus was moderate.

MEHP concentrations in dam plasma on GD 18 at the lowest exposure concentration were 630 ng/mL, approximately 60-fold higher than the median blood MEHP concentration of 10.4 ng/mL observed in pregnant women in the Hokkaido Study Sapporo Cohort.^203^ Moreover, the GD 18 MEHP concentration measured in amniotic fluid at the lowest exposure concentration was 73.4 ng/mL, which is 28-fold higher than the upper 95th percentile of MEHP levels measured in human amniotic fluid samples.^26^ Additional studies have detected MEHP in human amniotic fluid and cord blood plasma samples, indicating that DEHP or its metabolites cross the placental barrier and result in exposure to the developing conceptus.^204-206^ DEHP levels in control feed were below the limit of detection (1.27 ppm) of the analytical method; however, detectable levels of MEHP were measured in control amniotic fluid and fetuses, but not in control dam plasma (GD 18). Detection of MEHP in control animal samples might have resulted from sample contamination during collection or analysis, due to the presence of phthalates in manufactured laboratory plasticware. Although not assessed in the present study, DEHP and MEHP can be transferred from dam to offspring via lactation.^54^ DEHP exposure during the perinatal period was associated with significantly decreased total and live litter size, due to a significantly decreased number of female pups per litter in the 10,000 ppm group (626 mg/kg/day). In previous studies, increased resorptions, postimplantation loss, and whole-litter loss have been observed following DEHP exposure at doses >500 mg/kg/day in pregnant rats.^90,207-209^ In a multigenerational reproductive assessment of DEHP, previously conducted by NTP, significant effects on litter size and sex ratio were observed following perinatal exposure of Sprague Dawley rat F_0_ dams at concentrations of 7,500 and 10,000 ppm.^210^ In this perinatal and postweaning study (Study 1), exposure-related decreases in birth and weaning mean body weights were observed in both male and female groups. Gestational DEHP exposure was associated with 15% and 12% decreases in postnatal day (PND) 1 mean body weights of 10,000 ppm male and female pups, respectively. Further growth retardation during lactation was observed with male and female pup weights. Postweaning, mean body weights of the 10,000 ppm offspring remained significantly decreased relative to control groups throughout the 2-year exposure period. The magnitude of effect on body weight observed in 10,000 ppm offspring was higher than the 30% decrease in postweaning body weights observed at the same dose level in the NTP multigeneration assessment of DEHP.^210^

No significant differences in overall survival were observed in either the perinatal and postweaning study (Study 1) or the postweaning-only study (Study 2) relative to concurrent control groups, although there was some early postweaning mortality (Study 1). Lower mean body weights (postweaning to study termination) were observed in 10,000 ppm male and female rats in both studies relative to control rats. In both studies, lower mean body weights were associated with lower body weight gain; however, the magnitude of effect was higher following perinatal and postweaning exposure compared to postweaning-only exposure, due to early life exposure that included gestation, lactation, and a brief period after weaning. In the 10,000 ppm male and female rat groups, the largest difference in feed consumption relative to the control groups occurred directly following weaning. In rats, increased rates of feed and water consumption, relative to body weight, are commonly observed in younger animals and decrease with subsequent growth and development. Furthermore, in the perinatal and postweaning study (Study 1), the 2-year direct exposure period began at weaning, 3 weeks earlier than in the postweaning-only study (PND 42) (Study 2). Although this 3-week interval represents a small fraction of the total exposure timeframe, perinatal and postweaning exposure groups were exposed to DEHP at earlier ages and therefore at higher doses than the corresponding groups in the postweaning-only study (Study 2), likely contributing to the 3%–20% higher mean chemical consumption (mg/kg/day) postweaning in Study 1 versus Study 2.

The following conclusions on the carcinogenicity of DEHP were determined based on the weight-of-evidence approach described in the Explanation of Levels of Evidence of Carcinogenic Activity. Conclusions on DEHP carcinogenic activity are described separately for the perinatal and postweaning and postweaning-only studies, based on the independent results observed in each study. Although some variability in carcinogenic outcomes was observed between rats exposed to DEHP during the perinatal and postweaning periods and those only exposed postweaning, it is unclear whether any differences correspond to specific developmental mechanisms during the perinatal period. Some noncarcinogenic outcomes were related to perinatal exposure, however, which included the gross lesions in the reproductive tract and histological lesions in the kidney.

At the conclusion of both studies, numerous neoplastic and nonneoplastic lesions in the liver were identified. In male rats, increased incidences of hepatocellular adenoma and hepatocellular adenoma or carcinoma (combined) were observed in both 2-year studies. In the perinatal and postweaning study (Study 1), there was an increase in rare hepatocellular carcinomas (historical control 2/489; range 0% to 2%) in the 10,000 ppm group (8.7%), whereas a positive trend was observed in these neoplasms in the postweaning-only study (Study 2). In both perinatal and postweaning and postweaning-only studies, higher incidences of hepatocellular cytoplasmic alteration, liver pigmentation, and liver necrosis were observed in male rats. Although considered minimal in severity, a higher incidence of hepatocellular hypertrophy was observed in 10,000 ppm male rats exposed during the perinatal and postweaning periods (35%) compared to male rats in the postweaning-only study (12%). Additionally, a significantly increased incidence of basophilic focus was observed in the livers of 10,000 ppm male rats in the perinatal and postweaning study, but not in their counterparts in the postweaning-only study (Study 2). Taken together, the significantly increased incidence of hepatocellular adenoma or carcinoma (combined) supported clear evidence of carcinogenicity in male rats in both 2-year studies.

In female rats, increased incidences of hepatocellular adenoma, hepatocellular carcinoma, and hepatocellular adenoma or carcinoma (combined) were observed in both 2-year studies. In female rats in the perinatal and postweaning study, the incidence of hepatocellular adenomas in the 3,000 ppm group that was higher (18%) than in the historical control range (15/489; range 0% to 8%); in females in the postweaning-only study (Study 2), the incidence of hepatocellular adenomas was above the historical control range in the 10,000 ppm group. Furthermore, an increased incidence of hepatocellular carcinoma (17%), a rare neoplasm type (historical control 1/489; range 0% to 2%), was also observed in 10,000 ppm female rats in the perinatal and postweaning study, whereas there was occurrence of hepatocellular carcinomas (0% versus 4% compared to the control group) in the 10,000 ppm group of the postweaning-only study (Study 2). Taken together, the increased incidence of hepatocellular adenoma or carcinoma (combined) supported clear evidence of carcinogenicity in the liver of female rats in both studies.

Significantly increased incidences of hepatocellular cytoplasmic alteration, hepatocellular hypertrophy, and liver pigmentation were observed in female rats in both 2-year studies. Higher incidences of eosinophilic foci were observed in 10,000 ppm female rats in the perinatal and postweaning study (Study 1), but not in the postweaning-only study (Study 2). A significantly increased incidence of hepatocellular carcinomas was observed only in 10,000 ppm females of the perinatal and postweaning study (17%) compared to the postweaning-only study (4%). This observation could be due to a higher rate of progression from hepatocellular adenoma to carcinoma because of early life or prolonged exposure, observations that are similar to those made in the perfluorooctanoic acid (PFOA) 2-year study^211^ in which perinatal and postweaning exposure led to a marginally higher carcinoma rate (4%) of this rare neoplasm in male rats relative to the rats with postweaning-only exposure (0%). Males with perinatal and postweaning exposure to DEHP also had a marginally higher hepatocellular carcinoma incidence compared to males with postweaning-only exposures.

Numerous chronic exposure studies have found that DEHP induces hepatic neoplasms in rats and mice. In the current study, estimated DEHP daily exposure concentrations (mg/kg/day) associated with higher incidences of hepatocellular adenomas or carcinomas were comparable to concentrations reported in previous studies. In a previous NTP study, chronic DEHP exposure via dosed feed resulted in increased incidences of hepatocellular carcinomas in male and female Fischer 344 (F344) rats at estimated daily exposures of 322 and 674 mg/kg/day in males and 394 and 774 mg/kg/day in females.^69^ In another study, increased incidences of hepatocellular adenomas and carcinomas were observed in male Sprague Dawley rats following lifetime exposure to 300 mg/kg/day.^126^ The precise mechanism by which DEHP induces hepatic neoplasms is not fully characterized. However, activation of peroxisome proliferator-activated receptor alpha (PPARα) by the DEHP proximal metabolite MEHP has been defined as a key molecular event by which DEHP causes hepatic neoplasms in rodents. The human relevance of mechanisms of carcinogenesis of the peroxisome proliferator class of chemicals is frequently debated.^212^ Additional research suggests that multiple signaling pathways and downstream mediators likely contribute to DEHP-induced hepatic carcinogenesis, rather than a single hallmark event such as activation of PPAR.^73,212^

Increased incidences of pancreatic acinar adenomas, carcinomas, and adenoma or carcinoma (combined) were observed in male rats in both studies. In both perinatal and postweaning and postweaning-only exposed male rats, increased incidences of pancreatic acinar adenomas occurred in the 3,000 and 10,000 ppm groups at higher rates than the historical control range (60/488; range 0% to 28%). Notably, a higher incidence of pancreatic cell adenomas occurred in 3,000 ppm perinatal and postweaning-exposed males (72%) when compared to males exposed to the same concentration postweaning-only (46%). Due to the potentially high background incidence of pancreatic acinar adenoma in the test rat strain (up to 28% in historical control groups), observed differences between perinatal and postweaning and postweaning-only exposure groups might have resulted from background variability of this lesion and not increased sensitivity related to perinatal exposure. A higher incidence of pancreatic acinar carcinoma, a rare neoplasm type (historical control 4/488; range 0% to 4%), was observed in 3,000 ppm male rats (6%) exposed during the perinatal and postweaning periods, and this neoplasm was increased in the 10,000 ppm male rats exposed postweaning-only. Furthermore, increased incidences of pancreatic acinar hyperplasia were noted in 3,000 and 10,000 ppm males exposed postweaning-only. The increased incidence of pancreatic acinar adenoma or carcinoma (combined) was considered clear evidence of carcinogenicity in male rats in both 2-year studies.

In female rats, occurrences of pancreatic acinar adenoma and carcinomas were observed in the postweaning-only study (Study 2), whereas occurrences of pancreatic acinar adenomas were observed in the perinatal and postweaning study (Study 1). In contrast to males, pancreatic acinar neoplasms are very rare in female rats (historic control 0/489). Occurrences of pancreatic acinus hyperplasia were also observed in exposed groups in both studies. After considering the rarity of this lesion type in female rats, the corroborating effect in male rats, and findings supportive of neoplastic progression, the incidence of pancreatic acinar adenoma or carcinoma (combined) was considered related to DEHP exposure in female rats.

Pancreatic acinar adenomas and carcinomas have been observed previously in male F344 rats following chronic DEHP exposure.^86^ Pancreatic adenomas have been reported in rodent models following exposure to various chemicals known to activate PPARα, such as PFOA, butyl benzyl phthalate (BBP), and Wyeth-14,643 (WY).^211,213,214^ Although direct activity of PPARα agonists on acinar cells has yet to be established, some data suggest that induction of pancreatic neoplasms by PPARα agonists is secondary to functional alterations in the liver. One proposed mode of action suggests that hepatic PPARα activation and subsequent alteration of transcriptional activity leads to alteration in bile acid composition and flow, resulting in cholestasis and increased expression of cholecystokinin (CCK).^127^ CCK is a growth factor reported to induce normal, adaptive, and neoplastic growth of pancreatic acinar cells in rats.^215-217^

Numerous gross lesions in the male reproductive tract were observed in male rats in the 10,000 ppm group exposed during both the perinatal and postweaning period, consistent with the “phthalate syndrome” suite of effects.^99,218,219^ These findings included decreased size of the phallus, testes, epididymides, prostate, seminal vesicles, and levator ani/bulbocavernosus (LABC) muscle; gubernacular length exceeding 20 mm; no gubernaculum present; nonregression of the cranial suspensory ligament (CSL); cleft phallus or prepuce; undescended testes (cryptorchid); epididymal agenesis (caput, corpus, or cauda); and incomplete preputial separation. All examined males exposed to 10,000 ppm DEHP in the perinatal and postweaning study presented with at least one of the aforementioned reproductive tract malformations; small or undescended testes were the most frequently observed reproductive tract malformations at 10,000 ppm. Male reproductive tract malformations have been observed in rodents following perinatal exposure to various phthalates, such as DEHP, di-n-butyl phthalate (DBP), di-isobutyl phthalate (DiBP), BBP, and diisononyl phthalate (DINP), and are indicative of hormone disruption of developmental androgen and insulin-like peptide 3 (Insl3) dependent signaling pathways.^95,220,221^ Differentiation of Wolffian structures (e.g., the epididymis, vas deferens, seminal vesicles) depends on fetal testosterone signaling, and masculinization of the prostate and external genitalia depends on the biosynthesis and signaling of the more potent androgen, dihydrotestosterone.^222^ Targeted disruption of Insl3 signaling alters gubernaculum development and CSL regression, leading to cryptorchidism.^223,224^ Developmental exposure to phthalates, such as DEHP, DBP, and BBP, disrupts Insl3 signaling leading to complete agenesis or hypoplasia of the gubernacular ligaments and retention of the testes in the inguinal or abdominal position.^95,225^ In the study presented here, undescended testes were consistently reduced in size and were more often retained in the abdominal region compared to the inguinal region.

Additional microscopic nonneoplastic lesions diagnosed in the testis and epididymis of male rats exposed during both the perinatal and postweaning periods were considered related to DEHP exposure. Observations of testicular germinal epithelium degeneration were noted in 10,000 ppm male rats with or without perinatal exposure and occurred concomitantly with epididymal hypospermia. Findings of testicular edema and exfoliated germ cells in the epididymal duct were observed in 10,000 ppm males of both studies; however, these effects were not significant in the perinatal and postweaning study and therefore considered related to exposure only in the postweaning-only study (Study 2). It is possible that evaluation at the end of a 2-year exposure led to lower sensitivity in detecting testicular degeneration as a higher incidence in control males can occur in older animals and findings are likely to be more evident in younger animals at lower exposure concentrations at earlier timepoints than in younger control animals.^226,227^ Seminiferous tubule dysgenesis was only present in 10,000 ppm males with perinatal and postweaning exposure (10/49). Seminiferous tubule dysgenesis is characterized as a developmental malformation seen microscopically as aberrant or misshapen seminiferous tubules, either with no or dilated lumens, which are often surrounded by focal Leydig cell aggregates. The Leydig cell aggregates within foci of dysgenesis differ morphologically from the Leydig cells in adenomas. The Leydig cells in these foci of dysgenesis appear to be poorly differentiated, are spindle-shaped and resemble embryonic Leydig cells, and do not have the abundant eosinophilic or vacuolated cytoplasm often apparent in hyperplasia or adenoma.^226^ Dysgenetic lesions might occur as one or more small foci per testis, and tend to be located near the center of the testis or might occupy the entire testis.^226^ The malformed tubules can appear to form anastomotic networks. The dysgenetic tubules contain poorly differentiated Sertoli cells, with small, elongated, and sometimes cleaved nuclei and less prominent nucleoli than the typical, prominent, tripartite nucleoli seen in mature Sertoli cells. Spermatogenesis is absent in these foci of dysgenesis but can be present elsewhere in the testis. Dysgenetic foci might be present in one or both testes and can be more severe in undescended than in scrotal testes.^228,229^ In men, similar microscopic dysgenetic foci have been reported in cryptorchid (undescended) testes,^230^ in testes also containing testicular cancer (both scrotal and cryptorchid testes^231^), and from testicular biopsies from the contralateral testis in men undergoing orchiectomy for testicular cancer.^232^

Increased pituitary pars distalis hypertrophy occurred in 10,000 ppm male rats in both studies. This lesion is commonly associated with disruption of the hypothalamus-pituitary-gonad signaling axis. Loss of negative feedback signaling by testicular-derived androgens, due to the antiandrogenic activity of phthalates, leads to increased hypothalamic release of gonadotropin-releasing hormone and subsequent increased releases of luteinizing hormone and follicle-stimulating hormone by gonadotrophs, or “castration cells,” in the pars distalis of the pituitary gland.^233^

There was a significant positive trend with testicular interstitial cell adenoma neoplasms in the postweaning-only study (Study 2), and the incidence of testicular interstitial cell adenoma (15/50; 30%) observed in 10,000 ppm male rats was above NTP’s historical control range (19/487; range 0% to 14%). However, there were no significant pairwise differences among the exposed groups compared to the control groups in the incidences of neoplasms or hyperplasias. Taken together, the data suggest that testicular interstitial cell adenomas may have been related to DEHP exposure in postweaning-only exposed male rats.

In contrast, perinatal and postweaning exposure did not increase the incidence of Leydig cell (interstitial) neoplasms relative to control animals, although the incidence of interstitial cell hyperplasia was considerably higher. Currently, it is unclear whether developmental malformations in the male reproductive tract, such as altered seminiferous tubule morphology or structural and functional alterations in Sertoli and Leydig cell populations, affect the carcinogenic potential of DEHP in testes in perinatally exposed rats relative to functional effects observed following adult exposure only. Increased incidences of focal interstitial cell hyperplasia were observed in both 2-year studies. Focal hyperplasia is considered a preneoplastic lesion that commonly forms as a part of a continuum leading to interstitial cell adenoma; it is distinct from diffuse hyperplasia, generally considered a physiological response to hormonal imbalance.^234-236^

Several PPARα agonists, including DEHP, PFOA, and WY, have been shown to induce Leydig cell neoplasms in rats.^126,214^ Multiple mechanisms by which PPARα agonists might induce testicular neoplasms through disruption of the hypothalamus-pituitary-thyroid axis have been postulated; however, the weight of evidence is currently inadequate to establish a mode of action.^127^ The marginal to no response in Leydig cell neoplasms to DEHP in this study is inconsistent with published studies and could be due to differential diagnoses. Varying morphological criteria distinguishing Leydig cell adenomas from seminiferous tubule dysgenesis may account for differential diagnoses^226^; the rodent strain studies may also be a factor as there were no Leydig cell neoplasms observed in the NTP PFOA studies,^211^ which used the Hsd:Sprague Dawley^®^ SD^®^ rat.

In female rats, increased incidences of adenoma, adenocarcinoma, squamous cell carcinoma, or squamous cell papilloma (combined) (mostly adenocarcinoma) were observed in the uterus (including cervix). Higher incidences of uterine (including cervix) adenoma, adenocarcinoma, squamous cell carcinoma, or squamous cell papilloma (combined) (26%) were observed in 10,000 ppm postweaning-only exposed females, which was above the NTP historical control incidence of this combination of lesions of 2% to 10%. Uterine inflammation was increased in all DEHP-exposed groups in the postweaning-only study (Study 2). This supported clear evidence of carcinogenic activity from DEHP postweaning-only exposure in female rats.

In the perinatal and postweaning study (Study 1), however, there was a marginally higher incidence of uterine neoplasms in DEHP-exposed groups compared to the control group and none of the pairwise comparisons to the control group were significant. The magnitude of the difference between the 10,000 ppm group and the control group in each study was lower in the perinatal and postweaning study (8% difference) compared to the postweaning-only study (22% difference). There was reduced certainty in this marginal response such that the incidence of uterine neoplasms may have been related to perinatal and postweaning exposure. The reason for this is not clear, but it is noteworthy that the testis and uterus, sites of endocrine action, had a lower response in general with the perinatal and postweaning exposure compared to the postweaning-only exposure.

The present study is the first to identify an association between DEHP exposure and induction of uterine neoplasms in female rats. The mechanism for this response is unclear. For previous chronic studies, no alterations in female reproductive organ histology were reported.^69,86,123^ Induction of the “tumor triad,” including liver, Leydig cell, and pancreatic acinar cell tumors, is a finding characteristic of sustained exposure to PPARα agonists in rats^214^; however, the relevance of this finding to humans is uncertain. The uterine neoplasm response in the NTP PFOA carcinogenicity study^211^ was considered equivocal evidence of carcinogenic activity. The magnitude of the response and level of evidence for PFOA is similar to that of the DEHP perinatal and postweaning study, whereas the response in the DEHP postweaning-only study was considerably higher. Further work will be required to assess the mode of action for these outcomes.

Evidence of DEHP-associated renal toxicity was specific to male and female rats with perinatal and postweaning exposure. Numerous nonneoplastic kidney lesions were increased in DEHP-exposed groups relative to control groups, such as papilla edema, papilla epithelium hyperplasia, papilla hemorrhage, infarct, and renal tubule cysts. Papillary edema was the most prevalent kidney lesion in 10,000 ppm male (39/49) and female (38/48) rats in the perinatal and postweaning study and was not present in the postweaning-only study (Study 2). This highly unusual bilateral lesion was characterized by marked dilation and/or distortion of the collecting ducts and moderate to marked expansion of the papilla interstitium by pale eosinophilic to fibrillary amphophilic material, consistent with edema. Periodic acid-Schiff (PAS) staining demonstrated that the basement of vascular structures, in addition to the renal tubule basement membranes in the cortex and medulla, were intact. An abrupt loss of PAS staining of the basement membranes of collecting tubules was observed, however, at the junction of the outer and inner medulla. Therefore, perinatal exposure to DEHP is presumed to interfere directly or indirectly with the proper development of the collecting tubules. The normal function of the collecting duct system is urine transport as well as electrolyte and fluid balance through reabsorption and excretion, processes regulated by aldosterone and vasopressin. Additional studies have reported DEHP-associated renal toxicity. Chronic dietary exposure to DEHP (≥789 mg/kg/day) was associated with increased severity of routinely occurring renal tubule pigmentation and chronic progressive nephropathy in male and female rats.^86^ Altered kidney function and kidney lesions have been reported in rats following developmental DEHP exposure. Impaired kidney development and function were observed in adult Wistar rats following maternal exposure to DEHP at doses of 0.25 and 6.25 mg/kg/day from GD 0 through offspring PND 21.^237^ Maternal exposure resulted in a decreased number of nephrons, higher glomerular volume, and smaller Bowman's capsule in offspring at weaning, as well as glomerulosclerosis, interstitial fibrosis, and effacement of podocyte foot processes in 33-week-old F_1_ rats. Taken together, these data suggest the developing kidney may be a sensitive target of DEHP toxicity.

Cardiovascular findings of increased heart valve fibrosis and thrombus were present in 10,000 ppm male rats in both of the present studies. Thrombosis in male rats has been associated with pancreatic cancer related to onset of an intrinsic hypercoagulable state caused by elevated activation of platelets and increased expression of procoagulant factors.^238^ However, a low concurrence of pancreatic cancer and cardiovascular thrombosis was observed in the present studies. Additionally, increased systolic blood pressure has been observed in rats and mice exposed to DEHP; however, this effect is thought to be secondary to renal dysfunction or alterations in renin and angiotensin II signaling.^237,239^

NTP has tested DEHP in a range of in vitro and in vivo genotoxicity assays, and the results were generally negative. The positive results seen in some of the in vitro assays for induction of sister chromatid exchanges (SCE) were seen in the presence of excessive cytotoxicity. The Organization for Economic Co-operation and Development test guideline^240^ for the in vitro SCE test was withdrawn in 2014, and the test is no longer requested by regulatory agencies. In vivo, the nonnegative responses that were observed in some of the NTP micronucleus assays were generally weak. The consensus from published data is that DEHP shows limited evidence of genotoxic potential, and for the sporadic positive results that have been reported, the response is either weak, not reproducible, obtained in a nonstandard test system, or qualified to some degree by the authors.

Lastly, carcinogenic responses that were related or may have been related to DEHP exposure were modeled to estimate benchmark doses corresponding to a 10% increase in neoplasm incidence (BMD_10_). For the similar target sites, the BMD_10_ levels based on the hepatocellular response were lower in males in the perinatal and postweaning study compared to the postweaning-only study (383 mg/kg/day and 434 mg/kg/day, respectively) and in females (123 mg/kg/day and 384 mg/kg/day, respectively). Conversely, BMD_10_ levels were lower for the pancreatic acinar neoplasm response in males with postweaning-only exposure compared with perinatal and postweaning exposure (31 mg/kg/day versus 86 mg/kg/day, respectively). The BMD_10_ for the neoplastic responses in the uterus in females was lower in the postweaning-only study compared to the perinatal and postweaning study (324 mg/kg/day versus 594 mg/kg/day, respectively). The lowest BMD_10_ levels were associated with incidences of pancreatic acinar adenoma or carcinoma (combined) in male rats in both studies. These data show no obvious overall increased sensitivity in carcinogenic response with perinatal and postweaning exposure compared to postweaning-only exposure, which is consistent with NTP’s study of PFOA perinatal exposure.^211^