# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-601.^202^

## Perinatal and Postweaning Study in Rats (Study 1)

### Perinatal Phase

No effects on maternal survival were observed following exposure to di(2-ethylhexyl) phthalate (DEHP), and no exposure-related maternal clinical observations were noted (Appendix H). Administration of DEHP had no effects on the percentage of pregnant females that produced pups, gestation length, or pup sex distribution (Table 2; Appendix H). The lower number of females that produced pups in the 10,000 ppm group was due to 13 mated females that were not pregnant. This was not attributed to the test article, because dam exposure to DEHP started after the period of implantation.

Table 2 Summary of the Disposition of F_0_ Female Rats during Perinatal Exposure in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Reproductive Performance
Time-mated Females (GD 6) | 45 | 45 | 45 | 45 | 45
Females Pregnant (%)^a^ | 39 (86.7) | 35 (77.8) | 38 (84.4) | 35 (77.8) | 32 (71.1)
Females Not Pregnant (%) | 6 (13.3) | 10 (22.2) | 7 (15.6) | 10 (22.2) | 13 (28.9)
Dams Not Delivering with Evidence of Pregnancy (%) | 5 (12.8) | 6 (17.1) | 7 (18.4) | 6 (17.1) | 6 (18.8)
Dams with Litters on LD 0 (%)^a^ | 34 (87.2) | 29 (82.9) | 31 (81.6) | 29 (82.9) | 26 (81.2)
Gestation Length (Days)^b,c^ | 22.1 ± 0.1 | 22.1 ± 0.1 | 22.3 ± 0.1 | 22.0 ± 0.0 | 22.2 ± 0.1
Number of Litters on LD 4^d^ | 34 | 29 | 28 | 29 | 26
Weaned Males/Females | 204/213 | 166/178 | 180/166 | 166/173 | 138/117

GD = gestation day; LD = lactation day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ Gestation length calculated for sperm-positive females that delivered a litter. Data are presented as mean ± standard error.

^d^ Litters were not standardized in this study.

Mean gestation body weights of dams receiving up to 3,000 ppm DEHP in the diet were within approximately 3.5% of control animals (Table 3). Dams that received 10,000 ppm DEHP in the diet displayed significantly decreased mean body weights (up to 10%), relative to control animals, throughout the gestational period. Lower relative body weights in 10,000 ppm dams were associated with significantly decreased body weight gain over the GD 6–9, GD 15–18, and GD 18–21 intervals (Table 3). During the gestational period (GD 6–21), the overall mean body weight gain of 10,000 ppm dams was significantly decreased 27% compared to that of the control animals. During the lactational period, there were no effects on maternal mean body weight or body weight gain among dam groups receiving up to 3,000 ppm DEHP (Table 3). Lactational body weights of 10,000 ppm dams were significantly decreased (up to approximately 25%) at all assessed lactational time points relative to control animals. This decrease was more severe in magnitude than what was observed during gestation and is likely the result of decreases in absolute body weight during the lactational period. All other exposure groups, including the control group, displayed positive weight gains during the lactation day (LD) 4–21 interval, whereas the 10,000 ppm dams lost an average of 24 g in body weight, corresponding to an approximate 10% decrease in body weight from LD 1 to LD 21.

Table 3 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

Parameter^a,b^ | 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Gestation Day
6 | 237.4 ± 2.14 (39) | 236.1 ± 2.63 (35) | 234.6 ± 2.63 (38) | 237.7 ± 1.90 (35) | 236.4 ± 2.38 (32)
9 | 253.1 ± 2.43** (39) | 251.9 ± 2.84 (35) | 246.6 ± 3.67 (38) | 250.1 ± 3.07 (35) | 244.6 ± 1.88* (32)
12 | 270.4 ± 2.03** (39) | 267.9 ± 2.42 (35) | 264.8 ± 2.52 (38) | 267.7 ± 2.05 (35) | 258.2 ± 1.93** (32)
15 | 288.0 ± 2.06** (39) | 284.5 ± 2.64 (35) | 280.7 ± 3.14 (38) | 286.5 ± 2.39 (35) | 274.8 ± 2.30** (32)
18 | 326.2 ± 2.48** (39) | 323.4 ± 3.57 (35) | 319.1 ± 3.97 (38) | 323.4 ± 4.77 (35) | 304.4 ± 3.04** (32)
21^c^ | 374.2 ± 3.62** (34) | 365.6 ± 5.14 (30) | 361.0 ± 6.19 (33) | 365.2 ± 6.95 (31) | 335.6 ± 4.63** (28)
Gestation Weight Change
Gestation Day Interval
6–9 | 15.70 ± 1.35** (39) | 15.77 ± 1.60 (35) | 12.02 ± 2.04 (38) | 12.34 ± 1.75 (35) | 8.22 ± 1.14** (32)
9–12 | 17.31 ± 1.17* (39) | 15.98 ± 1.19 (35) | 18.24 ± 1.61 (38) | 17.64 ± 1.71 (35) | 13.66 ± 0.64 (32)
12–15 | 17.61 ± 0.68 (39) | 16.68 ± 0.67 (35) | 15.91 ± 1.45 (38) | 18.73 ± 0.87 (35) | 16.53 ± 0.72 (32)
15–18 | 38.18 ± 0.95** (39) | 38.87 ± 1.40 (35) | 38.39 ± 2.11 (38) | 36.94 ± 3.14 (35) | 29.60 ± 1.04** (32)
18–21 | 48.47 ± 1.29** (34) | 44.81 ± 1.79 (30) | 43.84 ± 2.22 (33) | 44.50 ± 3.20 (31) | 32.58 ± 1.81** (28)
6–21 | 137.2 ± 2.96** (34) | 130.5 ± 4.49 (30) | 126.2 ± 6.02 (33) | 128.6 ± 6.10 (31) | 100.2 ± 3.03** (28)
Lactation Day
1 | 279.3 ± 2.28** (34) | 278.4 ± 2.68 (29) | 279.0 ± 2.21 (31) | 281.3 ± 2.19 (29) | 254.3 ± 2.06** (26)
4 | 294.4 ± 2.53** (34) | 292.9 ± 2.99 (28)^d^ | 292.2 ± 2.36 (29) | 292.7 ± 2.60 (29) | 255.8 ± 2.77** (26)
7 | 312.7 ± 2.43** (34) | 306.6 ± 3.35 (29) | 309.9 ± 2.84 (29) | 312.5 ± 2.35 (29) | 254.2 ± 3.07** (26)
14 | 317.4 ± 2.29** (34) | 315.2 ± 2.41 (29) | 317.3 ± 3.07 (29) | 315.9 ± 2.30 (29) | 238.7 ± 3.84** (26)
21 | 293.8 ± 2.34** (34) | 294.9 ± 2.52 (29) | 293.6 ± 2.77 (29) | 298.3 ± 2.40 (29) | 230.1 ± 3.79** (26)
Lactation Weight Change
Lactation Day Interval
1–4 | 15.12 ± 1.24** (34) | 14.23 ± 0.99 (28) | 12.53 ± 1.44 (29) | 11.34 ± 1.75 (29) | 1.53 ± 1.81** (26)
4–7 | 18.27 ± 1.19** (34) | 15.09 ± 1.46 (28) | 17.73 ± 1.23 (29) | 19.83 ± 1.74 (29) | −1.65 ± 1.55** (26)
7–14 | 4.74 ± 1.55** (34) | 8.58 ± 2.22 (29) | 7.42 ± 2.56 (29) | 3.40 ± 1.93 (29) | −15.5 ± 2.67** (26)
14–21 | −23.6 ± 1.40** (34) | −20.4 ± 1.63 (29) | −23.7 ± 2.36 (29) | −17.5 ± 1.54* (29) | −8.61 ± 3.25** (26)
1–21 | 14.53 ± 1.40** (34) | 16.47 ± 1.44 (29) | 13.93 ± 2.36 (29) | 17.02 ± 2.80 (29) | −24.2 ± 3.02** (26)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of dams). Body weight data are presented in grams.

^b^ Each exposure group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^c^ Decreased number of dams at gestation day (GD) 21 reflects animals removed at GD 18 for internal dose assessment.

^d^ One dam in the 300 ppm group was removed as an outlier on lactation day 4.

For dams exposed at 10,000 ppm DEHP, significantly decreased feed consumption during both gestation (GD 6–21; approximately 14%) and lactation (LD 1–14; 39%), relative to control animals (Table 4), likely contributed to the observed decrements in body weight (Table 3). Decreased feed consumption (8%) was also observed in 3,000 ppm dams during the LD 17–21 interval, and attained statistical significance, relative to control animals. Gestational DEHP intake (GD 6–21) for dams in the 300, 1,000, 3,000, and 10,000 ppm groups was approximately 21, 68, 206, and 626 mg DEHP/kg body weight/day (mg/kg/day), respectively (Table 4). Lactational DEHP intake (LD 1–14) for dams in the 300, 1,000, 3,000, and 10,000 ppm groups was approximately 49, 166, 482, and 1,244 mg/kg/day, respectively (Table 4). Chemical intake for the LD 14–21 interval was not calculated due to the unknown contribution of offspring feed consumption to the overall cage-based measurements.

Table 4 Summary of Feed and Di(2-ethylhexyl) Phthalate Consumption by F_0_ Female Rats during Gestation and Lactation in the Perinatal and Postweaning Two-year Feed Study

Parameter^a^ | 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Gestation Day Interval^b,c^
6–9 | 17.56 ± 0.41** (39) | 17.64 ± 0.45 (35) | 16.16 ± 0.72 (38) | 16.75 ± 0.58 (35) | 13.97 ± 0.22** (32)
9–12 | 18.64 ± 0.23** (39) | 18.61 ± 0.23 (35) | 18.33 ± 0.23 (38) | 18.43 ± 0.24 (35) | 16.11 ± 0.28** (32)
12–15 | 18.59 ± 0.27 (39) | 18.24 ± 0.23 (35) | 18.01 ± 0.42 (38) | 18.53 ± 0.28 (35) | 17.73 ± 0.25 (32)
15–18 | 20.41 ± 0.36** (39) | 20.87 ± 0.32 (35) | 20.74 ± 0.38 (38) | 21.02 ± 0.59 (35) | 18.16 ± 0.21** (32)
18–21 | 23.26 ± 0.29** (34) | 22.59 ± 0.37 (30) | 22.89 ± 0.41 (33) | 23.41 ± 0.57 (31) | 19.29 ± 0.29** (28)
6–21 | 19.69 ± 0.23** (34) | 19.45 ± 0.26 (30) | 19.17 ± 0.29 (33) | 19.50 ± 0.30 (31) | 17.03 ± 0.19** (28)
Lactation Day Interval^b,c^
1–4 | 35.54 ± 0.71** (30) | 34.83 ± 0.67 (28) | 35.65 ± 0.70 (25) | 34.97 ± 1.01 (18) | 28.73 ± 0.98** (23)
4–7 | 47.91 ± 0.79** (33) | 45.83 ± 0.78 (29) | 47.26 ± 0.98 (29) | 47.81 ± 1.29 (29) | 30.68 ± 0.74** (26)
7–10 | 54.85 ± 1.02** (34) | 51.92 ± 0.98 (29) | 53.85 ± 1.04 (28) | 53.65 ± 1.49 (29) | 31.38 ± 0.75** (26)
10–14 | 63.36 ± 0.98** (34) | 63.12 ± 0.76 (29) | 61.30 ± 1.42 (29) | 61.74 ± 1.70 (29) | 33.36 ± 0.92** (26)
14–17 | 62.05 ± 1.13** (34) | 63.72 ± 0.89 (29) | 63.26 ± 0.98 (29) | 62.52 ± 1.63 (29) | 37.70 ± 1.19** (26)
17–21 | 86.25 ± 1.28** (33) | 84.99 ± 1.64 (29) | 82.42 ± 1.85 (29) | 79.65 ± 2.34* (29) | 45.74 ± 2.12** (26)
1–14 | 51.01 ± 0.80** (29) | 50.13 ± 0.65 (28) | 50.28 ± 0.89 (24) | 49.26 ± 1.78 (18) | 31.04 ± 0.74** (23)
Chemical Intake (mg/kg/day)^d,e^
GD 6–21 | 0.00 ± 0.00 (34) | 20.58 ± 0.16 (30) | 68.11 ± 0.71 (33) | 205.6 ± 2.10 (31) | 625.6 ± 6.23 (28)
LD 1–14 | 0.00 ± 0.00 (29) | 49.40 ± 0.52 (27) | 165.5 ± 2.77 (24) | 482.1 ± 15.93 (18) | 1,244 ± 25.58 (23)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Data are presented as mean ± standard error (number of dams).

^b^ Feed consumption data are presented as grams/animal/day.

^c^ Each exposure group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^d^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^e^ No statistical analysis performed on the chemical intake data.

On postnatal day (PND) 1, total litter size and total live litter size of the 10,000 ppm group were significantly decreased, relative to the control group, corresponding to a reduction of approximately two pups per litter (Table 5). This litter effect corresponded to a significantly decreased number of live female offspring in 10,000 ppm DEHP-exposed litters. A significant decrease in the survival ratio (PND 5–21) of offspring exposed to 3,000 ppm was observed; however, this effect was not considered related to exposure because the survival ratio at 10,000 ppm was not different from that of the control group. No other effect of DEHP exposure on offspring survival was observed during the preweaning intervals (PND 1–4, PND 5–21, or PND 1–21) (Table 5).

Table 5 Summary of Mean Litter Size and Survival Ratio of F_1_ Male and Female Rats during Lactation in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

Parameter | 0 ppm | 300 ppm | 1,000 ppm^a^ | 3,000 ppm | 10,000 ppm
PND 1^b,c^
Total | 12.59 ± 0.38* (34) | 12.07 ± 0.31 (29) | 11.73 ± 0.66 (30) | 12.24 ± 0.55 (29) | 10.54 ± 0.45** (26)
Live | 12.44** ± 0.36 (34) | 12.07 ± 0.31 (29) | 11.67 ± 0.69 (30) | 12.21 ± 0.57 (29) | 10.08 ± 0.46** (26)
% Male per Litter | 48.73 ± 2.39 (34) | 46.87 ± 2.02 (29) | 51.95 ± 2.89 (28) | 49.06 ± 2.80 (29) | 54.83 ± 2.93 (26)
% Male^d,e^ | 49 (423) | 47 (350) | 52 (350) | 48 (354) | 54 (262)
Male^b,c^
PND 1 | 6.12 ± 0.38 (34) | 5.72 ± 0.33 (29) | 6.03 ± 0.48 (30) | 5.90 ± 0.42 (29) | 5.42 ± 0.34 (26)
PND 4 | 6.09 ± 0.39 (34) | 5.76 ± 0.32 (29) | 6.46 ± 0.41 (28) | 5.86 ± 0.41 (29) | 5.42 ± 0.36 (26)
PND 21 | 6.00 ± 0.39 (34) | 5.72 ± 0.32 (29) | 6.43 ± 0.41 (28) | 5.72 ± 0.41 (29) | 5.31 ± 0.35 (26)
Female^b,c^
PND 1 | 6.32 ± 0.33* (34) | 6.34 ± 0.24 (29) | 5.63 ± 0.48 (30) | 6.31 ± 0.47 (29) | 4.65 ± 0.35** (26)
PND 4 | 6.32 ± 0.33** (34) | 6.24 ± 0.25 (29) | 5.96 ± 0.40 (28) | 6.28 ± 0.48 (29) | 4.54 ± 0.36** (26)
PND 21 | 6.26 ± 0.33** (34) | 6.14 ± 0.25 (29) | 5.93 ± 0.41 (28) | 5.97 ± 0.49 (29) | 4.50 ± 0.36** (26)
Male and Female^b,c^
PND 4 | 12.41 ± 0.36** (34) | 12.00 ± 0.32 (29) | 12.43 ± 0.40 (28) | 12.14 ± 0.57 (29) | 9.96 ± 0.44** (26)
PND 7 | 12.41 ± 0.36** (34) | 11.93 ± 0.31 (29) | 12.43 ± 0.40 (28) | 11.97 ± 0.57 (29) | 9.88 ± 0.44** (26)
PND 10 | 12.38 ± 0.36** (34) | 11.90 ± 0.31 (29) | 12.43 ± 0.40 (28) | 11.83 ± 0.59 (29) | 9.88 ± 0.44** (26)
PND 14 | 12.29 ± 0.35** (34) | 11.86 ± 0.30 (29) | 12.39 ± 0.40 (28) | 11.69 ± 0.59 (29) | 9.81 ± 0.43** (26)
PND 17 | 12.29 ± 0.35** (34) | 11.86 ± 0.30 (29) | 12.36 ± 0.39 (28) | 11.69 ± 0.59 (29) | 9.81 ± 0.43** (26)
PND 21 | 12.26 ± 0.35** (34) | 11.86 ± 0.30 (29) | 12.36 ± 0.39 (28) | 11.69 ± 0.59 (29) | 9.81 ± 0.43** (26)
Survival per Litter
Total Dead: PND 1–4^f^ | 6 (34) | 2 (29) | 3 (30) | 3 (29) | 15 (26)
Total Dead: PND 5–21^f^ | 5 (34) | 4 (29) | 2 (28) | 13 (29) | 4 (26)
Dead: PND 1–4^b,c,g^ | 0.176 ± 0.079 (34) | 0.069 ± 0.048 (29) | 0.100 ± 0.056 (30) | 0.103 ± 0.058 (29) | 0.577 ± 0.294 (26)
Dead: PND 5–21^b,c,g^ | 0.147 ± 0.096 (34) | 0.138 ± 0.108 (29) | 0.071 ± 0.050 (28) | 0.448 ± 0.183* (29) | 0.154 ± 0.091 (26)
Dead: PND 1–21^b,c,g^ | 0.324 ± 0.151 (34) | 0.207 ± 0.115 (29) | 0.167 ± 0.069 (30) | 0.552 ± 0.214 (29) | 0.731 ± 0.326 (26)
Survival Ratio: PND 1–4^b,c,h^ | 0.998 ± 0.002 (34) | 0.994 ± 0.004 (29) | 0.997 ± 0.003 (28) | 0.994 ± 0.004 (29) | 0.990 ± 0.005 (26)
Survival Ratio: PND 5–21^b,c,i^ | 0.990 ± 0.007 (34) | 0.990 ± 0.008 (29) | 0.995 ± 0.003 (28) | 0.962 ± 0.015* (29) | 0.986 ± 0.008 (26)
Survival Ratio: PND 1–21^b,c,j^ | 0.987 ± 0.007 (34) | 0.984 ± 0.008 (29) | 0.992 ± 0.004 (28) | 0.958 ± 0.016 (29) | 0.977 ± 0.010 (26)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

PND = postnatal day.

^a^ One dam in the 1,000 ppm group was not included in any endpoint calculations due to differing pup counts on PND 1 and PND 4. Two additional dams in the 1,000 ppm group produced single pups that died on PND 1; these dams were only included in the PND 1 calculations.

^b^ Each exposure group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^c^ Data are presented as mean ± standard error (number of litters).

^d^ [100 × (number of live males in exposure group)/(number of live males and females in exposure group)] (number of pups).

^e^ No statistics performed on this endpoint.

^f^ Total number of dead pups in exposure group (number of litters).

^g^ Number dead per litter.

^h^ Survival per litter: Number of live pups on PND 4/number of live pups on PND 1.

^i^ Survival per litter: Number of live pups on PND 21/number of live pups on PND 5.

^j^ Survival per litter: Number of live pups on PND 21/number of live pups on PND 1.

Decreased PND 1 pup mean body weights were observed in male, female, and combined (male + female) offspring in 3,000 and 10,000 ppm DEHP litters (Table 6). PND 1 pup mean body weights (male, female, and combined) were significantly decreased by approximately 4% in the 3,000 ppm group, and by 15%, 12%, and 13% in males, females, and combined offspring in the 10,000 ppm group, respectively, relative to control animals. At weaning (PND 21), male and female pup mean body weights in the 1,000 and 3,000 ppm DEHP groups were significantly decreased approximately 6% compared to control animals. Severe effects on growth were evident in male and female offspring exposed to 10,000 ppm DEHP. At weaning (PND 21), mean body weights of male and female pups in the 10,000 ppm group were significantly decreased approximately 55% and 53% relative to those of control animals, respectively (Table 6). Significantly decreased mean body weights in 10,000 ppm pups were attributed to reduced body weight gain throughout the preweaning interval. Pup survival was not reduced, and there were no exposure-related clinical observations. Offspring from the 10,000 ppm group were therefore continued on study.

Table 6 Summary of Preweaning F_1_ Male and Female Rat Pup Mean Body Weights Following Perinatal Exposure to Di(2-ethylhexyl) Phthalate

Parameter^a^ | 0 ppm | 300 ppm | 1,000 ppm^b^ | 3,000 ppm | 10,000 ppm^c^
Male (g)
PND 1^d,e,f^ | 7.45 ± 0.09** (34) | 7.59 ± 0.08 (29) | 7.43 ± 0.10 (28) | 7.16 ± 0.10* (29) | 6.34 ± 0.09** (26)
PND 4^g,h^ | 10.64 ± 0.13** (207/34) | 10.51 ± 0.19 (167/29) | 10.72 ± 0.16 (181/28) | 10.34 ± 0.18 (170/29) | 11.13 ± 0.20** (140/26)
PND 7^g,h^ | 15.12 ± 0.20** (207/34) | 14.69 ± 0.28 (166/29) | 14.71 ± 0.27 (181/28) | 14.60 ± 0.23 (168/29) | 11.13 ± 0.20** (140/26)
PND 14^g,h^ | 29.19 ± 0.30** (205/34) | 28.44 ± 0.42 (166/29) | 27.80 ± 0.47* (181/28) | 28.49 ± 0.44 (166/29) | 17.24 ± 0.36** (138/26)
PND 21^g,h^ | 48.65 ± 0.59** (204/34) | 47.05 ± 0.72 (166/29) | 45.66 ± 0.79* (180/28) | 45.53 ± 0.83* (166/29) | 21.82 ± 0.84** (138/26)
Female (g)
PND 1^d,e,f^ | 7.01 ± 0.06** (34) | 7.17 ± 0.07 (29) | 7.02 ± 0.09 (28) | 6.76 ± 0.09* (29) | 6.19 ± 0.13** (26)
PND 4^g,h^ | 10.09 ± 0.11** (215/34) | 10.07 ± 0.13 (181/29) | 10.18 ± 0.17 (167/28) | 9.67 ± 0.18 (182/29) | 8.35 ± 0.21** (117/26)
PND 7^g,h^ | 14.25 ± 0.19** (215/34) | 13.97 ± 0.23 (180/29) | 13.92 ± 0.26 (167/28) | 13.50 ± 0.28 (179/29) | 10.97 ± 0.26** (117/26)
PND 14^g,h^ | 27.97 ± 0.30** (213/34) | 27.41 ± 0.28 (178/29) | 26.57 ± 0.45* (166/28) | 27.19 ± 0.44 (173/29) | 16.91 ± 0.44** (117/26)
PND 21^g,h^ | 45.85 ± 0.52** (213/34) | 44.84 ± 0.56 (178/29) | 43.27 ± 0.78* (166/28) | 42.91 ± 0.84* (173/29) | 21.64 ± 0.91** (117/26)
Male and Female (g)
PND 1^d,e,f^ | 7.20 ± 0.07** (34) | 7.35 ± 0.07 (29) | 7.22 ± 0.09 (28) | 6.96 ± 0.09* (29) | 6.29 ± 0.10** (26)
PND 4^g,h^ | 10.33 ± 0.11** (422/34) | 10.28 ± 0.14 (348/29) | 10.47 ± 0.16 (348/28) | 10.00 ± 0.17 (352/29) | 8.51 ± 0.16** (258/26)
PND 7^g,h^ | 14.66 ± 0.19** (422/34) | 14.32 ± 0.23 (346/29) | 14.36 ± 0.26 (348/28) | 14.05 ± 0.22 (347/29) | 11.10 ± 0.20** (257/26)
PND 14^g,h^ | 28.52 ± 0.28** (418/34) | 27.91 ± 0.32 (344/29) | 27.23 ± 0.45* (347/28) | 27.74 ± 0.40 (339/29) | 17.14 ± 0.39** (255/26)
PND 21^g,h^ | 47.18 ± 0.51** (417/34) | 45.90 ± 0.60 (344/29) | 44.51 ± 0.77* (346/28) | 44.08 ± 0.77** (339/29) | 21.79 ± 0.86** (255/26)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

PND = postnatal day.

^a^ Statistical analysis performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons (unless otherwise noted).

^b^ All pups from one dam in the 1,000 ppm group were excluded from all body weight calculations due to that dam having differing litter size counts from PND 1 to PND 4. Additionally, one pup was removed from all body weight calculations due to litter misclassification.

^c^ Two pups from two dams in the 10,000 ppm group were not included in the PND 4 body weight calculations. One pup was removed as an outlier and the other was excluded due to the pup dying on PND 4.

^d^ Data are presented as mean ± standard error (number of litters).

^e^ Each exposure group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^f^ Total pup weight at PND 1 divided by number of live pups at PND 1.

^g^ Data are presented as mean of litter means ± standard error (number of pups/number of litters).

^h^ Individual pup weights first adjusted for live litter size on PND 1.

Concentrations of the DEHP metabolite mono(2-ethylhexyl) phthalate (MEHP) were determined in maternal plasma, amniotic fluid, and fetal tissues collected on GD 18 (Table 7) using validated analytical methods (Appendix E). MEHP concentrations increased proportionally to exposure concentration in dam plasma in groups exposed to lower dietary DEHP concentrations (300 and 1,000 ppm). However, at higher dietary concentrations (3,000 and 10,000 ppm), the increase was greater than proportional to exposure concentration, despite proportional increases in chemical consumption, suggesting potential saturation of clearance pathways of MEHP (Figure 2). MEHP was measured in amniotic fluid and fetuses demonstrating transfer of MEHP across the placental barrier and exposure of the developing conceptus. The concentrations in fetuses were approximately 18%–28% of the plasma concentrations in dams, suggesting gestational transfer was moderate for MEHP, but the rate of transfer of other metabolites was not measured. MEHP was detected in amniotic fluid and fetus samples from control animals, whereas control dam plasma concentrations were below the limit of detection.

Table 7 Summary of Internal Dose Data for Rats in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
n | 5 | 5 | 5 | 4^a^ | 4^b^
Mono(2-ethylhexyl) Phthalate Concentration^c,d^
Gestation Day 18
Dam plasma (ng/mL) | BD^e^ | 630.2 ± 84.7 | 2,000.0 ± 156.9 | 8,950.0 ± 768.4 | 39,800.0 ± 4,192.9
Amniotic fluid (ng/mL)^f^ | 45.6 ± 2.0** | 73.4 ± 2.7** | 123.0 ± 6.2** | 456.8 ± 10.6** | 1,685.0 ± 156.0**
Fetuses (ng/g)^f^ | 53.2 ± 7.7** | 178.8 ± 22.2** | 383.4 ± 18.8** | 1,580.0 ± 105.4** | 8,295.0 ± 813.3**

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BD = below detection; group did not have over 20% of its values above the limit of detection.

^a^ One female in the 3,000 ppm group was found not to be pregnant and was replaced with an additional dam. The replacement dam was also found not to be pregnant, and another replacement dam was not selected.

^b^ Two females in the 10,000 ppm group were found not to be pregnant; one replacement dam was selected and added for analysis.

^c^ Data are presented as mean ± standard error.

^d^ If over 20% of the animals in a group were above the limit of detection (LOD), one-half of the LOD value was substituted for values below the LOD. LOD for dam plasma = 5 ng/mL; LOD for amniotic fluid = 12 ng/mL; LOD for fetuses = 10 ng/g.

^e^ When the vehicle control group did not have over 20% of its values above the LOD, no mean or standard error were calculated and no statistical analysis was performed.

^f^ Statistical analysis performed by the Jonckheere (trend) and the Shirley or Dunn (pairwise) tests.

### Postweaning Phase

Overall, survival at study termination of males and females in exposed groups was commensurate with control groups (Table 8; Figure 3). However, 6 to 7 rats per sex in the 10,000 ppm group died postweaning during the first two weeks of the study period. All but one of these early losses likely resulted from the severely reduced body weights of those animals.

Table 8 Summary of Survival of Male and Female Rats in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Animals Initially in Study | 50 | 49^a^ | 50 | 50 | 50
Moribund | 12 | 9 | 4 | 8 | 7
Natural Deaths | 13 | 7 | 6 | 7 | 14
Animals Surviving to Study Termination | 25^b^ | 33 | 40^b^ | 35 | 29^b^
Percent Probability of Survival at End of Study^c^ | 50.0 | 67.3 | 80.0 | 70.0 | 58.0
Mean Survival (Days)^d^ | 648 | 683 | 713 | 694 | 555
Survival Analysis^e^ | p = 0.171 | p = 0.118N | p = 0.004N | p = 0.059N | p = 0.938N
Female
Animals Initially in Study | 50 | 50 | 50 | 50 | 50
Moribund | 13 | 9 | 9 | 7 | 12
Natural Deaths | 6 | 9 | 7 | 9 | 11
Animals Surviving to Study Termination | 31 | 32 | 34 | 34^f^ | 27
Percent Probability of Survival at End of Study | 62.0 | 64.0 | 68.0 | 68.0 | 54.0
Mean Survival (Days) | 684 | 671 | 679 | 681 | 594
Survival Analysis | p = 0.083 | p = 0.995N | p = 0.693N | p = 0.667N | p = 0.185

^a^ One pup was mis-sexed at the beginning of the study and was removed.

^b^ Includes one animal that died naturally during the last week of the study.

^c^ Kaplan-Meier determinations.

^d^ Mean of litter means of all deaths (uncensored, censored, and study termination).

^e^ The result of the Cox proportional hazards trend test is in the vehicle control column, and the results of the Cox proportional hazards pairwise comparisons with the vehicle control group are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^f^ Includes one animal that died naturally and one animal that was euthanized moribund during the last week of the study.

Figure 3

Kaplan-Meier Survival Curves for Rats Exposed to Di(2-ethylhexyl) Phthalate in the Perinatal and Postweaning Two-year Feed Study

At study termination, group mean body weights for male and female rats in the 300, 1,000, and 3,000 ppm DEHP groups were within 10% of their respective control groups (Table 9, Table 10; Figure 4). During the first 3 (females) or 6 (males) weeks on study postweaning, mean body weights of rats in the 10,000 ppm groups were approximately half that of their respective control groups. Following week 3 (females) or week 6 (males) on study, however, mean body weights of those male and female rats exhibited a moderate recovery, attaining maximum group mean body weights that were 28% and 17% lower, respectively, relative to control animals during the chronic study period. The terminal mean body weights of 10,000 ppm males and females were 30% and 32% lower than those of control animals, respectively. Lower body weights observed in the 10,000 ppm groups at study termination were attributed to reduced body weight gain observed over the duration of the study.

Table 9 Summary of Survival and Mean Body Weights of Male Rats in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

Study Day^a^ | 0 ppm | | 300 ppm | | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Study Day^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 50.8 | 25 | 50.6 | 99.5 | 25 | 49.2 | 96.7 | 25 | 48.9 | 96.1 | 25 | 27.5 | 54.1 | 25
8 | 82.1 | 25 | 80.6 | 98.1 | 25 | 78.5 | 95.6 | 25 | 76.6 | 93.3 | 25 | 35.7 | 43.4 | 23
15 | 127.7 | 25 | 121.3 | 95.0 | 25 | 119.0 | 93.2 | 25 | 117.6 | 92.1 | 25 | 53.5 | 41.9 | 23
22 | 175.0 | 25 | 168.2 | 96.1 | 25 | 165.9 | 94.8 | 25 | 164.6 | 94.1 | 25 | 75.6 | 43.2 | 23
29 | 217.7 | 25 | 214.4 | 98.5 | 25 | 212.6 | 97.7 | 25 | 212.2 | 97.5 | 25 | 101.5 | 46.6 | 23
36 | 262.2 | 25 | 257.7 | 98.3 | 25 | 255.3 | 97.4 | 25 | 257.0 | 98.0 | 25 | 130.3 | 49.7 | 23
43 | 293.6 | 25 | 290.5 | 99.0 | 25 | 285.6 | 97.3 | 25 | 287.4 | 97.9 | 25 | 158.0 | 53.8 | 23
50 | 316.3 | 25 | 314.8 | 99.5 | 25 | 310.3 | 98.1 | 25 | 310.6 | 98.2 | 25 | 186.1 | 58.8 | 23
57 | 333.3 | 25 | 334.7 | 100.4 | 25 | 330.6 | 99.2 | 25 | 327.7 | 98.3 | 25 | 208.2 | 62.5 | 23
64 | 350.8 | 25 | 351.4 | 100.2 | 25 | 347.2 | 98.9 | 25 | 342.9 | 97.7 | 25 | 225.4 | 64.2 | 23
71 | 364.6 | 25 | 365.0 | 100.1 | 25 | 357.4 | 98.0 | 25 | 352.7 | 96.7 | 25 | 239.9 | 65.8 | 23
78 | 375.8 | 25 | 375.0 | 99.8 | 25 | 368.8 | 98.1 | 25 | 364.4 | 97.0 | 25 | 251.2 | 66.8 | 23
85 | 386.3 | 25 | 383.2 | 99.2 | 25 | 379.7 | 98.3 | 25 | 375.0 | 97.1 | 25 | 263.2 | 68.1 | 23
92 | 396.8 | 25 | 391.0 | 98.5 | 25 | 386.4 | 97.4 | 25 | 381.8 | 96.2 | 25 | 271.6 | 68.4 | 23
120 | 427.2 | 25 | 412.5 | 96.6 | 25 | 409.2 | 95.8 | 25 | 398.4 | 93.3 | 25 | 288.7 | 67.6 | 22
148 | 451.3 | 25 | 443.2 | 98.2 | 25 | 436.5 | 96.7 | 25 | 420.6 | 93.2 | 25 | 315.8 | 70.0 | 22
176 | 471.7 | 25 | 464.9 | 98.6 | 25 | 454.3 | 96.3 | 25 | 440.4 | 93.4 | 25 | 332.7 | 70.5 | 22
204 | 483.6 | 25 | 473.0 | 97.8 | 25 | 471.4 | 97.5 | 25 | 454.8 | 94.0 | 25 | 345.8 | 71.5 | 22
232 | 498.1 | 25 | 484.4 | 97.3 | 25 | 484.3 | 97.2 | 25 | 458.4 | 92.0 | 25 | 353.2 | 70.9 | 22
260 | 516.0 | 25 | 508.3 | 98.5 | 25 | 498.2 | 96.6 | 25 | 475.7 | 92.2 | 25 | 364.5 | 70.6 | 22
288 | 524.7 | 25 | 522.1 | 99.5 | 25 | 511.7 | 97.5 | 25 | 488.9 | 93.2 | 25 | 374.3 | 71.3 | 22
316 | 532.7 | 25 | 527.0 | 98.9 | 25 | 520.1 | 97.6 | 25 | 496.6 | 93.2 | 25 | 376.0 | 70.6 | 22
344 | 546.8 | 25 | 528.0 | 96.5 | 25 | 537.0 | 98.2 | 25 | 504.5 | 92.3 | 25 | 384.4 | 70.3 | 22
372 | 555.4 | 25 | 547.9 | 98.7 | 25 | 545.8 | 98.3 | 25 | 510.5 | 91.9 | 25 | 389.2 | 70.1 | 22
400 | 555.2 | 25 | 557.2 | 100.4 | 25 | 551.4 | 99.3 | 25 | 521.6 | 93.9 | 25 | 392.1 | 70.6 | 22
428 | 566.3 | 25 | 563.6 | 99.5 | 25 | 564.7 | 99.7 | 25 | 528.6 | 93.3 | 25 | 400.4 | 70.7 | 22
456 | 576.3 | 25 | 568.6 | 98.7 | 25 | 571.8 | 99.2 | 25 | 533.3 | 92.5 | 25 | 404.9 | 70.3 | 22
484 | 577.8 | 25 | 575.4 | 99.6 | 25 | 579.0 | 100.2 | 25 | 534.8 | 92.6 | 25 | 406.8 | 70.4 | 22
512 | 583.2 | 25 | 589.7 | 101.1 | 25 | 585.6 | 100.4 | 25 | 541.8 | 92.9 | 25 | 411.6 | 70.6 | 22
540 | 584.6 | 25 | 587.1 | 100.4 | 25 | 588.6 | 100.7 | 25 | 546.7 | 93.5 | 25 | 415.1 | 71.0 | 22
568 | 582.9 | 25 | 587.4 | 100.8 | 25 | 596.8 | 102.4 | 25 | 549.6 | 94.3 | 25 | 416.1 | 71.4 | 22
596 | 583.2 | 24 | 598.1 | 102.5 | 24 | 600.8 | 103.0 | 25 | 552.7 | 94.8 | 25 | 417.4 | 71.6 | 22
624 | 592.3 | 22 | 593.5 | 100.2 | 24 | 604.1 | 102.0 | 25 | 551.4 | 93.1 | 25 | 418.5 | 70.7 | 22
652 | 585.7 | 22 | 587.4 | 100.3 | 24 | 610.4 | 104.2 | 25 | 565.4 | 96.5 | 24 | 420.5 | 71.8 | 21
680 | 584.2 | 22 | 590.5 | 101.1 | 23 | 609.3 | 104.3 | 24 | 571.4 | 97.8 | 22 | 416.1 | 71.2 | 20
708 | 588.5 | 20 | 586.9 | 99.7 | 23 | 606.7 | 103.1 | 23 | 556.5 | 94.6 | 22 | 403.0 | 68.5 | 20
EOS | 581.2 | 18 | 585.8 | 100.8 | 23 | 594.5 | 102.3 | 23 | 569.5 | 98.0 | 21 | 408.7 | 70.3 | 20

EOS = end of study; No. of litters = number of litters represented in weight average.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are means of litter means.

Table 10 Summary of Survival and Mean Body Weights of Female Rats in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

Study Day^a^ | 0 ppm | | 300 ppm | | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Study Day^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 49.8 | 25 | 51.5 | 103.3 | 25 | 49.2 | 98.7 | 25 | 48.7 | 97.6 | 25 | 26.0 | 52.1 | 25
8 | 77.5 | 25 | 78.6 | 101.4 | 25 | 75.6 | 97.5 | 25 | 74.3 | 95.9 | 25 | 36.9 | 47.6 | 22
15 | 112.7 | 25 | 111.2 | 98.6 | 25 | 107.9 | 95.7 | 25 | 107.4 | 95.2 | 25 | 53.5 | 47.5 | 22
22 | 141.8 | 25 | 141.7 | 99.9 | 25 | 138.0 | 97.3 | 25 | 137.8 | 97.2 | 25 | 73.1 | 51.5 | 22
29 | 162.1 | 25 | 164.7 | 101.6 | 25 | 159.7 | 98.5 | 25 | 160.7 | 99.1 | 25 | 94.4 | 58.2 | 22
36 | 181.3 | 25 | 187.3 | 103.3 | 25 | 180.5 | 99.6 | 25 | 180.7 | 99.7 | 25 | 114.5 | 63.1 | 22
43 | 193.3 | 25 | 200.7 | 103.8 | 25 | 193.4 | 100.0 | 25 | 196.1 | 101.4 | 25 | 132.4 | 68.5 | 22
50 | 206.7 | 25 | 211.4 | 102.3 | 25 | 205.2 | 99.3 | 25 | 206.5 | 99.9 | 25 | 147.9 | 71.5 | 22
57 | 216.8 | 25 | 223.2 | 103.0 | 25 | 215.7 | 99.5 | 25 | 216.9 | 100.1 | 25 | 161.1 | 74.3 | 22
64 | 224.0 | 25 | 232.0 | 103.6 | 25 | 223.7 | 99.9 | 25 | 224.1 | 100.0 | 25 | 171.9 | 76.8 | 22
71 | 231.0 | 25 | 238.3 | 103.1 | 25 | 230.4 | 99.7 | 25 | 232.2 | 100.5 | 25 | 181.5 | 78.6 | 22
78 | 236.4 | 25 | 242.1 | 102.4 | 25 | 233.7 | 98.9 | 25 | 235.8 | 99.8 | 25 | 188.0 | 79.6 | 22
85 | 240.9 | 25 | 246.2 | 102.2 | 25 | 241.3 | 100.2 | 25 | 241.3 | 100.1 | 25 | 195.1 | 81.0 | 22
92 | 245.6 | 25 | 249.0 | 101.4 | 25 | 245.8 | 100.1 | 25 | 245.4 | 99.9 | 25 | 199.2 | 81.1 | 22
120 | 259.1 | 25 | 259.5 | 100.1 | 25 | 257.8 | 99.5 | 25 | 258.6 | 99.8 | 25 | 212.8 | 82.1 | 22
148 | 268.6 | 25 | 273.3 | 101.8 | 25 | 266.2 | 99.1 | 25 | 269.0 | 100.2 | 25 | 222.0 | 82.7 | 22
176 | 278.4 | 25 | 280.9 | 100.9 | 25 | 274.2 | 98.5 | 25 | 275.9 | 99.1 | 25 | 230.6 | 82.8 | 22
204 | 283.3 | 25 | 282.1 | 99.6 | 25 | 282.1 | 99.6 | 25 | 282.3 | 99.6 | 25 | 232.8 | 82.2 | 22
232 | 290.7 | 25 | 291.7 | 100.4 | 25 | 285.8 | 98.3 | 25 | 286.4 | 98.5 | 25 | 237.1 | 81.6 | 22
260 | 297.0 | 25 | 300.4 | 101.1 | 25 | 290.8 | 97.9 | 25 | 293.7 | 98.9 | 25 | 240.6 | 81.0 | 22
288 | 302.4 | 25 | 303.1 | 100.2 | 25 | 296.8 | 98.1 | 25 | 297.9 | 98.5 | 25 | 244.2 | 80.8 | 22
316 | 301.0 | 25 | 305.3 | 101.4 | 25 | 300.9 | 100.0 | 25 | 302.3 | 100.4 | 25 | 244.9 | 81.4 | 22
344 | 311.2 | 25 | 311.1 | 100.0 | 25 | 306.0 | 98.3 | 25 | 302.0 | 97.0 | 25 | 247.8 | 79.6 | 22
372 | 314.7 | 25 | 319.2 | 101.4 | 25 | 307.2 | 97.6 | 25 | 304.4 | 96.7 | 25 | 247.5 | 78.7 | 22
400 | 320.6 | 25 | 325.9 | 101.6 | 25 | 314.2 | 98.0 | 25 | 311.8 | 97.2 | 25 | 250.0 | 78.0 | 22
428 | 325.4 | 25 | 330.2 | 101.5 | 25 | 320.9 | 98.6 | 25 | 310.6 | 95.5 | 25 | 250.4 | 76.9 | 22
456 | 331.4 | 25 | 335.0 | 101.1 | 25 | 327.5 | 98.8 | 25 | 315.8 | 95.3 | 25 | 251.1 | 75.8 | 22
484 | 339.0 | 25 | 345.3 | 101.9 | 25 | 332.7 | 98.2 | 25 | 326.2 | 96.2 | 25 | 253.4 | 74.8 | 22
512 | 348.5 | 25 | 355.8 | 102.1 | 25 | 344.8 | 98.9 | 25 | 332.6 | 95.4 | 25 | 253.3 | 72.7 | 22
540 | 350.3 | 24 | 344.4 | 98.3 | 24 | 348.1 | 99.4 | 25 | 330.2 | 94.3 | 25 | 256.7 | 73.3 | 22
568 | 358.2 | 24 | 354.9 | 99.1 | 24 | 356.2 | 99.4 | 25 | 335.8 | 93.8 | 24 | 258.5 | 72.2 | 22
596 | 361.9 | 24 | 353.6 | 97.7 | 23 | 357.9 | 98.9 | 24 | 342.5 | 94.6 | 24 | 257.0 | 71.0 | 22
624 | 368.8 | 24 | 361.6 | 98.1 | 23 | 367.2 | 99.6 | 24 | 348.0 | 94.4 | 24 | 253.1 | 68.6 | 21
652 | 378.9 | 24 | 368.8 | 97.3 | 23 | 376.1 | 99.3 | 23 | 351.4 | 92.7 | 24 | 251.4 | 66.3 | 20
680 | 379.7 | 24 | 369.5 | 97.3 | 23 | 379.6 | 100.0 | 23 | 344.5 | 90.7 | 22 | 252.3 | 66.4 | 20
708 | 376.4 | 23 | 359.5 | 95.5 | 21 | 380.1 | 101.0 | 23 | 338.2 | 89.9 | 21 | 252.6 | 67.1 | 19
EOS | 374.3 | 22 | 371.0 | 99.1 | 21 | 391.4 | 104.6 | 23 | 337.4 | 90.1 | 20 | 255.6 | 68.3 | 18

EOS = end of study; No. of litters = number of litters represented in weight average.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are means of litter means.

Figure 4

Growth Curves for Rats Exposed to Di(2-ethylhexyl) Phthalate in the Perinatal and Postweaning Two-year Feed Study

Feed consumption by male and female rats in the 300, 1,000, and 3,000 ppm DEHP groups was commensurate to that of the control groups throughout the study (Table 11, Table 12; Appendix H). Feed consumption was generally lower in the 10,000 ppm male and female rat groups with the largest difference directly following weaning. This finding was restricted to the early time interval and likely resulted from the significantly reduced body size of animals in the highest exposure group. Dietary concentrations of 300, 1,000, 3,000, and 10,000 ppm resulted in average daily doses of approximately 18, 58, 189, and 678 mg/kg/day for males and 18, 62, 196, and 772 mg/kg/day for females (Appendix H).

Table 11 Summary of Feed and Di(2-ethylhexyl) Phthalate Consumption of Male Rats in the Perinatal and Postweaning Two-year Feed Study

Week | 0 ppm | 300 ppm | | 1,000 ppm | | 3,000 ppm | | 10,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 9.7 | 9.8 | 58.2 | 9.5 | 193.2 | 8.8 | 540.0 | 2.5 | 908.5
13 | 25.0 | 24.0 | 18.8 | 24.4 | 64.3 | 25.3 | 202.4 | 21.0 | 797.7
54 | 27.7 | 28.6 | 15.7 | 26.6 | 48.7 | 28.6 | 168.0 | 22.3 | 569.5
102 | 26.6 | 27.6 | 14.1 | 25.0 | 41.3 | 29.0 | 154.4 | 27.4 | 681.4

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of di(2-ethylhexyl) phthalate consumed/kilogram body weight/day.

Table 12 Summary of Feed and Di(2-ethylhexyl) Phthalate Consumption of Female Rats in the Perinatal and Postweaning Two-year Feed Study

Week | 0 ppm | 300 ppm | | 1,000 ppm | | 3,000 ppm | | 10,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 9.1 | 9.2 | 53.6 | 9.0 | 182.9 | 8.8 | 542.5 | 2.7 | 1,076.8
13 | 15.8 | 16.0 | 19.5 | 16.5 | 68.4 | 16.8 | 208.9 | 15.5 | 796.9
54 | 16.9 | 16.6 | 15.6 | 16.5 | 53.6 | 16.9 | 166.6 | 17.6 | 709.8
102 | 20.3 | 20.3 | 17.0 | 21.0 | 56.1 | 23.2 | 204.4 | 22.9 | 899.7

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of di(2-ethylhexyl) phthalate consumed per kilogram body weight per day.

No exposure-related clinical findings were observed in any of the exposed groups (Appendix H).

#### Pathology

This section describes statistically significant or biologically noteworthy changes in the incidences of gross lesions, neoplasms, and/or nonneoplastic lesions of the liver, pancreas, male and female reproductive organs, kidney, heart, bone marrow, and pituitary gland. Summaries of the incidences of neoplasms and nonneoplastic lesions, individual animal neoplasm diagnoses, and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented as supplemental data in Appendix H.

Liver: There were significant increases in the incidences of hepatocellular adenoma (10,000 ppm males and 3,000 ppm females) and carcinoma (10,000 ppm females) relative to control animals and a positive trend in incidence with increasing exposure concentration in males for hepatocellular carcinomas (Table 13). The incidences of hepatocellular adenoma or carcinoma (combined) were significantly increased in the 10,000 ppm male and female groups and in the 3,000 ppm female group relative to control animals. Hepatocellular adenomas were characterized by regions that were sharply demarcated from surrounding liver parenchyma, nodular, and compressing adjacent normal hepatocytes, with loss of normal lobular architecture and an irregular growth pattern. The liver plates typically impinged obliquely on the surrounding liver parenchyma. The hepatocytes within an adenoma generally varied in size. Hepatocellular carcinomas were characterized by one or more of the following features: local infiltrating growth and/or distinct lack of demarcation with the adjacent tissue, the presence of trabeculae composed of multiple layers of hepatocytes, cellular pleomorphism, loss of normal lobular architecture, regions of hemorrhage and/or necrosis, and increased mitotic figures.

Table 13 Incidences of Neoplastic and Nonneoplastic Lesions of the Liver in Male and Female Rats in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
n^a^ | 50 | 49 | 50 | 50 | 49
Hepatocyte, Cytoplasmic Alteration^b^ | 0** | 0 | 1 (1.0)^c^ | 28** (1.3) | 37** (2.6)
Hepatocyte, Hypertrophy | 0** | 0 | 0 | 3 (1.3) | 17** (1.6)
Pigment | 0** | 1 (1.0) | 5* (1.2) | 40** (1.7) | 38** (2.5)
Necrosis | 3** (1.3) | 4 (2.0) | 1 (1.0) | 6 (1.8) | 13* (1.3)
Eosinophilic Focus | 4** | 1 | 7 | 2 | 11
Basophilic Focus | 1** | 1 | 4 | 4 | 17**
Bile Duct Hyperplasia | 13 (1.2) | 18 (1.1) | 13 (1.2) | 21 (1.0) | 15 (1.1)
Hepatocellular Adenoma^d^
Overall rate^e^ | 0/50 (0%) | 1/49 (2%) | 0/50 (0%) | 3/50 (6%) | 8/49 (16%)
Rate per litters^f^ | 0/25 (0%) | 1/25 (4%) | 0/25 (0%) | 3/25 (12%) | 7/25 (28%)
Adjusted rate^g^ | 0% | 2.4% | 0% | 6.7% | 22.3%
Rao-Scott-adjusted Poly-3 test^h^ | p < 0.001 | p = 0.604 | (e) | p = 0.246 | p = 0.018
Hepatocellular Carcinoma^i^
Overall rate | 1/50 (2%) | 0/49 (0%) | 0/50 (0%) | 0/50 (0%) | 3/49 (6%)
Rate per litters | 1/25 (4%) | 0/25 (0%) | 0/25 (0%) | 0/25 (0%) | 3/25 (12%)
Adjusted rate | 2.6% | 0% | 0% | 0% | 8.7%
Rao-Scott-adjusted Poly-3 test | p = 0.038 | p = 0.589N | p = 0.587N | p = 0.587N | p = 0.341
Hepatocellular Adenoma or Carcinoma (Combined)^j^
Overall rate | 1/50 (2%) | 1/49 (2%) | 0/50 (0%) | 3/50 (6%) | 11/49 (22%)
Rate per litters | 1/25 (4%) | 1/25 (4%) | 0/25 (0%) | 3/25 (12%) | 9/25 (36%)
Adjusted rate | 2.6% | 2.4% | 0% | 6.7% | 30.6%
Rao-Scott-adjusted Poly-3 test | p < 0.001 | p = 0.750N | p = 0.565N | p = 0.429 | p = 0.009
Female
n | 49 | 50 | 50 | 50 | 48
Hepatocyte, Cytoplasmic Alteration | 0** | 4* (1.0) | 7** (1.1) | 39** (1.6) | 39** (3.4)
Hepatocyte, Hypertrophy | 0** | 2 (2.0) | 5* (1.6) | 9** (1.6) | 34** (2.4)
Pigment | 0** | 6* (1.0) | 14** (1.1) | 36** (1.6) | 40** (2.6)
Necrosis | 3 (2.0) | 9 (2.3) | 3 (2.3) | 7 (1.9) | 8 (2.3)
Eosinophilic Focus | 3** | 4 | 4 | 7 | 12**
Basophilic Focus | 4** | 5 | 3 | 2 | 10
Bile Duct Hyperplasia | 9 (1.2) | 13 (1.0) | 13 (1.2) | 21* (1.1) | 8 (1.1)
Hepatocellular Adenoma^k^
Overall rate | 1/49 (2%) | 0/50 (0%) | 5/50 (10%) | 9/50 (18%) | 5/48 (10%)
Rate per litters | 1/25 (4%) | 0/25 (0%) | 4/25 (6%) | 7/25 (28%) | 5/25 (20%)
Adjusted rate | 2.4% | 0% | 11.8% | 20.9% | 13.8%
Rao-Scott-adjusted Poly-3 test | p = 0.089 | p = 0.587N | p = 0.170 | p = 0.033 | p = 0.126
Hepatocellular Carcinoma^l^
Overall rate | 0/49 (0%) | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 8/48 (17%)
Rate per litters | 0/25 (0%) | 0/25 (0%) | 0/25 (0%) | 0/25 (0%) | 7/25 (28%)
Adjusted rate | 0% | 0% | 0% | 0% | 21.8%
Rao-Scott-adjusted Poly-3 test | p < 0.001 | (e) | (e) | (e) | p = 0.023
Hepatocellular Adenoma or Carcinoma (Combined)^m^
Overall rate | 1/49 (2%) | 0/50 (0%) | 5/50 (10%) | 9/50 (18%) | 13/48 (27%)
Rate per litters | 1/25 (4%) | 0/25 (0%) | 4/25 (16%) | 7/25 (28%) | 11/25 (44%)
Adjusted rate | 2.4% | 0% | 11.8% | 20.9% | 35.4%
Rao-Scott-adjusted Poly-3 test | p < 0.001 | p = 0.568N | p = 0.158 | p = 0.028 | p = 0.002

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Significantly different (p ≤ 0.05) from the control group by the Rao-Scott-adjusted Poly-3 test; **p ≤ 0.01.

(e) = value of statistic could not be computed.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 2/489 (0.44% ± 0.88%); range: 0% to 2%.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Number of litters with neoplasm-bearing animals per number of litters examined at site.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the control group and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach study termination) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^i^ Historical control incidence: 2/489 (0.45% ± 0.89%); range: 0% to 2%.

^j^ Historical control incidence: 4/489 (0.89% ± 1.06%); range: 0% to 2%.

^k^ Historical control incidence: 15/489 (2.65% ± 2.59%); range: 0% to 8%.

^l^ Historical control incidence: 1/489 (0.22% ± 0.67%); range: 0% to 2%.

^m^ Historical control incidence: 16/489 (2.87% ± 2.8%); range: 0% to 8%.

There were significant increases in the incidences of many nonneoplastic liver lesions in DEHP-exposed groups relative to the control groups (Table 13). The incidences of hepatocellular cytoplasmic alteration were significantly increased in 3,000 and 10,000 ppm males and in all exposed groups of females relative to control animals. There were significant increases in the incidence of hepatocellular hypertrophy in the 10,000 ppm males and in the 1,000, 3,000, and 10,000 ppm females. Significant increases in the incidence of pigment were observed in the 1,000, 3,000, and 10,000 ppm males and in all exposed groups of females. There were significant increases in the incidence of hepatocellular necrosis in the 10,000 ppm males relative to control animals. The incidence of hepatocellular eosinophilic foci was significantly increased in 10,000 ppm females over that of the control group, and a positive trend was seen in males with increasing exposure concentration. The incidence of hepatocellular basophilic foci was significantly increased in the 10,000 ppm males relative to the control group, and a positive trend with increasing exposure occurred in females. There was a significant increase in the incidence of bile duct hyperplasia in 3,000 ppm females compared to control animals.

Hepatocellular cytoplasmic alteration was characterized by hepatocytes that were expanded with eosinophilic granular cytoplasm (Figure 5). A four-grade severity scale reflected the degree of tissue affected in the section of liver that was evaluated histologically: minimal (grade 1), up to 25% of hepatocyte involvement; mild (grade 2), 26% to 50% of hepatocyte involvement; moderate (grade 3), 51% to 75% of hepatocyte involvement; and marked (grade 4), at least 76% of hepatocyte involvement. Hepatocellular hypertrophy often occurred in conjunction with cytoplasmic alteration and/or pigment. Hypertrophy was characterized by enlargement of the hepatocytes. In lesser affected animals, hypertrophy was confined to centrilobular regions, but in more severely affected animals, hypertrophy extended into the midzonal and periportal areas. A four-grade severity scale was used: minimal (grade 1), up to 10% of hepatocyte involvement; mild (grade 2), 11% to 25% of hepatocyte involvement; moderate (grade 3), up to 50% of hepatocyte involvement; and severe (grade 4), >51% of hepatocyte involvement. Hypertrophy was generally centrilobular and often involved only a few cells per lobule. Although hypertrophy was only occasionally observed in males (at the 3,000 and 10,000 ppm exposure concentrations), in females it exhibited a concentration-responsive significant increase in incidence (but not severity) starting at the 1,000 ppm exposure concentration.

Figure 5

Hepatocellular Cytoplasmic Alteration with Pigment in Male Rats Exposed to Di(2-ethylhexyl) Phthalate in the Perinatal and Postweaning Two-year Feed Study (H&E)

Compare normal liver from a male control rat (panel A) to liver from a male rat exposed to 10,000 ppm DEHP (panel B). Hepatocytes are expanded with eosinophilic granular cytoplasm and pigment at 40× magnification.

Pigment only occurred in exposed animals and was characterized by a pale gold-colored pigment within the hepatocellular cytoplasm (Figure 5). A four-grade severity scale was used: minimal (grade 1), up to 30% of hepatocytes contained pigment; mild (grade 2), 31% to 50% of hepatocytes contained pigment; moderate (grade 3), >51% of hepatocytes contained pigment; and marked (grade 4), >51% of hepatocytes contained pigment and the pigment was very dense. Hepatocellular necrosis was characterized by multiple adjacent hepatocytes that were swollen with increased eosinophilia, karyorrhectic nuclear debris, with or without accompanying inflammatory cells. A four-grade severity scale was used: minimal (grade 1), up to three focal areas of necrosis present; mild (grade 2), necrosis in more than three involved regions or up to 25% of the liver; moderate (grade 3), necrosis in 26% to 60% of the liver; and severe (grade 4), necrosis in >61% of the liver.

Eosinophilic and basophilic hepatocellular foci were diagnosed when there was an enlargement of the hepatocytes with increased acidophilic or basophilic staining, respectively, compared with the surrounding normal liver cells. Foci typically had a discrete lesion margin, where attenuated hepatocytes at the lesion margin (compression) involved <70% of the lesion circumference. There was preservation of lobular architecture and absence of cellular atypia. The distinction between large foci (usually eosinophilic or mixed) and hepatocellular adenomas was made on the basis of retention of normal lobular architecture in the foci, greater size of hepatocellular adenomas (usually measuring at least 3 mm), and presence of compression or bulging from the liver surface along >70% of the lesion circumference.

Bile duct hyperplasia was diagnosed when increased numbers of small bile ducts arose in portal regions. The biliary epithelium lining the ducts was well differentiated, forming normal ducts.

Pancreas: In male rats, there were significant increases in the incidences of pancreatic acinar adenoma and pancreatic acinar adenoma or carcinoma (combined) in the 3,000 and 10,000 ppm groups compared to the control group (Table 14). In males, acinar carcinomas were present in the 3,000 and 10,000 ppm groups, but the incidences were not significant (Table 14). In females, acinar adenomas were observed in the 3,000 and 10,000 ppm groups, but the incidences were not significant (Table 14). Pancreatic acinar adenomas were characterized as distinct nodular masses that were not contiguous with the adjacent parenchyma, which were >3 mm in diameter, and that compressed the adjacent tissue; pleomorphism or atypia was rarely present. Pancreatic acinar carcinomas were typically larger than adenomas and frequently exhibited cellular pleomorphism and atypia; invasion or metastasis was pathognomonic. Scirrhous reactions were occasionally present, characterized by dense fibrous or connective tissue. Pancreatic acinar hyperplasias were higher in the 1,000, 3000, and 10,000 ppm male groups and in the 3,000 and 10,000 ppm female groups compared to the control group, but the differences were not significant.

Table 14 Incidences of Neoplastic and Nonneoplastic Lesions of the Pancreas in Male and Female Rats in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
n^a^ | 50 | 49 | 50 | 50 | 49
Acinus, Hyperplasia^b^ | 13 (3.1)^c^ | 9 (2.6) | 16 (3.3) | 25 (3.5) | 15 (3.3)
Acinar Adenoma^d^
Overall rate^e^ | 10/50 (20%) | 7/49 (14%) | 8/50 (16%) | 36/50 (72%) | 22/49 (45%)
Rate per litters^f^ | 8/25 (32%) | 5/25 (20%) | 8/25 (32%) | 24/25 (96%) | 18/25 (72%)
Adjusted rate^g^ | 26% | 16.6% | 16.9% | 77.9% | 62.5%
Rao-Scott-adjusted Poly-3 test^h^ | p < 0.001 | p = 0.209N | p = 0.210N | p < 0.001 | p < 0.001
Acinar Carcinoma^i^
Overall rate | 0/50 (0%) | 0/49 (0%) | 0/50 (0%) | 3/50 (6%) | 1/49 (2%)
Rate per litters | 0/25 (0%) | 0/25 (0%) | 0/25 (0%) | 3/25 (12%) | 1/25 (4%)
Adjusted rate | 0% | 0% | 0% | 6.6% | 2.9%
Rao-Scott-adjusted Poly-3 test | p = 0.290 | (e) | (e) | p = 0.250 | p = 0.534
Acinar Adenoma or Carcinoma (Combined)^j^
Overall rate | 10/50 (20%) | 7/49 (14%) | 8/50 (16%) | 38/50 (76%) | 22/49 (45%)
Rate per litters | 8/25 (32%) | 5/25 (20%) | 8/25 (32%) | 25/25 (100%) | 18/25 (72%)
Adjusted rate | 26% | 16.6% | 16.9% | 81.2% | 62.5%
Rao-Scott-adjusted Poly-3 test | p < 0.001 | p = 0.209N | p = 0.210N | p < 0.001 | p < 0.001
Female
n | 49 | 50 | 50 | 50 | 48
Acinus, Hyperplasia | 0 | 0 | 0 | 2 (1.5) | 3 (2.0)
Acinar Adenoma^k^
Overall rate | 0/49 (0%) | 0/50 (0%) | 0/50 (0%) | 2/50 (4%) | 1/48 (2%)
Rate per litters | 0/25 (0%) | 0/25 (0%) | 0/25 (0%) | 2/25 (8%) | 1/25 (4%)
Adjusted rate | 0% | 0% | 0% | 4.6% | 2.8%
Rao-Scott-adjusted Poly-3 test | p = 0.307 | (e) | (e) | p = 0.366 | p = 0.561
Acinar Carcinoma^l^
Overall rate | 0/49 (0%) | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 0/48 (0%)
Rate per litters | 0/25 (0%) | 0/25 (0%) | 0/25 (0%) | 0/25 (0%) | 0/25 (0%)
Adjusted rate | 0% | 0% | 0% | 0% | 0%
Rao-Scott-adjusted Poly-3 test | –^m^ | – | – | – | –
Acinar Adenoma or Carcinoma (Combined)^n^
Overall rate | 0/49 (0%) | 0/50 (0%) | 0/50 (0%) | 2/50 (4%) | 1/48 (2%)
Rate per litters | 0/25 (0%) | 0/25 (0%) | 0/25 (0%) | 2/25 (8%) | 1/25 (4%)
Adjusted rate | 0% | 0% | 0% | 4.6% | 2.8%
Rao-Scott-adjusted Poly-3 test | p = 0.307 | (e) | (e) | p = 0.366 | p = 0.561

(e) = value of statistic could not be computed.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 60/488 (11.58% ± 9.25%); range: 0% to 28%.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Number of litters with neoplasm-bearing animals per number of litters examined at site.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the control group and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach study termination) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^i^ Historical control incidence: 4/488 (0.8% ± 1.42%); range: 0% to 4%.

^j^ Historical control incidence: 62/488 (12.03% ± 9.16%); range: 0% to 28%.

^k^ Historical control incidence: 0/489.

^l^ Historical control incidence: 0/489.

^m^ Not applicable; no neoplasms in group.

^n^ Historical control incidence: 0/489.

There was a clear morphological continuum from focal acinar hyperplasia to adenoma and to carcinoma. Pancreatic acinar hyperplasia was characterized by circumscribed areas of enlarged acini that were <3 mm in diameter and that were contiguous with the adjacent parenchyma. Severity grades were assigned using a four-grade scale: minimal (grade 1), no more than one lobule was affected and the lesion was smaller than 1 mm; mild (grade 2), lesion was 1 to 2 mm; moderate (grade 3), lesion was 2 to 3 mm; and marked (grade 4), lesion was 3 mm but lacked features of an adenoma, such as compression. Severity grades were increased if multiple lesions were present.

Gross lesions of the reproductive tract: Significantly increased incidences of several genitourinary abnormalities consistent with perturbation of developmental testosterone signaling and Wolffian duct differentiation were evident among 10,000 ppm DEHP-exposed males relative to control animals (Table 15). Small reproductive tissues were noted in 10,000 ppm males, including, but not limited to, the phallus, testes, epididymides, seminal vesicles, levator ani/bulbocavernosus (LABC) muscle, Cowper’s glands, and prostate (Table 15; Appendix H). Findings in the testes (small) were particularly prevalent, occurring in all 10,000 ppm males that survived past the initial 2 weeks of the 2-year study period relative to only two incidences in examined control rats (Table 15). Undescended testes (unilateral or bilateral) were noted in the abdomen in 19 (approximately 39%) rats and the inguinal region in 4 (approximately 8%) rats in the 10,000 ppm group relative to a single incidence of undescended testes in the abdomen (bilateral) in control males. Findings commonly associated with testicular retention in the abdomen, such as the presence of a cranial suspensory ligament (approximately 10%) and extended (>20 mm; approximately 16%) or absent gubernaculum (unilateral or bilateral; approximately 35%), were also significantly increased in the 10,000 ppm males relative to control animals (Table 15). Exposure-related increases in the left and right mean gubernaculum lengths were evident in 10,000 ppm males. Using a nonparametric (rank-based) analysis, a significant increase in the length of the right gubernaculum was observed in 10,000 ppm males. This corresponded to data in which the effect was largely associated with increased right gubernaculum lengths (≥35 mm) in seven males in the 10,000 ppm group compared to five animals with these lengths in the left gubernaculum (Table 15; Appendix H). In addition, there were 18 animals with gubernaculum not present, 12 of which had a bilateral finding. Epididymal anomalies, such as agenesis, are typically seen concomitant with other abnormalities in organs that are developed from Wolffian ducts. Agenesis of all or part of the epididymis (unilateral or bilateral) was observed only in rats in the 10,000 ppm group. Incomplete separation of the prepuce (approximately 14%), cleft phallus (approximately 6%), and/or cleft prepuce (2%) was observed in 10,000 ppm males relative to no incidences in control rats (Table 15).

Table 15 Summary of Gross Lesions in the Reproductive Tract of Male and Female Rats in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Testis^a,b^ | 49 | 49 | 50^c^ | 50 | 49
Size, small^d^ | 2** (2)^e^ | 2 (2) | 4 (4) | 2 (2) | 45** (23)
Size, enlarged (or swelling) | 0 | 0 | 0 | 0 | 1 (1)
Fluid or blood filled | 0 | 1 (1) | 1 (1) | 1 (1) | 1 (1)
Left, abdominal, undescended | 1** (1) | 0 | 0 | 0 | 13* (10)
Left, inguinal, undescended | 0* | 1 (1) | 1 (1) | 0 | 4 (4)
Right, abdominal, undescended | 1** (1) | 0 | 0 | 0 | 18** (14)
Right, inguinal, undescended | 0 | 1 (1) | 1 (1) | 0 | 3 (3)
Right or left; abdominal; undescended | 1** (1) | 0 | 0 | 0 | 19** (14)
Right or left; inguinal; undescended | 0* | 1 (1) | 1 (1) | 0 | 4 (4)
Right or left; abdominal or inguinal; undescended | 1** (1) | 1 (1) | 1 (1) | 0 | 23** (16)
Right, not present | 0 | 0 | 0 | 0 | 1 (1)
Cranial suspensory ligament | 0** | 0 | 0 | 0 | 5 (4)
Epididymis^a,b^ | 49 | 49 | 50^c^ | 50 | 49
Size, small | 0** | 0 | 2 (2) | 0 | 14** (12)
Left, caput, agenesis | 0 | 0 | 0 | 0 | 1 (1)
Left, corpus, agenesis | 0 | 0 | 0 | 0 | 1 (1)
Left, corpus, cauda, or caput, agenesis/not present | 0 | 0 | 0 | 0 | 1 (1)
Right, caput, agenesis | 0** | 0 | 0 | 0 | 4 (4)
Right, cauda, agenesis | 0 | 0 | 0 | 0 | 2 (2)
Right, corpus, agenesis | 0 | 0 | 0 | 0 | 2 (2)
Right, corpus, cauda, or caput, agenesis/not present | 0** | 0 | 0 | 0 | 6 (5)
Right or left, caput, agenesis | 0** | 0 | 0 | 0 | 4 (4)
Right or left, cauda, agenesis | 0 | 0 | 0 | 0 | 2 (2)
Right or left, corpus, agenesis | 0* | 0 | 0 | 0 | 3 (3)
Right or left, corpus, cauda, or caput, agenesis/not present | 0** | 0 | 0 | 0 | 6 (5)
LABC Muscle | 50 | 49 | 50 | 50 | 48
Size, small | 0 | 0 | 0 | 0 | 2 (2)
Cowper’s Glands | 50 | 49 | 50 | 50 | 47
Left, size, small | 0 | 0 | 0 | 0 | 1 (1)
Right, size, small | 0 | 0 | 0 | 0 | 1 (1)
Prostate Glands | 50 | 49 | 50 | 50 | 47
Size, small | 0 | 0 | 0 | 0 | 1 (1)
Seminal Vesicles/Coagulating Glands | 50 | 49 | 50 | 50 | 47
Size, small | 1** (1) | 0 | 1 (1) | 1 (1) | 8 (7)
Phallus^a,b^ | 50 | 49 | 49 | 50 | 49
Size, small | 0* | 0 | 0 | 0 | 3 (3)
Cleft | 0* | 0 | 0 | 0 | 3 (3)
Prepuce^a,b^ | 50 | 49 | 50 | 50 | 49
Cleft | 0 | 0 | 0 | 0 | 1 (1)
Incomplete preputial separation | 0** | 0 | 0 | 0 | 7* (7)
Gubernaculum^a,b^ | 47 | 49 | 49^c^ | 50 | 41
Left, not present | 0** | 0 | 0 | 0 | 15** (12)
Right, not present | 0** | 0 | 0 | 0 | 15** (12)
Right or left, not present | 0** | 0 | 0 | 0 | 18** (14)
Gubernaculum Length^f,g^
Left, length (mm) | 15.32 ± 0.69 47 (25)^h^ | 15.60 ± 0.63 49 (25) | 14.50 ± 0.52 49 (25) | 15.64 ± 0.58 50 (25) | 20.91 ± 1.91 24 (17)^i^
Right, length (mm) | 15.60 ± 0.61* 47 (25) | 15.46 ± 0.57 49 (25) | 14.34 ± 0.52 48 (25) | 15.62 ± 0.44 50 (25) | 24.22 ± 2.61** 24 (16)
Female
Vagina^b^ | 50 | 50 | 50 | 50 | 48
Not patent | 0* | 0 | 0 | 0 | 5 (3)
Phallus^b^ | 50 | 50 | 50 | 50 | 48
Cleft | 0 | 0 | 0 | 2 (1) | 1 (1)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

LABC = levator ani/bulbocavernosus.

^a^ Number of animals examined for each tissue.

^b^ Statistical analysis performed by the Cochran-Armitage test with a Rao-Scott modification for the random effect due to litter.

All trend and pairwise p values are reported as one-sided.

^c^ One animal in the 1,000 ppm group was not examined for right-sided gross lesion in this tissue.

^d^ Number of animals affected given for each observation.

^e^ Number of litters with observations shown in parentheses for F_1_ animals. F_1_ litter incidence based on the number of F_0_ dams.

^f^ Statistical analysis performed using a bootstrapped Jonckheere test for trend, and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons.

^g^ Data are presented as mean ± standard error.

^h^ n = number of animals examined (number of litters represented).

^i^ 15 animals from the 10,000 ppm group were excluded from statistical analysis due to at least one (left or right) of the gubernaculum observations listed as “not present.” An additional two animals from the 10,000 ppm group were excluded from statistical analysis with values listed as “within normal limits,” and eight animals had no data collected.

Limited genitourinary abnormalities were associated with DEHP exposure in female rats. A greater incidence of vaginal nonpatency (approximately 10%) occurred in 10,000 ppm females; in contrast a similar finding was not found in any other exposure group. Additionally, observations of cleft phallus were noted in both the 3,000 ppm (approximately 4%) and 10,000 ppm (approximately 2%) females.

Testis: There were significant increases in germinal epithelium degeneration (includes bilateral), interstitial cell hyperplasia (includes bilateral), and seminiferous tubule dysgenesis (includes bilateral) in the 10,000 ppm group compared to the control group (Table 16). Two of the occurrences of seminiferous tubule dysgenesis were bilateral (Table 16; Appendix H). Germinal epithelium degeneration was recorded when one or more of the following features was present in tubules not adjacent to the rete testis: tubular vacuolation, partial depletion of germ cells, degenerating (multinucleated or apoptotic) germ cells, disordered arrangement of the germ cell layers, or seminiferous tubules completely devoid of germ cells (atrophy) and lined only by Sertoli cells. Germinal epithelium degeneration was scored for severity on a four-grade scale: minimal (grade 1), up to 25% of at least one testis involved; mild (grade 2), 26% to 50% of at least one testis involved; moderate (grade 3), 51% to 75% of at least one testis involved; and marked (grade 4), rare to no normal seminiferous tubules in either testis were present (i.e., remaining seminiferous tubules solely lined by Sertoli cells).

Table 16 Incidences of Neoplastic and Nonneoplastic Lesions of the Testis and Epididymis in Male Rats in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
n^a^ | 49 | 49 | 50 | 50 | 49
Testis
Germinal epithelium, degeneration (includes bilateral)^b,c^ | 16** (1.6)^d^ | 25 (1.6) | 21 (2.0) | 21 (1.5) | 44** (4.0)
Interstitial cell, hyperplasia, focal (includes bilateral) | 4** (2.0) | 3 (2.0) | 6 (2.0) | 5 (1.4) | 30** (2.3)
Seminiferous tubule, dysgenesis (includes bilateral) | 0** | 0 | 0 | 0 | 10* (1.6)
Epididymis
Hypospermia (includes bilateral) | 4** (2.3) | 5 (3.4) | 12 (2.8) | 8 (2.4) | 43** (4.0)
Testis
Interstitial cell, adenoma^e^
Overall rate^f^ | 3/49 (6%) | 1/49 (2%) | 3/50 (6%) | 5/50 (10%) | 5/49 (10%)
Rate per litters^g^ | 3/25 (12%) | 1/25 (4%) | 3/25 (12%) | 5/25 (20%) | 4/25 (16%)
Adjusted rate^h^ | 7.9% | 2.4% | 6.4% | 11.2% | 14.1%
Rao-Scott-adjusted Poly-3 test^i^ | p = 0.097 | p = 0.295N | p = 0.526N | p = 0.461 | p = 0.330

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Significantly different (p ≤ 0.05) from the control group by the Rao-Scott-adjusted Poly-3 test; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Incidence reported is the combination of unilateral and bilateral lesions.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^e^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 19/487 (4.06% ± 4.36%); range: 0% to 14%.

^f^ Number of animals with neoplasm per number of animals necropsied.

^g^ Number of litters with neoplasm-bearing animals per number of litters examined at site.

^h^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^i^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the control group and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach study termination) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

Interstitial cell hyperplasia, defined as focal aggregates of Leydig cells, was scored using a four-grade scale: minimal (grade 1), when only a thin rim of interstitial cells or a cluster of cells one-fourth the size of a normal seminiferous tubule was present; mild (grade 2), when several such areas were present or one cluster was present that was one-half the size of a normal seminiferous tubule; moderate (grade 3), when a cluster three-fourths the size of a normal seminiferous tubule was present; and marked (grade 4), when a cluster of interstitial cells approached the diameter of a normal seminiferous tubule. The interstitial cells involved were frequently elongated and flattened in profile. Interstitial cell adenomas were characterized by regions of increased interstitial cells, described as mostly uniform polyhedral cells with abundant eosinophilic, finely granular, or vacuolated cytoplasm, which exceeded the diameter of three seminiferous tubules. Circumferential compression of adjacent seminiferous tubules was observed occasionally.

Seminiferous tubule dysgenesis only occurred in the highest exposure concentration group (10,000 ppm) and was characterized by seminiferous tubules that were misshapen and contorted, lined by only Sertoli cells, surrounded by a thickened basement membrane, and often accompanied by Leydig cell aggregates (Figure 6). The dysgenesis lesions were commonly associated with an undescended testis but were also identified in scrotal testes. Three of the 10 animals with seminiferous tubule dysgenesis died early, each on day 3 of the study (two were 24 days old and one was 23 days old), and all seminiferous tubule dysgenesis lesions were focal. Focal lesion locations were variable, sometimes being present in sections that did not include the rete testis.

Figure 6

Seminiferous Tubule Dysgenesis in a Male Rat Exposed to Di(2-ethylhexyl) Phthalate in the Perinatal and Postweaning Two-year Feed Study (H&E)

This image highlights the misshapen, convoluted, and anastomosing tubules in a male rat exposed to 10,000 ppm DEHP. Panel B is a higher magnification (20x) of the region within the circle of panel A (4× magnification).

Epididymis: There were significant increases in the incidences of epididymis hypospermia (includes bilateral) in the 10,000 ppm group compared to the control group (Table 16). Epididymis hypospermia was characterized by a reduced density of sperm in the lumen of the epididymal duct, often accompanied by luminal cell debris. It was scored using a four-grade scale: minimal (grade 1), 25% to 50% reduction of spermatozoa; mild (grade 2), 51% to 66% reduction; moderate (grade 3), 67% to 80% reduction; and marked (grade 4), 81% to 100% reduction.

Uterus: A positive trend with increasing exposure concentration in uterus endometrium adenocarcinoma and uterus adenoma, adenocarcinoma, squamous cell carcinoma, or squamous cell papilloma (combined) (Table 17). Uterus endometrium adenocarcinoma typically is poorly circumscribed and invades the myometrium. The neoplastic epithelial cells form solid nests, cords, papillary, or acinar structures that are within, or supported by, stroma.

Table 17 Incidences of Neoplastic Lesions of the Uterus (Including Cervix) in Female Rats in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
n^a^ | 50 | 50 | 50 | 50 | 48
Adenoma^b,c^ | 0 | 1 | 0 | 0 | 0
Adenocarcinoma^d^
Overall rate^e^ | 3/50 (6%) | 0/50 (0%) | 1/50 (2%) | 3/50 (6%) | 6/48 (13%)
Rate per litters^f^ | 3/25 (12%) | 0/25 (0%) | 1/25 (4%) | 3/25 (12%) | 6/25 (24%)
Adjusted rate^g^ | 7% | 0% | 2.4% | 7% | 16.4%
Rao-Scott-adjusted Poly-3 test^h^ | p = 0.008 | p = 0.147N | p = 0.325N | p = 0.653N | p = 0.184
Squamous Cell Carcinoma (Includes Multiple)^i^ | 0 | 1 | 0 | 0 | 1
Squamous Cell Papilloma^j^ | 0 | 0 | 0 | 1 | 0
Adenoma, Adenocarcinoma, Squamous Cell Carcinoma, or Squamous Cell Papilloma (Combined)^k^
Overall rate | 3/50 (6%) | 1/50 (2%) | 1/50 (2%) | 3/50 (6%) | 7/48 (15%)
Rate per litters | 3/25 (12%) | 1/25 (4%) | 1/25 (4%) | 3/25 (12%) | 7/25 (28%)
Adjusted rate | 7% | 2.4% | 2.4% | 7% | 19%
Rao-Scott-adjusted Poly-3 test | p = 0.005 | p = 0.325N | p = 0.317N | p = 0.651N | p = 0.113

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group.

* Significantly different (p ≤ 0.05) from the control group by the Rao-Scott-adjusted Poly-3 test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 1/350 (0.29% ± 0.76%); range: 0% to 2%.

^d^ Historical control incidence: 20/350 (5.71% ± 3.35%); range: 2% to 10%.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Number of litters with neoplasm-bearing animals per number of litters examined at site.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the control group and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach study termination) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^i^ Historical control incidence: 2/350 (0.57% ± 1.51%); range: 0% to 4%.

^j^ Historical control incidence: 0/350.

^k^ Historical control incidence: 23/350 (6.57% ± 3.41%); range: 2% to 10%.

Kidney: There were significant increases in the incidences of nonneoplastic kidney lesions in male and female DEHP-exposed groups relative to the control groups (Table 18). The incidences of papilla edema and papilla epithelium hyperplasia were significantly increased in the 10,000 ppm males and females relative to control animals; there was a significant increase in the incidence of papilla hemorrhage in the 10,000 ppm males. There were significant increases in the incidence of kidney infarct in the 300 and 10,000 ppm males and the 1,000 and 10,000 ppm females. A significant increase in the incidence of renal tubule cyst was observed in the 10,000 ppm female group compared to that of the control group. A positive trend in the incidence of renal tubule dilation occurred with increasing exposure concentration in the females.

Table 18 Incidences of Nonneoplastic Lesions of the Kidney in Male and Female Rats in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
n^a^ | 50 | 49 | 50 | 50 | 49
Papilla, Edema^b^ | 0** | 0 | 0 | 0 | 39** (2.2)^c^
Papilla, Hemorrhage | 0** | 1 (2.0) | 0 | 2 (1.0) | 12** (1.7)
Epithelium, Papilla, Hyperplasia | 9** (1.3) | 4 (1.3) | 4 (1.8) | 3 (1.0) | 17* (1.2)
Infarct | 2** (1.0) | 10* (1.0) | 9 (1.0) | 7 (1.0) | 17** (1.1)
Renal Tubule, Cyst | 9 | 2 | 4 | 7 | 5
Renal Tubule, Dilation | 0 | 0 | 0 | 2 (2.5) | 0
Female
n | 50 | 50 | 50 | 50 | 48
Papilla, Edema | 0** | 0 | 2 (1.5) | 0 | 38** (1.6)
Papilla, Hemorrhage | 0 | 0 | 0 | 0 | 2 (1.0)
Epithelium, Papilla, Hyperplasia | 2** (1.0) | 1 (3.0) | 2 (1.0) | 4 (1.3) | 15** (1.3)
Infarct | 0** | 3 (2.0) | 7* (1.1) | 5 (1.0) | 12** (1.5)
Renal Tubule, Cyst | 0** | 0 | 2 | 0 | 7*
Renal Tubule, Dilation | 0* | 0 | 0 | 0 | 3 (2.7)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant (p ≤ 0.05) from the vehicle control group by the Rao-Scott-adjusted Poly-3 test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Papilla edema (Figure 7) occurred only in exposed animals, was present in most males and females exposed to 10,000 ppm, and was observed in two females exposed to 1,000 ppm DEHP. Papillary edema affected the kidneys bilaterally and was characterized by expansion of the papillary interstitium by fibrillary amphophilic to pale eosinophilic material. Collecting ducts were often dilated and distorted and lined by a continuous layer of thin attenuated epithelium. The dilatation of collecting ducts sometimes extended to include renal tubules within the medulla and/or cortex. Representative sections were stained with Alcian blue, which identifies glycosaminoglycans (GAGs), and with periodic acid-Schiff (PAS) to evaluate basement membrane integrity. The interstitial material stained positively for Alcian blue, confirming that the material contained GAGs. The basement membranes of vascular structures stained intensely positive for PAS throughout the kidney sections and were not compromised in any areas, indicating they were intact. The renal tubules in the cortex and outer medulla stained uniformly and intensely positive for PAS, but there was an abrupt loss of staining at the junction of the outer and inner medulla. Tubules and collecting ducts within the inner medulla and papilla lacked staining for PAS, indicating disruption of the basement membrane of tubules/ducts within this region.

Figure 7

Kidney Papilla Edema in Male and Female Rats Exposed to Di(2-ethylhexyl) Phthalate in the Perinatal and Postweaning Two-year Feed Study (H&E)

Kidney from a control female rat with normal papilla structure (panel A at 4× magnification, panel C at 20× magnification) compared to kidney from a male 10,000 ppm rat with papillary edema (panel B at 4× magnification, panel D at 20× magnification). This lesion was characterized by expansion of the papillary interstitium by fibrillary amphophilic to pale eosinophilic material. Collecting ducts were often dilated, distorted, and lined by a continuous layer of thin attenuated epithelium.

Papillary hemorrhage occurred in regions of papillary edema (Figure 8). Papilla epithelium hyperplasia was diagnosed when there was thickening and/or variably sized outgrowths (with clear spaces) of the epithelium overlying the renal papilla (Figure 9). Occasionally, these spaces contained eosinophilic material or cells. Although papillary epithelial hyperplasia is commonly associated with advanced chronic progressive nephropathy (CPN), there was no direct correlation with CPN severity in this study.

Figure 8

Renal Papillary Hemorrhage in a Male Rat Exposed to Di(2-ethylhexyl) Phthalate in the Perinatal and Postweaning Two-year Feed Study (H&E)

This image is an example of mild hemorrhage in a kidney from a 1,000 ppm male rat with moderate papillary edema at 10× magnification.

Figure 9

Renal Papillary Epithelium Hyperplasia in a Male Rat Exposed to Di(2-Ethylhexyl) Phthalate in the Perinatal and Postweaning Two-year Feed Study (H&E)

This image is an example of mild epithelial hyperplasia in a 10,000 ppm male rat with normal low cuboidal lining cells (long arrow) are increased in thickness (arrowhead) at 10× magnification.

Kidney infarct consisted of well-demarcated, wedge-shaped regions characterized by renal interstitial fibrosis and depression of the overlying capsule; lesions extended from the capsular surface into the medulla. Infarcts were scored using a four-grade severity scale: minimal (grade 1), <25% of renal involvement; mild (grade 2), 25% to 50% of renal involvement; moderate (grade 3), 51% to 75% of renal involvement; and marked (grade 4), >75% renal involvement. Renal tubule cysts were characterized by dilated renal tubules lined by cuboidal to thin attenuated epithelial cells. There was a positive trend in renal tubule dilation in females.

Heart: A significant increase in the incidences of heart valve fibrosis and heart valve thrombus occurred in the 10,000 ppm males, relative to the control animals (Table 19). Heart valve fibrosis was diagnosed when valves were expanded by fibrous connective tissue that was more densely eosinophilic than the loose lightly basophilic to amphophilic tissue of a normal heart valve (Figure 10). Severity was scored using a four-grade scale: minimal (grade 1), change was barely detectable to thickening of the valve up to double the normal thickness; mild (grade 2), thickening up to three times the normal thickness, involvement of several portions of the valve, or more than one valve up to double the normal thickness; moderate (grade 3), thickening of several regions of the valve or valves, at least one of which was greater than double the normal thickness of a valve at that location; marked (grade 4) valve fibrosis was not diagnosed. Heart valve thrombus was characterized by fibrin, admixed with variable numbers of blood cells, that covered the cardiac valves. Severity grades were assigned according to the following grading scheme: minimal (grade 1), amount of fibrin and cells was less than the thickness of the widest part of the valve; mild (grade 2), layering upon the valves that could occlude approximately 50% of the valve lumen; moderate (grade 3), lesions that occluded 51% to 80% of the valve lumen; marked (grade 4), lesions that occluded ≥81% of the valve lumen.

Table 19 Incidences of Select Nonneoplastic Lesions of the Heart, Bone Marrow, and Pituitary Gland in Male Rats in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Heart^a^ | 50 | 49 | 50 | 50 | 49
Valve, fibrosis^b^ | 0** | 2 (1.0)^c^ | 1 (2.0) | 3 (1.3) | 11** (1.7)
Valve, thrombus | 0** | 0 | 0 | 0 | 6* (1.8)
Bone Marrow | 50 | 49 | 50 | 50 | 50
Hypercellularity | 21** (2.2) | 17 (1.9) | 29 (1.9) | 34* (1.9) | 36** (2.1)
Pituitary Gland | 50 | 49 | 50 | 50 | 49
Pars distalis, hypertrophy | 3** (1.0) | 7 (1.1) | 5 (1.0) | 15** (1.3) | 37** (2.4)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant (p ≤ 0.05) from the vehicle control group by the Rao-Scott-adjusted Poly-3 test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Figure 10

Heart Valve Fibrosis in a Male Rat Exposed to Di(2-Ethylhexyl) Phthalate in the Perinatal and Postweaning Two-year Feed Study (H&E)

The images show examples of heart valve fibrosis in a 1,000 ppm male at 10× magnification (A) and 20× magnification (B). The lesion was characterized by valves that were expanded by fibrous connective tissue that was more densely eosinophilic than the loose lightly basophilic to amphophilic tissue of a normal heart valve. Cartilaginous metaplasia (arrow) was sometimes associated with the valvular fibrosis.

Bone Marrow: There was a significant increase in the incidence of bone marrow hypercellularity in the 3,000 and 10,000 ppm male groups, relative to the control group (Table 19). Bone marrow hypercellularity was characterized by an increase in one or more hematopoietic cell lines, generally with a decrease in adipocytes.

Pituitary Gland: There was a significant increase in the incidence of pars distalis hypertrophy in the 3,000 and 10,000 ppm males compared to control animals (Table 19). Pars distalis hypertrophy was characterized by clusters of cells that were round, with abundant vacuolated amorphous amphophilic or pale eosinophilic cytoplasm and peripherally compressed nuclei, scattered throughout the pars distalis (Figure 11). A severity grade was assigned based on the numbers of affected cells.

Figure 11

Pituitary Pars Distalis Hypertrophy in Male Rats Exposed to Di(2-ethylhexyl) Phthalate in the Perinatal and Postweaning Two-year Feed Study (H&E)

The images compare normal pars distalis in a control male (panel A) with one from a 10,000 ppm male that is hypertrophied (panel B) and characterized by clusters of cells that are round, with abundant amorphous amphophilic or pale eosinophilic cytoplasm and peripherally compressed nuclei (arrows) at 40× magnification.

The toxicological significance of other lesion findings is unknown as the response was considered either marginal, not dose-responsive, and/or potentially decreased (potentially due to lower body weights) (Appendix H). In males, these lesions included: adrenal cortex focal hyperplasia, adrenal medulla focal hyperplasia, testis polyarteritis nodosa, bilateral testis polyarteritis nodosa, thyroid gland C-cell adenoma, and thyroid gland C-cell adenoma or carcinoma (combined). In females, these lesions included: nose respiratory epithelium hyaline droplet accumulation, ovary atrophy, uterus endometrium squamous metaplasia, mammary gland fibroadenoma, pituitary gland pars distalis, or unspecified site adenoma in females.

## Postweaning-only Study in Rats (Study 2)

Overall, survival at study termination of male and female rats exposed to DEHP was commensurate with or greater than that of control animals (Table 20; Figure 12). Survival to study termination was significantly increased in 10,000 ppm males (approximately 84%) relative to control males (approximately 64%).

Table 20 Summary of Survival of Male and Female Rats in the Postweaning-only Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Animals Initially in Study | 50 | 50 | 50 | 50 | 50
Moribund | 4 | 8 | 2 | 8 | 4
Natural Deaths | 14 | 8 | 9 | 7 | 4
Animals Surviving to Study Termination | 32 | 34^a^ | 39 | 35 | 42
Percent Probability of Survival at End of Study^b^ | 64.0 | 68.0 | 78.0 | 70.0 | 84.0
Mean Survival (Days)^c^ | 675 | 692 | 706 | 696 | 711
Survival Analysis^d^ | p = 0.061N | p = 0.692N | p = 0.139N | p = 0.553N | p = 0.037N
Female
Animals Initially in Study | 50 | 50 | 50 | 50 | 50
Moribund | 9 | 10 | 13 | 9 | 6
Natural Deaths | 8 | 6 | 4 | 7 | 12
Animals Surviving to Study Termination | 33 | 34 | 33^e^ | 34 | 32^f^
Percent Probability of Survival at End of Study | 66.0 | 68.0 | 66.0 | 68.0 | 64.0
Mean Survival (Days) | 691 | 668 | 678 | 700 | 684
Survival Analysis | p = 0.834 | p = 1.000N | p = 1.000 | p = 0.932N | p = 0.904

^a^ Includes one animal that died naturally during the last week of the study.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and study termination).

^d^ The result of the life-table trend test is in the vehicle control column, and the results of the life-table pairwise comparisons with the vehicle control group are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^e^ Includes one animal that died naturally and one animal that was euthanized moribund during the last week of the study.

^f^ Includes one animal that died naturally during the last week of the study.

Figure 12

Kaplan-Meier Survival Curves for Rats Exposed to Di(2-ethylhexyl) Phthalate in the Postweaning-only Two-year Feed Study

At study termination, group mean body weights for the 300, 1,000, and 3,000 ppm DEHP groups were within 6% of control animals in both male and female rats (Table 21, Table 22; Figure 13). Lower body weights were noted in males (approximately 16%) and females (approximately 22%) in the 10,000 ppm groups at the end of study relative to control animals. These effects were attributed to reduced body weight gain relative to control animals, which occurred throughout the study.

Table 21 Summary of Survival and Mean Body Weights of Male Rats in the Postweaning-only Two-year Feed Study of Di(2-ethylhexyl) Phthalate

Study Day^a^ | 0 ppm | | 300 ppm | | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Study Day^a^ | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 138.2 | 50 | 138.5 | 100.2 | 50 | 139.0 | 100.5 | 50 | 138.7 | 100.3 | 50 | 139.3 | 100.8 | 50
8 | 182.5 | 50 | 182.4 | 100.0 | 50 | 184.1 | 100.9 | 50 | 182.3 | 99.9 | 50 | 174.1 | 95.4 | 50
15 | 222.3 | 50 | 225.4 | 101.4 | 50 | 224.7 | 101.1 | 50 | 223.2 | 100.4 | 50 | 215.1 | 96.8 | 50
22 | 253.2 | 50 | 256.9 | 101.5 | 50 | 254.6 | 100.6 | 50 | 253.4 | 100.1 | 50 | 243.0 | 96.0 | 50
29 | 273.8 | 50 | 279.4 | 102.1 | 50 | 275.8 | 100.8 | 50 | 273.1 | 99.8 | 50 | 259.4 | 94.8 | 50
36 | 290.0 | 50 | 296.6 | 102.3 | 50 | 293.0 | 101.0 | 50 | 288.7 | 99.6 | 50 | 271.2 | 93.5 | 50
43 | 303.0 | 50 | 310.6 | 102.5 | 50 | 306.6 | 101.2 | 50 | 301.3 | 99.4 | 50 | 283.8 | 93.7 | 50
50 | 314.9 | 50 | 318.7 | 101.2 | 50 | 316.7 | 100.6 | 50 | 311.8 | 99.0 | 50 | 294.0 | 93.4 | 50
57 | 326.4 | 50 | 326.5 | 100.0 | 50 | 325.9 | 99.9 | 50 | 319.1 | 97.8 | 50 | 301.2 | 92.3 | 50
64 | 337.6 | 50 | 337.4 | 99.9 | 50 | 336.8 | 99.8 | 50 | 328.6 | 97.3 | 50 | 309.5 | 91.7 | 50
71 | 346.3 | 50 | 347.1 | 100.2 | 50 | 345.2 | 99.7 | 50 | 335.4 | 96.9 | 50 | 316.4 | 91.4 | 50
78 | 357.7 | 50 | 354.7 | 99.1 | 50 | 354.3 | 99.0 | 50 | 343.8 | 96.1 | 50 | 323.0 | 90.3 | 50
85 | 365.2 | 50 | 360.9 | 98.8 | 50 | 361.7 | 99.0 | 50 | 346.3 | 94.8 | 50 | 324.2 | 88.8 | 50
92 | 372.1 | 50 | 365.2 | 98.2 | 50 | 366.3 | 98.5 | 50 | 351.0 | 94.3 | 50 | 329.4 | 88.5 | 50
120 | 386.2 | 50 | 388.4 | 100.6 | 50 | 380.2 | 98.4 | 50 | 365.1 | 94.5 | 50 | 341.9 | 88.5 | 50
148 | 404.6 | 50 | 409.5 | 101.2 | 50 | 398.5 | 98.5 | 50 | 385.6 | 95.3 | 50 | 361.1 | 89.3 | 50
176 | 420.8 | 50 | 426.9 | 101.4 | 50 | 415.8 | 98.8 | 50 | 400.2 | 95.1 | 50 | 373.2 | 88.7 | 50
204 | 435.4 | 50 | 435.6 | 100.0 | 50 | 428.4 | 98.4 | 50 | 409.0 | 93.9 | 50 | 375.8 | 86.3 | 50
232 | 443.7 | 50 | 447.1 | 100.8 | 50 | 436.8 | 98.4 | 50 | 412.8 | 93.0 | 50 | 380.5 | 85.8 | 50
260 | 455.5 | 50 | 463.2 | 101.7 | 49 | 451.1 | 99.0 | 50 | 430.5 | 94.5 | 50 | 393.2 | 86.3 | 50
288 | 463.2 | 49 | 468.7 | 101.2 | 48 | 460.0 | 99.3 | 50 | 437.8 | 94.5 | 50 | 396.5 | 85.6 | 50
316 | 475.3 | 49 | 477.8 | 100.5 | 48 | 467.8 | 98.4 | 49 | 444.2 | 93.5 | 50 | 401.4 | 84.4 | 50
344 | 478.3 | 49 | 489.5 | 102.3 | 48 | 477.9 | 99.9 | 48 | 448.0 | 93.7 | 49 | 406.9 | 85.1 | 50
372 | 481.2 | 49 | 490.2 | 101.9 | 48 | 481.6 | 100.1 | 48 | 457.6 | 95.1 | 48 | 412.7 | 85.8 | 50
400 | 499.7 | 48 | 508.9 | 101.8 | 48 | 492.3 | 98.5 | 48 | 468.2 | 93.7 | 48 | 420.6 | 84.2 | 50
428 | 508.5 | 48 | 510.8 | 100.5 | 48 | 501.2 | 98.6 | 48 | 472.1 | 92.8 | 48 | 422.7 | 83.1 | 49
456 | 507.2 | 47 | 513.9 | 101.3 | 48 | 505.4 | 99.6 | 48 | 476.4 | 93.9 | 48 | 424.2 | 83.6 | 48
484 | 515.8 | 46 | 521.1 | 101.0 | 48 | 514.3 | 99.7 | 48 | 481.2 | 93.3 | 48 | 430.8 | 83.5 | 48
512 | 515.5 | 44 | 522.5 | 101.4 | 48 | 511.6 | 99.2 | 48 | 481.9 | 93.5 | 47 | 432.7 | 83.9 | 48
540 | 522.6 | 44 | 519.9 | 99.5 | 48 | 516.3 | 98.8 | 48 | 489.0 | 93.6 | 47 | 435.8 | 83.4 | 48
568 | 525.8 | 42 | 528.0 | 100.4 | 47 | 524.2 | 99.7 | 48 | 490.8 | 93.4 | 47 | 436.0 | 82.9 | 48
596 | 523.6 | 42 | 527.8 | 100.8 | 46 | 524.2 | 100.1 | 48 | 493.7 | 94.3 | 46 | 436.3 | 83.3 | 48
624 | 517.5 | 41 | 536.6 | 103.7 | 44 | 520.8 | 100.6 | 47 | 496.8 | 96.0 | 44 | 435.0 | 84.1 | 46
652 | 525.7 | 38 | 530.6 | 100.9 | 43 | 520.5 | 99.0 | 47 | 501.6 | 95.4 | 42 | 428.5 | 81.5 | 46
680 | 515.6 | 36 | 530.7 | 102.9 | 38 | 522.5 | 101.3 | 43 | 501.8 | 97.3 | 40 | 427.4 | 82.9 | 43
708 | 512.4 | 33 | 537.6 | 104.9 | 38 | 524.9 | 102.4 | 40 | 501.0 | 97.8 | 37 | 430.2 | 83.9 | 42
EOS | 505.9 | 32 | 524.8 | 103.7 | 33 | 520.6 | 102.9 | 39 | 500.9 | 99.0 | 35 | 426.9 | 84.4 | 42

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Table 22 Summary of Survival and Mean Body Weights of Female Rats in the Postweaning-only Two-year Feed Study of Di(2-ethylhexyl) Phthalate

Study Day^a^ | 0 ppm | | 300 ppm | | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Study Day^a^ | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 118.4 | 50 | 121.2 | 102.4 | 50 | 120.2 | 101.6 | 50 | 121.2 | 102.4 | 50 | 119.7 | 101.1 | 50
8 | 141.7 | 50 | 141.0 | 99.5 | 50 | 141.2 | 99.6 | 50 | 144.2 | 101.8 | 50 | 139.3 | 98.3 | 50
15 | 158.6 | 50 | 161.4 | 101.8 | 50 | 158.4 | 99.9 | 50 | 162.4 | 102.4 | 50 | 156.8 | 98.9 | 50
22 | 172.5 | 50 | 177.4 | 102.9 | 50 | 174.7 | 101.3 | 50 | 179.9 | 104.3 | 50 | 170.6 | 98.9 | 50
29 | 185.0 | 50 | 193.2 | 104.4 | 50 | 185.5 | 100.2 | 50 | 189.4 | 102.3 | 50 | 178.3 | 96.3 | 50
36 | 193.7 | 50 | 200.9 | 103.7 | 50 | 194.1 | 100.2 | 50 | 200.0 | 103.2 | 50 | 185.8 | 95.9 | 50
43 | 200.1 | 50 | 207.7 | 103.8 | 50 | 203.0 | 101.5 | 50 | 206.8 | 103.4 | 50 | 191.9 | 95.9 | 50
50 | 205.8 | 50 | 212.4 | 103.2 | 50 | 210.6 | 102.3 | 50 | 210.9 | 102.5 | 50 | 196.0 | 95.3 | 50
57 | 211.4 | 50 | 219.0 | 103.6 | 50 | 217.2 | 102.7 | 50 | 216.0 | 102.2 | 50 | 201.7 | 95.4 | 50
64 | 216.4 | 50 | 221.1 | 102.2 | 50 | 223.0 | 103.0 | 50 | 220.8 | 102.1 | 50 | 205.0 | 94.7 | 50
71 | 220.5 | 50 | 226.4 | 102.7 | 50 | 225.4 | 102.2 | 50 | 225.1 | 102.1 | 50 | 208.3 | 94.5 | 50
78 | 224.9 | 50 | 228.6 | 101.7 | 50 | 230.8 | 102.7 | 50 | 229.7 | 102.1 | 50 | 213.0 | 94.7 | 50
85 | 228.8 | 50 | 231.0 | 100.9 | 50 | 231.8 | 101.3 | 50 | 233.0 | 101.8 | 50 | 215.0 | 94.0 | 50
92 | 233.4 | 50 | 232.7 | 99.7 | 50 | 234.4 | 100.4 | 50 | 233.4 | 100.0 | 50 | 216.8 | 92.9 | 50
120 | 241.1 | 50 | 248.2 | 102.9 | 50 | 240.8 | 99.9 | 50 | 242.7 | 100.6 | 50 | 221.6 | 91.9 | 50
148 | 248.1 | 50 | 255.7 | 103.1 | 50 | 250.7 | 101.1 | 50 | 251.2 | 101.3 | 50 | 229.3 | 92.4 | 50
176 | 253.9 | 50 | 267.2 | 105.2 | 50 | 259.7 | 102.3 | 50 | 258.6 | 101.8 | 50 | 234.5 | 92.4 | 50
204 | 258.3 | 50 | 266.6 | 103.2 | 50 | 261.3 | 101.1 | 49 | 260.8 | 100.9 | 50 | 235.4 | 91.1 | 50
232 | 264.1 | 50 | 276.6 | 104.8 | 50 | 262.1 | 99.3 | 49 | 266.2 | 100.8 | 50 | 236.3 | 89.5 | 50
260 | 265.8 | 50 | 280.1 | 105.4 | 49 | 270.9 | 101.9 | 49 | 269.5 | 101.4 | 50 | 240.7 | 90.5 | 50
288 | 272.7 | 50 | 285.2 | 104.6 | 48 | 271.4 | 99.5 | 48 | 273.2 | 100.2 | 50 | 241.5 | 88.6 | 50
316 | 274.2 | 50 | 289.6 | 105.6 | 48 | 274.0 | 99.9 | 48 | 273.8 | 99.8 | 50 | 241.9 | 88.2 | 50
344 | 279.5 | 50 | 291.4 | 104.3 | 47 | 277.8 | 99.4 | 48 | 278.6 | 99.7 | 50 | 242.5 | 86.8 | 50
372 | 283.3 | 49 | 295.7 | 104.4 | 46 | 282.1 | 99.6 | 48 | 281.3 | 99.3 | 50 | 242.8 | 85.7 | 50
400 | 290.1 | 49 | 301.8 | 104.0 | 46 | 286.3 | 98.7 | 48 | 284.9 | 98.2 | 50 | 244.4 | 84.2 | 50
428 | 295.3 | 49 | 303.2 | 102.7 | 46 | 293.0 | 99.2 | 48 | 291.1 | 98.6 | 49 | 247.7 | 83.9 | 49
456 | 300.7 | 49 | 309.8 | 103.0 | 46 | 296.3 | 98.6 | 47 | 293.5 | 97.6 | 49 | 249.0 | 82.8 | 49
484 | 304.6 | 48 | 305.8 | 100.4 | 44 | 302.5 | 99.3 | 47 | 297.4 | 97.6 | 49 | 252.0 | 82.7 | 47
512 | 308.3 | 47 | 313.1 | 101.6 | 44 | 307.0 | 99.6 | 46 | 302.8 | 98.2 | 49 | 251.7 | 81.6 | 45
540 | 308.6 | 46 | 314.6 | 101.9 | 43 | 316.8 | 102.6 | 46 | 300.2 | 97.3 | 46 | 251.9 | 81.6 | 45
568 | 311.3 | 45 | 324.0 | 104.1 | 42 | 313.8 | 100.8 | 43 | 299.2 | 96.1 | 46 | 253.2 | 81.3 | 45
596 | 315.8 | 43 | 319.2 | 101.1 | 39 | 320.9 | 101.6 | 43 | 303.2 | 96.0 | 46 | 251.5 | 79.6 | 43
624 | 321.7 | 42 | 322.6 | 100.3 | 39 | 327.3 | 101.7 | 42 | 304.4 | 94.6 | 44 | 251.4 | 78.2 | 41
652 | 325.1 | 40 | 325.6 | 100.1 | 38 | 327.3 | 100.7 | 36 | 307.6 | 94.6 | 40 | 247.4 | 76.1 | 37
680 | 324.4 | 36 | 328.8 | 101.4 | 36 | 322.6 | 99.5 | 35 | 311.3 | 96.0 | 38 | 247.3 | 76.2 | 33
708 | 329.5 | 35 | 328.9 | 99.8 | 34 | 334.3 | 101.4 | 35 | 312.0 | 94.7 | 36 | 247.7 | 75.2 | 33
EOS | 322.5 | 33 | 336.3 | 104.3 | 34 | 341.5 | 105.9 | 31 | 312.5 | 96.9 | 34 | 252.0 | 78.1 | 32

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 13

Growth Curves for Rats Exposed to Di(2-ethylhexyl) Phthalate in the Postweaning-only Two-year Feed Study

Feed consumption by male and female rats in the 300, 1,000, 3,000, and 10,000 ppm DEHP groups was commensurate with that of the control group throughout the study with the exception of study week 1, when feed consumption was approximately 21% lower in the 10,000 ppm male and female groups (Table 23, Table 24). This finding might reflect an initial adjustment related to the palatability of feed containing high concentrations (1%) of DEHP. Dietary concentrations of 300, 1,000, 3,000, and 10,000 ppm resulted in average daily doses of approximately 17, 54, 170, and 602 mg/kg/day for males and 17, 60, 177, and 646 mg/kg/day for females (Appendix H).

Table 23 Summary of Feed and Di(2-ethylhexyl) Phthalate Consumption of Male Rats in the Postweaning-only Two-year Feed Study

Week | 0 ppm | 300 ppm | | 1,000 ppm | | 3,000 ppm | | 10,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 20.2 | 20.4 | 44.2 | 20.4 | 146.8 | 19.8 | 428.2 | 15.9 | 1,141.5
13 | 21.6 | 20.2 | 16.8 | 20.2 | 55.9 | 20.5 | 177.6 | 19.3 | 595.3
54 | 27.4 | 26.3 | 16.1 | 26.7 | 55.4 | 26.3 | 172.4 | 24.0 | 581.5
102 | 25.1 | 26.4 | 14.7 | 25.1 | 47.8 | 23.6 | 141.3 | 24.5 | 569.5

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of di(2-ethylhexyl) phthalate consumed/kilogram body weight/day.

Table 24 Summary of Feed and Di(2-ethylhexyl) Phthalate Consumption of Female Rats in the Postweaning-only Two-year Feed Study

Week | 0 ppm | 300 ppm | | 1,000 ppm | | 3,000 ppm | | 10,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 14.5 | 14.5 | 35.9 | 14.2 | 118.1 | 14.6 | 361.5 | 11.5 | 960.6
13 | 14.0 | 13.2 | 17.1 | 14.6 | 63.0 | 14.2 | 182.8 | 13.6 | 632.7
54 | 15.0 | 17.2 | 17.4 | 16.5 | 58.5 | 16.3 | 173.9 | 15.1 | 621.9
102 | 18.1 | 18.3 | 16.7 | 18.8 | 56.2 | 18.6 | 175.5 | 16.9 | 682.2

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of di(2-ethylhexyl) phthalate consumed/kilogram body weight/day.

No exposure-related clinical findings were observed in any of the exposed groups (Appendix H).

### Pathology

This section describes the statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the liver, pancreas, male and female reproductive organs, heart, bone marrow, and pituitary gland. Summaries of the incidences of neoplasms and nonneoplastic lesions, individual animal neoplasm diagnoses, and statistical analyses of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group are presented as supplemental data in Appendix H.

Liver: There were significant increases in the incidences of hepatocellular adenomas (10,000 ppm males and females) and carcinomas (10,000 ppm males) relative to that of control animals and a positive trend in females for hepatocellular carcinomas with increasing exposure concentration (Table 25). The incidence of adenoma or carcinoma (combined) was significantly increased in the 10,000 ppm male and female groups relative to the respective control groups. Hepatocellular adenomas were characterized by regions that were sharply demarcated from surrounding liver parenchyma, nodular, and compressing adjacent normal hepatocytes, with loss of normal lobular architecture and an irregular growth pattern. The liver plates typically impinged obliquely on the surrounding liver parenchyma. The hepatocytes within an adenoma generally varied in size. Hepatocellular carcinomas were characterized by one or more of the following features: local infiltrating growth and/or distinct lack of demarcation with the adjacent tissue, the presence of trabeculae composed of multiple layers of hepatocytes, cellular pleomorphism, loss of normal lobular architecture, regions of hemorrhage and/or necrosis, and increased mitotic figures.

Table 25 Incidences of Neoplastic and Nonneoplastic Lesions of the Liver in Male and Female Rats in the Postweaning-only Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
n^a^ | 50 | 50 | 50 | 50 | 50
Hepatocyte, Cytoplasmic Alteration^b^ | 0** | 1 (2.0)^c^ | 0 | 38** (1.3) | 49** (3.6)
Hepatocyte, Hypertrophy | 0** | 0 | 0 | 2 (1.0) | 6* (1.2)
Pigment | 0** | 0 | 7* (1.0) | 45** (1.8) | 50** (2.5)
Necrosis | 0** | 2 (1.5) | 4 (1.0) | 7* (1.3) | 8** (1.3)
Eosinophilic Focus | 1** | 0 | 4 | 2 | 24**
Clear Cell Focus | 29* | 31 | 33 | 35 | 39
Hepatocellular Adenoma^d^
Overall rate^e^ | 0/50 (0%) | 2/50 (4%) | 0/50 (0%) | 1/50 (2%) | 6/50 (12%)
Adjusted rate^f^ | 0% | 4.5% | 0% | 2.2% | 12.9%
Poly-3 test^g^ | p < 0.001 | p = 0.251 | (e) | p = 0.514 | p = 0.022
Hepatocellular Carcinoma^h^
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 6/50 (12%)
Adjusted rate | 0% | 0% | 0% | 0% | 12.8%
Poly-3 test | p < 0.001 | (e) | (e) | (e) | p = 0.022
Hepatocellular Adenoma or Carcinoma (Combined)^i^
Overall rate | 0/50 (0%) | 2/50 (4%) | 0/50 (0%) | 1/50 (2%) | 12/50 (24%)
Adjusted rate | 0% | 4.5% | 0% | 2.2% | 25.6%
Poly-3 test | p < 0.001 | p = 0.251 | (e) | p = 0.514 | p < 0.001
Female
n | 50 | 50 | 50 | 50 | 49
Hepatocyte, Cytoplasmic Alteration | 0** | 2 (1.0) | 15** (1.1) | 38** (1.3) | 45** (2.8)
Hepatocyte, Hypertrophy | 0** | 0 | 6* (1.2) | 14** (1.0) | 28** (1.3)
Pigment | 3** (1.0) | 0 | 18** (1.1) | 30** (1.3) | 48** (2.5)
Necrosis | 2 (1.0) | 5 (1.8) | 4 (1.5) | 2 (2.5) | 4 (2.0)
Eosinophilic Focus | 7 | 6 | 6 | 3 | 7
Clear Cell Focus | 8 | 10 | 14 | 7 | 5
Hepatocellular Adenoma^j^
Overall rate | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 1/50 (2%) | 13/49 (27%)
Adjusted rate | 0% | 0% | 2.4% | 2.3% | 31.3%
Poly-3 test | p < 0.001 | (e) | p = 0.495 | p = 0.505 | p < 0.001
Hepatocellular Carcinoma^k^
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 2/49 (4%)
Adjusted rate | 0% | 0% | 0% | 0% | 4.9%
Poly-3 test | p = 0.018 | (e) | (e) | (e) | p = 0.226
Hepatocellular Adenoma or Carcinoma (Combined)^l^
Overall rate | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 1/50 (2%) | 14/49 (29%)
Adjusted rate | 0% | 0% | 2.4% | 2.3% | 33.7%
Poly-3 test | p < 0.001 | (e) | p = 0.495 | p = 0.505 | p < 0.001

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Poly-3 test; **p ≤ 0.01.

(e) = value of statistic could not be computed.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 2/489 (0.44% ± 0.88%); range: 0% to 2%.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the vehicle control group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. A negative trend or a lower incidence in an exposure group is indicated by N.

^h^ Historical control incidence: 2/489 (0.45% ± 0.89%); range: 0% to 2%.

^i^ Historical control incidence: 4/489 (0.89% ± 1.06%); range: 0% to 2%.

^j^ Historical control incidence: 15/489 (2.65% ± 2.59%); range: 0% to 8%.

^k^ Historical control incidence: 1/489 (0.22% ± 0.67%); range: 0% to 2%.

^l^ Historical control incidence: 16/489 (2.87% ± 2.8%); range: 0% to 8%.

There were significant increases in the incidences of many nonneoplastic liver lesions in DEHP-exposed groups relative to the control groups (Table 25). The incidence of hepatocellular cytoplasmic alteration was significantly increased in 3,000 and 10,000 ppm males and in 1,000, 3,000, and 10,000 ppm females relative to that of the respective control animals. There were significant increases in the incidence of hepatocellular hypertrophy in the 10,000 ppm males and in the 1,000, 3,000, and 10,000 ppm females. Significant increases in the incidence of liver pigment were observed in the 1,000, 3,000, and 10,000 ppm males and females. There were significant increases in the incidence of liver necrosis in the 3,000 and 10,000 ppm males. There was a significant increase in the incidence of hepatocellular eosinophilic foci in the 10,000 ppm males, and a positive trend in the incidence of hepatocellular clear cell foci in exposed males with increasing exposure concentration.

Hepatocellular cytoplasmic alteration was characterized by hepatocytes that were expanded with eosinophilic granular cytoplasm (see Figure 5 as an example). A four-grade severity scale was used based on degree of tissue affected in the section of liver that was evaluated histologically: minimal (grade 1), up to 25% of hepatocyte involvement; mild (grade 2), 26% to 50% of hepatocyte involvement; moderate (grade 3), 51% to 75% of hepatocyte involvement; and marked (grade 4) at least 76% of hepatocyte involvement. Hepatocellular hypertrophy often occurred in conjunction with cytoplasmic alteration and/or pigment. Hypertrophy was characterized by enlargement of the hepatocytes. In lesser affected animals, hypertrophy was confined to centrilobular regions, but in more severely affected animals, hypertrophy extended into the midzonal and periportal areas. A four-grade severity scale was used: minimal (grade 1), up to 10% of hepatocyte involvement; mild (grade 2), 11% to 25% of hepatocyte involvement; moderate (grade 3), 26% to 50% of hepatocyte involvement; and severe (grade 4), ≥51% of hepatic involvement. Hypertrophy was generally centrilobular and often involved only a few cells per lobule. Although hypertrophy was only occasionally observed in males (at the 3,000 and 10,000 ppm concentrations), in females, its incidence (but not severity) increased significantly with exposure concentrations starting at 1,000 ppm.

Pigment was characterized by a pale gold-colored pigment within the hepatocellular cytoplasm (see Figure 5 as an example). A four-grade severity scale was used: minimal (grade 1), up to 30% of hepatocytes contained pigment; mild (grade 2), 31% to 50% of hepatocytes contained pigment; moderate (grade 3), ≥51% of hepatocytes contained pigment; and marked (grade 4), >51% of hepatocytes contained pigment, and the pigment was very dense. Hepatocellular necrosis was characterized by multiple adjacent hepatocytes that were swollen with increased eosinophilia, karyorrhectic nuclear debris, with or without accompanying inflammatory cells. Necrosis was scored using a four-grade severity scale: minimal (grade 1), up to three focal areas of necrosis present; mild (grade 2), necrosis in up to 25% of the liver; moderate (grade 3), necrosis in 26% to 60% of the liver; and severe (grade 4), necrosis in ≥61% of the liver.

Hepatocellular foci were diagnosed when there was an alteration in the arrangement of hepatocytes involving at least six cells, with a discrete lesion margin, where attenuated hepatocytes at the lesion margin (compression) involved <70% of the lesion circumference. Lobular architecture was preserved in the absence of cellular atypia, and the hepatocytes within the eosinophilic foci were more eosinophilic than those within the surrounding parenchyma. Clear cell foci were characterized by circular or ovoid regions composed of normal-sized or enlarged cells with distinct cytoplasmic clear spaces compared with the surrounding parenchyma. The nuclei were often small and dense, prominent, and centrally located, occasionally exhibiting increased volume. The distinction between large foci (usually eosinophilic) and hepatocellular adenomas was based on retention of normal lobular architecture in the foci, greater size of hepatocellular adenomas (usually measuring at least 3 mm), and presence of compression or bulging of the adenoma from the liver surface along >70% of the lesion circumference.

Pancreas: In male rats, there were significant increases in the incidences of acinar adenoma and acinar adenoma or carcinoma (combined) in the 3,000 and 10,000 ppm groups relative to the control group. There was a significant increase in the incidence of acinar carcinoma in the 10,000 ppm male group (Table 26). In females, there was a positive trend for pancreas acinar adenoma or carcinoma (combined). Pancreatic acinar adenomas were distinct nodular masses that were not contiguous with the adjacent parenchyma, which were >3 mm in diameter, and that compressed the adjacent tissue; pleomorphism or atypia was rarely present. Pancreatic acinar carcinomas were typically larger than adenomas and frequently exhibited cellular pleomorphism and atypia; invasion or metastasis was pathognomonic. Scirrhous reactions were occasionally present, characterized by dense fibrous or connective tissue.

Table 26 Incidences of Neoplastic and Nonneoplastic Lesions of the Pancreas in Male and Female Rats in the Postweaning-only Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
n^a^ | 49 | 50 | 50 | 50 | 50
Acinus, Hyperplasia^b^ | 7** (2.6)^c^ | 8 (2.3) | 9 (1.8) | 24** (3.3) | 26** (3.0)
Acinar Adenoma^d^
Overall rate^e^ | 1/49 (2%) | 4/50 (8%) | 5/50 (10%) | 23/50 (46%) | 30/50 (60%)
Adjusted rate^f^ | 2.4% | 9% | 10.7% | 49.9% | 64%
Poly-3 test^g^ | p < 0.001 | p = 0.202 | p = 0.131 | p < 0.001 | p < 0.001
Acinar Carcinoma^h^
Overall rate | 0/49 (0%) | 1/50 (2%) | 0/50 (0%) | 1/50 (2%) | 5/50 (10%)
Adjusted rate | 0% | 2.3% | 0% | 2.2% | 10.6%
Poly-3 test | p < 0.001 | p = 0.513 | (e) | p = 0.515 | p = 0.043
Acinar Adenoma or Carcinoma (Combined)^i^
Overall rate | 1/49 (2%) | 5/50 (10%) | 5/50 (10%) | 23/50 (46%) | 33/50 (66%)
Adjusted rate | 2.4% | 11.2% | 10.7% | 49.9% | 69.8%
Poly-3 test | p < 0.001 | p = 0.119 | p = 0.131 | p < 0.001 | p < 0.001
Female
n | 50 | 50 | 50 | 50 | 47
Acinus, Hyperplasia | 0** | 1 (2.0) | 1 (1.0) | 1 (1.0) | 5* (3.0)
Acinar Adenoma^j^
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 1/47 (2%)
Adjusted rate | 0% | 0% | 0% | 2.3% | 2.5%
Poly-3 test | (n) | (n) | (n) | (n) | (n)
Acinar Carcinoma^j^
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 1/47 (2%)
Adjusted rate | 0% | 0% | 0% | 0% | 2.5%
Poly-3 test | (n) | (n) | (n) | (n) | (n)
Acinar Adenoma or Carcinoma (Combined)^j^
Overall rate | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 2/47 (4%)
Adjusted rate | 0% | 0% | 0% | 2.3% | 5%
Poly-3 test | p = 0.038 | (e) | (e) | p = 0.505 | p = 0.219

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Poly-3 test; **p ≤ 0.01.

(e) = value of statistic could not be computed; (n) = no statistics were calculated.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 60/488 (11.58% ± 9.25%); range: 0% to 28%.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^g^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the vehicle control group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. A negative trend or a lower incidence in an exposure group is indicated by N.

^h^ Historical control incidence: 4/488 (0.8% ± 1.42%); range: 0% to 4%.

^i^ Historical control incidence: 62/488 (12.03% ± 9.16%); range: 0% to 28%.

^j^ Historical control incidence: 0/489.

There were significant increases in the incidences of pancreatic acinus hyperplasia in male rats in the 3,000 and 10,000 ppm groups relative to the control group. In females, there was a significant increase in the incidence of pancreatic acinus hyperplasia in the 10,000 ppm group. Pancreatic acinus hyperplasia was characterized by circumscribed areas of enlarged acini that were <3 mm in diameter and that were contiguous with the adjacent parenchyma. A four-grade severity scale was used: minimal (grade 1), no more than one lobule was affected, and the lesion was smaller than 1 mm; mild (grade 2), lesion was 1 to 2 mm; moderate (grade 3), lesion was 2 to 3 mm; and marked (grade 4), lesion was 3 mm but lacked features of an adenoma, such as compression. Severity grades were increased if multiple hyperplastic lesions were present within the pancreas.

Testis: There was a positive trend in the incidence of testicular interstitial cell adenoma in male rats (Table 27). Interstitial cell adenomas were characterized by regions of increased Leydig cells, described as mostly uniform polyhedral cells with abundant eosinophilic, finely granular, or vacuolated cytoplasm, which exceeded the diameter of three seminiferous tubules. Circumferential compression of adjacent seminiferous tubules was observed occasionally.

Table 27 Incidences of Neoplastic and Nonneoplastic Lesions of the Testis and Epididymis in Male Rats in the Postweaning-only Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
n^a^ | 50 | 50 | 50 | 50 | 50
Testis
Germinal epithelium, degeneration (includes bilateral)^b,c^ | 31** (1.6)^d^ | 25 (1.7) | 21* (1.5) | 22* (1.6) | 50** (3.6)
Edema (includes bilateral) | 27** (1.3) | 23 (1.1) | 29 (1.1) | 24 (1.2) | 45** (2.7)
Interstitial cell, hyperplasia, focal (includes bilateral) | 1* (3.0) | 1 (3.0) | 0 | 4 (2.0) | 4 (2.3)
Epididymis
Hypospermia (includes bilateral) | 4** (3.8) | 4 (3.5) | 4 (3.3) | 3 (3.7) | 43** (4.0)
Duct, exfoliated germ cell (includes bilateral) | 2** (2.0) | 3 (2.0) | 4 (2.0) | 4 (2.0) | 36** (1.4)
Testis
Interstitial cell, adenoma^e^
Overall rate^f^ | 7/50 (14%) | 3/50 (6%) | 3/50 (6%) | 6/50 (12%) | 15/50 (30%)
Adjusted rate^g^ | 16.7% | 6.8% | 6.5% | 13.4% | 32.2%
Poly-3 test^h^ | p < 0.001 | p = 0.135N | p = 0.119N | p = 0.451N | p = 0.073

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Poly-3 test; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Incidence reported is the combination of unilateral and bilateral lesions.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^e^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 19/487 (4.06% ± 4.36%); range: 0% to 14%.

^f^ Number of animals with neoplasm per number of animals necropsied.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the vehicle control group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. A negative trend or a lower incidence in an exposure group is indicated by N.

There were significant increases in the incidences of germinal epithelium degeneration, bilateral germinal epithelium degeneration, testis edema, and bilateral testis edema in the 10,000 ppm group compared to the control males; there was a positive trend in the incidence of focal interstitial cell hyperplasia (Table 27). Germinal epithelium degeneration was recorded when one or more of the following features was present in tubules not adjacent to the rete testis: tubular vacuolation, partial depletion of germ cells, degenerating (multinucleated or apoptotic) germ cells, and disordered arrangement of the germ cell layers and/or seminiferous tubules completely devoid of germ cells and lined only by Sertoli cells. Germinal epithelium degeneration was scored using a four-grade severity scale: minimal (grade 1), up to 25% of at least one testis involved; mild (grade 2), 26% to 50% of at least one testis involved; moderate (grade 3), 51% to 75% of at least one testis involved; and marked (grade 4), rare to no normal seminiferous tubules in either testis were present (i.e., remaining seminiferous tubules solely lined by Sertoli cells).

Testis edema was characterized by the presence of acellular, finely granular or fibrillar pale eosinophilic material in the interstitium. In most animals, this finding was bilateral. A severity grade was determined by the amount of interstitial fluid. Generally, the severity of edema was higher in testes with reduced numbers of seminiferous tubules, because the interstitial fluid filled the intervening space. In some animals with reduced numbers of seminiferous tubules, however, the testis was collapsed and shrunken, leaving no interstitial space.

Interstitial cell hyperplasia was scored using a four-grade severity scale: minimal (grade 1), when only a thin rim of interstitial cells or a cluster of cells one-fourth the size of a normal seminiferous tubule was present; mild (grade 2), when several such areas were present or one cluster was present that was one-half the size of a normal seminiferous tubule; moderate (grade 3), when a cluster three-fourths the size of a normal seminiferous tubule was present; and marked (grade 4), when a cluster of interstitial cells approached the diameter of a normal seminiferous tubule. The interstitial cells involved were frequently very elongated and flattened in profile.

Epididymis: There were significant increases in the incidences of bilateral hypospermia and bilateral epididymis duct exfoliated germ cell in the 10,000 ppm group relative to the control males (Table 27). Epididymis hypospermia was characterized by a reduced density of sperm in the lumen of the epididymal duct, often accompanied by luminal cell debris. Its severity was scored using a four-grade scale: minimal (grade 1), 25%–50% reduction of spermatozoa; mild (grade 2), 51%–66% reduction; moderate (grade 3), 67%–80% reduction; and marked (grade 4), 81%–100% reduction. The lesion of epididymis duct exfoliated germ cell was characterized by the presence of nondegenerate germ cells and debris in the epididymal lumen. This was often accompanied by depletion of germ cells from the seminiferous epithelium in testes diagnosed with germinal epithelium degeneration.

Uterus: There was a significant increase in the incidence of endometrium adenocarcinoma in the 10,000 ppm group and a positive trend in the incidence of uterine squamous cell papilloma with increasing exposure concentration (Table 28). Uterus adenocarcinomas were typically poorly circumscribed and invaded the myometrium. The neoplastic epithelial cells formed solid nests, cords, papillary, or acinar structures. Uterine squamous cell papillomas were characterized by a neoplasm that arose from the surface epithelium with either a broad base or a delicate stalk. The epithelium was well differentiated and arranged in papillary, glandular, or tubular structures that were lined by cuboidal to columnar cells, one to two cell layers thick. The combined incidence of these was significantly increased in the 10,000 ppm group (Table 28).

Table 28 Incidences of Neoplastic and Nonneoplastic Lesions of the Uterus (Including Cervix) in Female Rats in the Postweaning-only Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
n^a^ | 50 | 50 | 50 | 50 | 49
Inflammation, Chronic^b^ | 2 (2.5)^c^ | 9* (2.0) | 6* (2.5) | 8 (2.0) | 8* (3.0)
Adenoma^d^ | 0 | 1 | 0 | 0 | 0
Adenocarcinoma^e^
Overall rate^f^ | 2/50 (4%) | 2/50 (4%) | 1/50 (2%) | 4/50 (8%) | 10/50 (20%)
Adjusted rate^g^ | 4.7% | 4.9% | 2.4% | 9% | 23.8%
Poly-3 test^h^ | p < 0.001 | p = 0.678 | p = 0.508N | p = 0.352 | p = 0.011
Squamous Cell Carcinoma^i^ | 0 | 1 | 0 | 2 | 1
Squamous Cell Papilloma (Includes Multiple)^j^ | 0* | 0 | 0 | 0 | 2
Adenoma, Adenocarcinoma, Squamous Cell Carcinoma, or Squamous Cell Papilloma (Combined)^k^
Overall rate | 2/50 (4%) | 4/50 (8%) | 1/50 (2%) | 6/50 (12%) | 13/50 (26%)
Adjusted rate | 4.7% | 9.7% | 2.4% | 13.4% | 30.7%
Poly-3 test | p < 0.001 | p = 0.315 | p = 0.508N | p = 0.145 | p < 0.001

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Poly-3 test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 1/350 (0.29% ± 0.76%); range: 0% to 2%.

^e^ Historical control incidence: 20/350 (5.71% ± 3.35%); range: 2% to 10%.

^f^ Number of animals with neoplasm per number of animals necropsied.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the vehicle control group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach study termination. A negative trend or a lower incidence in an exposure group is indicated by N.

^i^ Historical control incidence: 2/350 (0.57% ± 1.51%); range: 0% to 4%.

^j^ Historical control incidence: 0/350.

^k^ Historical control incidence: 23/350 (6.57% ± 3.41%); range: 2% to 10%.

There were significant increases in the incidences of uterine inflammation in the 300, 1,000, and 10,000 ppm groups, compared to the control group (Table 28). Uterine inflammation was characterized by a spectrum of changes from mostly mononuclear cells (recorded as chronic inflammation) to a mixture of mononuclear cells and neutrophils (recorded as chronic active inflammation); both diagnoses were considered a part of the same process.

Heart: There were significant increases in the incidences of heart valve fibrosis and heart valve thrombus in the 10,000 ppm male group relative to the control group (Table 29). Valve fibrosis was diagnosed when valves were expanded by fibrous connective tissue that was more densely eosinophilic than the loose lightly basophilic to amphophilic tissue of a normal heart valve. Heart valve thrombus was characterized by fibrin, admixed with variable numbers of blood cells, which covered the cardiac valves.

Table 29 Incidences of Nonneoplastic Lesions of the Heart, Bone Marrow, and Pituitary Gland in Male Rats in the Postweaning-only Two-year Feed Study of Di(2-ethylhexyl) Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
n^a^ | 50 | 50 | 50 | 50 | 50
Male
Heart
Valve, fibrosis^b^ | 2** (1.5)^c^ | 0 | 0 | 1 (1.0) | 9* (1.9)
Valve, thrombus | 0** | 0 | 0 | 2 (2.5) | 6* (1.8)
Bone Marrow
Hypercellularity | 18** (2.1) | 22 (2.1) | 30* (1.8) | 25 (1.8) | 34** (1.9)
Pituitary Gland
Pars distalis, hypertrophy | 8** (1.0) | 10 (1.2) | 11 (1.2) | 14 (1.1) | 37** (1.9)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Poly-3 test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Bone Marrow: There was a significant increase in the incidence of bone marrow hypercellularity in the 1,000 and 10,000 ppm male groups relative to the control group (Table 29). Bone marrow hypercellularity was characterized by an increase in one or more hematopoietic cell lines, generally with a decrease in adipocytes.

Pituitary Gland: There was a significant increase in the incidence of pars distalis hypertrophy in the 10,000 ppm males compared to the control group (Table 29). Pars distalis hypertrophy was characterized by clusters of cells that were enlarged, with abundant amorphous amphophilic or pale eosinophilic cytoplasm and peripherally compressed nuclei (“signet ring” cells). A severity grade was assigned based on the numbers of affected cells.

The toxicological significance of other lesion findings is unknown as the response was considered either marginal, not dose-responsive, and/or decreased (potentially due to lower body weights). (Appendix H). In males, these lesions included heart cardiomyopathy and parathyroid gland diffuse hyperplasia. In females, these lesions included: heart cardiomyopathy; uterus endometrium metaplasia; mammary gland fibroadenoma; mammary gland fibroma, fibroadenoma, or adenoma; mammary gland fibroma, fibroadenoma, carcinoma, or adenoma; nose, olfactory epithelium, hyaline droplet accumulation; pituitary gland pars distalis adenoma; thyroid gland C-cell hyperplasia; and thyroid gland C-cell adenoma or carcinoma.

## Comparative Carcinogenic Benchmark Dose Analysis

Exposure-related neoplastic lesions were further assessed via benchmark dose (BMD) analyses. Daily doses for each exposure group were calculated using time-weighted averages of postweaning feed consumption and corresponding chemical intake during the 2-year exposure period for each study. All available dichotomous models in U.S. EPA’s BMD Software (BMDS version 3.1.2)^169^ were fit to the adjusted incidence data for assessed neoplastic lesions. Model fit was assessed by a chi-square goodness-of-fit test, visual inspection of the respective plots of observed versus predicted values from the various models, and Akaike information criterion (AIC) values (Appendix F). A benchmark response (BMR) of 0.1, corresponding to a 10% extra risk of a DEHP carcinogenic response, was used to determine benchmark doses. Benchmark doses (i.e., BMD_10_ [BMD corresponding to a 10% extra risk] and BMDL_10_ [95% lower bound on the BMD corresponding to a 10% extra risk]) were determined for incidences of hepatocellular adenoma or carcinoma (combined), pancreatic acinar adenoma or carcinoma (combined), testicular interstitial cell adenoma, and uterine (including cervix) adenoma, adenocarcinoma, squamous cell carcinoma, or squamous cell papilloma (combined). The BMD_10_ and BMDL_10_ were calculated separately for the perinatal and postweaning study (Study 1) and for the postweaning-only study (Study 2).

Higher adjusted incidences of hepatocellular adenoma or carcinoma (combined) occurred in the 3,000 and 10,000 ppm male rats exposed during the perinatal and postweaning periods (6.7% and 30.6%), relative to postweaning-only exposure (2.2% and 25.6%) (Table 30). A probit model provided the best relative model fit for the adjusted rates of hepatocellular adenoma or carcinoma (combined) in the perinatal and postweaning study (Figure 14A). Using this model, a BMD_10_ of 382.90 mg/kg/day was estimated for hepatocellular adenoma or carcinoma (combined) in male rats. A multistage degree 4 model provided the best relative model fit for the adjusted rates of hepatocellular adenoma or carcinoma (combined) in the postweaning-only study (Figure 14B). Using this model, a BMD_10_ of 434.41 mg/kg/day was estimated for hepatocellular adenoma or carcinoma (combined) observed in male rats.

Table 30 Adjusted Incidence Data and Benchmark Dose Modeling for Select Neoplasms in Male Rats in the Two-year Feed Studies of Di(2-Ethylhexyl) Phthalate

Neoplasm | 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm | BMD_10_ (mg/kg/day) | BMDL_10_ (mg/kg/day) | Model
Perinatal and Postweaning Study (Study 1)
DEHP Intake (mg/kg/day) | 0 | 17.6 | 57.5 | 188.5 | 678.3 | – | – | –
Hepatocellular Adenoma or Carcinoma (Combined)^a^ | 2.6%^b^ | 2.4% | 0% | 6.7% | 30.6% | 382.90^c^ | 306.05^c^ | Probit
Pancreatic Acinar Adenoma or Carcinoma (Combined)^d^ | 26% | 16.6% | 16.9% | 81.2% | 62.5% | 85.92^c^ | 56.78^c^ | Dichotomous Hill
Postweaning-only Study (Study 2)
DEHP Intake (mg/kg/day) | 0 | 16.8 | 53.5 | 169.9 | 602.3 | – | – | –
Hepatocellular Adenoma or Carcinoma (Combined)^a^ | 0% | 4.5% | 0% | 2.2% | 25.6% | 434.41 | 263.52 | Multistage degree 4
Pancreatic Acinar Adenoma or Carcinoma (Combined)^d^ | 2.4% | 11.2% | 10.7% | 49.9% | 69.8% | 30.99 | 20.20 | Log-logistic
Testis Interstitial Cell Adenoma^e^ | 16.7% | 6.8% | 6.5% | 13.4% | 32.2% | 366.69 | 164.41 | Multistage degree 4

BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk.

^a^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 4/489 (0.89% ± 1.06%); range: 0% to 2%.

^b^ Percentages represent adjusted incidence rate based on Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ BMD models excluded incidences in the 10,000 ppm group due to the nonmonotonicity of the dose response.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 62/488 (12.03% ± 9.16%); range: 0% to 28%.

^e^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 19/487 (4.06% ± 4.36%); range: 0% to 14%.

Figure 14

Benchmark Dose Modeling Results for Hepatocellular Adenoma or Carcinoma (Combined) in Male Rats

Frequentist (A) probit model (perinatal and postweaning; Study 1) and (B) multistage degree 4 model (postweaning-only; Study 2) with BMR of 10% extra risk for the BMD_10_ and 0.95 lower confidence limit for the BMDL_10_ for the incidence of hepatocellular adenoma or carcinoma (combined) in male rats.

BMR = benchmark response; BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk.

A higher adjusted incidence of hepatocellular adenoma or carcinoma (combined) occurred in 3,000 ppm female rats exposed during the perinatal and postweaning periods (20.9%) relative to postweaning-only exposure (2.3%) (Table 31). A log-logistic model provided the best relative model fit for the adjusted rates of hepatocellular adenoma or carcinoma (combined) in the perinatal and postweaning study (Figure 15A). Using this model, a BMD_10_ of 122.95 mg/kg/day was estimated for hepatocellular adenoma or carcinoma (combined) in female rats. A multistage degree 4 model provided the best relative model fit for the adjusted rates of hepatocellular adenoma or carcinoma (combined) in the postweaning-only study (Figure 15B). Using this model, a BMD_10_ of 383.63 mg/kg/day was estimated for hepatocellular adenoma or carcinoma (combined) in female rats.

Table 31 Adjusted Incidence Data and Benchmark Dose Modeling for Select Neoplasms in Female Rats in the Two-year Feed Studies of Di(2-Ethylhexyl) Phthalate

Neoplasm | 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm | BMD_10_ (mg/kg/day) | BMDL_10_ (mg/kg/day) | Model
Perinatal and Postweaning Study (Study 1)
DEHP Intake (mg/kg/day) | 0 | 17.9 | 61.7 | 195.6 | 772.3 | – | – | –
Hepatocellular Adenoma or Carcinoma (Combined)^a^ | 2.4%^b^ | 0% | 11.8% | 20.9% | 35.4% | 122.95 | 79.74 | Log-logistic
Uterus (Including Cervix) Adenocarcinoma, Adenoma, Squamous Cell Carcinoma, or Squamous Cell Papilloma (Combined)^c^ | 7.0% | 2.4% | 2.4% | 7.0% | 19.0% | 594.19 | 432.23 | Logistic
Postweaning-only Study (Study 2)
DEHP Intake (mg/kg/day) | 0 | 17.2 | 59.5 | 177.1 | 646.3 | – | – | –
Hepatocellular Adenoma or Carcinoma (Combined)^a^ | 0% | 0% | 2.4% | 2.3% | 33.7% | 383.63 | 207.99 | Multistage degree 4
Uterus (Including Cervix) Adenocarcinoma, Adenoma, Squamous Cell Carcinoma, or Squamous Cell Papilloma (Combined)^c^ | 4.7% | 9.7% | 2.4% | 13.4% | 30.7% | 324.15 | 249.01 | Probit

BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk.

^a^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 16/489 (2.87% ± 2.8%); range: 0% to 8%.

^b^ Percentages represent adjusted incidence rate based on Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^c^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 23/350 (6.57% ± 3.41%); range: 2% to 10%.

Figure 15

Benchmark Dose Modeling Results for Hepatocellular Adenoma or Carcinoma (Combined) in Female Rats

Frequentist (A) log-logistic model (perinatal and postweaning; Study 1) and (B) multistage degree 4 model (postweaning-only; Study 2) with BMR of 10% extra risk for the BMD_10_ and 0.95 lower confidence limit for the BMDL_10_ for the incidence of hepatocellular adenoma or carcinoma (combined) in female rats.

BMR = benchmark response; BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk.

A higher adjusted incidence of pancreatic acinar adenoma or carcinoma (combined) occurred in 3,000 ppm male rats exposed during the perinatal and postweaning periods (81.2%), relative to postweaning-only exposure (49.9%); however, incidences in the 10,000 ppm group were similar between the two studies (62.5% versus 69.8%, respectively) (Table 30). A dichotomous Hill model provided the best relative model fit for the adjusted rates of pancreatic acinar adenoma or carcinoma (combined) in the perinatal and postweaning study (Figure 16A). Using this model, a BMD_10_ of 85.92 mg/kg/day was estimated for pancreatic acinar adenoma or carcinoma (combined) in male rats (Table 30). A log-logistic model provided the best relative model fit for the adjusted rates of pancreatic acinar adenoma or carcinoma (combined) in the postweaning-only study (Figure 16B). Using this model, a BMD_10_ of 30.99 mg/kg/day was estimated for pancreatic acinar adenoma or carcinoma (combined) in male rats (Table 30).

Figure 16

Benchmark Dose Modeling Results for Pancreatic Acinar Adenoma or Carcinoma (Combined) in Male Rats

Frequentist (A) dichotomous Hill model (perinatal and postweaning; Study 1) and (B) log-logistic model (postweaning-only; Study 2) with BMR of 10% extra risk for the BMD_10_ and 0.95 lower confidence limit for the BMDL_10_ for the incidence of pancreatic acinar adenoma or carcinoma (combined) in male rats.

BMR = benchmark response; BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk.

The incidences of pancreatic acinar adenoma or carcinoma (combined) in female rats were not amenable to BMD modeling. These lesions are considered rare in female rats and were only observed at adjusted rates up to 5% in any single exposed group across both studies. Therefore, an estimated BMR corresponding to 10% extra risk would be greater than the maximum exposure concentration used in the study.

A higher adjusted incidence of testicular interstitial cell adenoma occurred only in 10,000 ppm male rats exposed during the postweaning period (32.3%), relative to perinatal and postweaning exposure (14.1%) (Table 16, Table 27, Table 32). Although there was no exposure-related response in the testis from the perinatal and postweaning study (Study 1), there was a marginal response in the testis with postweaning-only exposure (Study 2). A multistage degree 4 model provided the best relative model fit for the adjusted rates of testicular interstitial cell adenoma in the postweaning-only study (Table 32; Figure 16; Appendix H). Using this model, a BMD_10_ of 366.69 mg/kg/day was estimated for testicular interstitial cell adenoma in male rats.

Table 32 Incidence Data and Benchmark Dose Modeling Results for Testicular Interstitial Cell Adenoma in Male Rats in the Postweaning-only Two-year Feed Study of Di(2-ethylhexyl) Phthalate

Neoplasm | 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm | BMD_10_ (mg/kg/day) | BMDL_10_ (mg/kg/day) | Model
Postweaning-only Study (Study 2)
n^a^ | 50 | 50 | 50 | 50 | 50
Testicular Interstitial Cell Adenoma^b^
Overall rate^c^ | 7/50 (14%) | 3/50 (6%) | 3/50 (6%) | 6/50 (12%) | 15/50 (30%) | 366.69 | 164.41 | Multistage degree 4
Adjusted rate^d^ | 16.7% | 6.8% | 6.5% | 13.4% | 32.3% | 366.69 | 164.41 | Multistage degree 4
Poly-3 test^e^ | p < 0.001 | p = 0.135N | p = 0.119N | p = 0.451N | p = 0.073 | 366.69 | 164.41 | Multistage degree 4

BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMD_L10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk.

^a^ Number of animals with tissue examined microscopically.

^b^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 19/487 (4.06% ± 4.36%); range: 0% to 14%.

^c^ Number of animals with neoplasm per number of animals necropsied.

^d^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^e^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the vehicle control group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in an exposure group is indicated by N.

Higher adjusted incidences of uterine (including cervix) adenocarcinoma, adenoma, squamous cell carcinoma, or squamous cell papilloma (combined) occurred in 3,000 and 10,000 ppm female rats exposed postweaning-only (13.4% and 30.7%, respectively), relative to exposure during the perinatal and postweaning periods (7% and 19%, respectively) (Table 31). A logistic model provided the best relative model fit for the adjusted rates of uterine neoplasms in the perinatal and postweaning study (Figure 17A). Using this model, a BMD_10_ of 594.19 mg/kg/day was estimated for uterine (including cervix) adenocarcinoma, adenoma, squamous cell carcinoma, or squamous cell papilloma (combined) in female rats (Table 31). A probit model provided the best relative model fit for the adjusted rates of uterine (including cervix) adenocarcinoma, adenoma, squamous cell carcinoma, or squamous cell papilloma (combined) in the postweaning-only study (Figure 17B). Using this model, a BMD_10_ of 324.15 mg/kg/day was estimated for uterine (including cervix) adenocarcinoma, adenoma, squamous cell carcinoma, or squamous cell papilloma (combined) in female rats (Table 31).

Figure 17

Benchmark Dose Modeling Results for Uterine Adenocarcinoma, Adenoma, Squamous Cell Carcinoma, or Squamous Cell Papilloma (Combined) in Female Rats

Frequentist (A) logistic model (perinatal and postweaning; Study 1) and (B) probit model (postweaning-only; Study 2) with BMR of 10% extra risk for the BMD_10_ and 0.95 lower confidence limit for the BMDL_10_ for the incidence of uterine adenocarcinoma, adenoma, squamous cell carcinoma, or squamous cell papilloma (combined) in female rats.

BMR = benchmark response; BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk.

## Genetic Toxicology

DEHP was tested in a variety of genotoxicity assays in vitro and in vivo; most results were negative. DEHP (100–10,000 µg/plate) was tested in six independent bacterial mutation assays using a variety of strains of Salmonella typhimurium (TA100, TA1535, TA1537, TA97, and TA98) and exogenous metabolic activation systems (induced hamster, rat, or mouse liver S9 plus cofactors); results from all bacterial assays were negative (Appendix H).^149^ A single mouse lymphoma gene mutation assay was conducted with DEHP (0.125–3.0 µL/mL) and was negative overall, with and without induced rat liver S9 mix (Appendix H). In three independent studies, no increases in chromosomal aberrations were observed in Chinese hamster ovary (CHO) cells exposed to DEHP (concentrations up to 5,000 µg/mL) with or without induced rat liver S9 (Appendix H).^153^ In a series of nine in vitro sister chromatid exchange (SCE) tests conducted in CHO cells with and without S9, DEHP produced positive responses in four tests, equivocal results in three, and negative results in two (Appendix H).^153^ All of the increases in SCEs judged to be positive or equivocal were observed only in the absence of S9 and at concentrations of DEHP that induced severe cell cycle delay, necessitating longer incubation prior to cell harvesting. The level of cytotoxicity and the extended incubation times might have contributed to the increased SCE levels observed in these seven studies, rather than the SCE reflecting a direct interaction of DEHP with chromosomal DNA. DEHP was tested for induction of sex-linked recessive lethal mutations in male Drosophila melanogaster in two independent studies, one using adult injection and one using larval feeding as the route of exposure; both studies yielded negative results (Appendix H).^158,159^

In vivo, no significant increases in chromosomal aberrations were observed in bone marrow cells of female B6C3F1 mice following exposure to DEHP (3,000–12,000 ppm) in dosed feed for 14 days (Table D-1). DEHP was tested in three independent erythrocyte micronucleus tests and produced varying results. In one test, B6C3F1 female mice were exposed to DEHP (3,000–12,000 ppm) in dosed feed for 14 days; results were judged to be equivocal overall—the response was negative in the immature erythrocyte population (polychromatic erythrocytes) and positive in the mature erythrocyte population (normochromatic erythrocytes) (Table D-2). In a second test, DEHP (1,500–6,000 ppm) induced an equivocal response in male TgAC (FVB/N) mice and a positive response in female TgAC (FVB/N) mice following exposure via dosed feed for 26 weeks (Table D-3). Another 26-week exposure test in TgAC (FVB/N) mice used dermal application of DEHP (100–400 mg/kg/day) and produced negative results in both male and female mice (Table D-4).