# Materials and Methods

## Procurement and Characterization of Di(2-ethylhexyl) Phthalate

Di(2-ethylhexyl) phthalate (DEHP) was obtained from Aldrich Chemical Company Inc. (St. Louis, MO) in a single lot (lot 01514TH) that was used in both 2-year studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at RTI International (Research Triangle Park, NC) (Appendix A). Reports on analyses performed in support of the DEHP studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot 01514TH of the chemical, a clear liquid, was identified as DEHP by infrared (IR) spectroscopy, ^1^H and ^13^C nuclear magnetic resonance (NMR) spectroscopy, gas chromatography (GC) with mass spectrometry (MS) detection, and high-resolution MS (HRMS) (Table A-1). The IR spectrum was in good agreement with a reference spectrum and the structure was consistent with DEHP. Both ^1^H and ^13^C NMR spectra were consistent with reference and predicted spectra. The GC/MS spectra correlated well with the structure of DEHP and the HRMS resulted in measured mass within 0.5 ppm of the theoretical value. The elemental analysis was consistent with the composition of DEHP.

Karl Fisher titration determined the water content of lot 01514TH to be 0.145%. Ultra-performance liquid chromatography (UPLC) with photodiode array (PDA) detection and GC with flame ionization detection (FID) were used to determine a purity of 99.7% (Table A-1). The UPLC/PDA and GC/FID showed a minor peak accounting for 0.2% and 0.3%, respectively, of the total response in the chromatograms. Therefore, bulk purity was determined to be >99%.

Accelerated stability studies confirmed that lot 01514TH was stable for at least 2 weeks when stored in sealed glass vials at 5°C and 60°C. The bulk chemical of lot 01514TH was homogenized by shaking each of the 50 L plastic jugs for approximately 2 minutes and then transferred to 4 L amber glass storage bottles, which were stored at room temperature. Periodic reanalysis of the bulk chemical was performed during the studies by the study laboratory using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection, and no degradation was detected (Table A-1).

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared approximately monthly by mixing DEHP with NIH-07 or NTP-2000 feed (Table A-2). Both the perinatal and postweaning study (Study 1) and the postweaning-only study (Study 2) used dose formulations of 300, 1,000, 3,000, and 10,000 ppm. Formulations were stored in sealed plastic bag-lined containers at room temperature (approximately 25°C) for up to 42 days. The plastic bags used by the study laboratory in the preparation and storage of blank and dosed feed were determined to have no DEHP above the limit of detection of the assay (1.27 ppm).

Homogeneity studies of the dose formulations in a 72-kg NIH-07 feed batch (300 and 10,000 ppm) and in a 92-kg NTP-2000 feed batch (300, 3,000, and 10,000 ppm) were performed prior to animal studies by the study laboratory with HPLC/UV (Table A-1). Formulations were determined to be homogenous and stable for 42 days at room temperature and under simulated dosing conditions.

Periodic analysis of the DEHP dose formulations was conducted by the study laboratory using HPLC/UV to determine purity and concentration (Table A-3, Table A-4). All preadministration dose formulations were within 10% of the target concentrations. For the perinatal and postweaning study (Study 1), all postadministration dose formulations of DEHP were within 10% of target concentrations. In the postweaning-only study (Study 2), one sample collected from the residual feed in the feeder was below 10% of the target concentration (−12.3%). All other postadministration values were within 10% of the target concentrations.

## Animal Source

Time-mated (F_0_) female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) for use in the perinatal and postweaning study (Study 1). Weanling (4 to 5 weeks old) male and female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were also obtained from Envigo for use in the postweaning-only study (Study 2).

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle (Columbus, OH) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health (NIH) and National Toxicology Program (NTP) animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-year Studies

### Exposure Concentration Selection Rationale

Dietary exposure concentrations of 0, 300, 1,000, 3,000, or 10,000 ppm DEHP were selected based on previous data from an NTP multigenerational reproductive assessment by continuous breeding (RACB) study, which included a perinatal exposure paradigm in the Sprague Dawley rat model. In the RACB study, the highest tested exposure concentration (10,000 ppm) was well-tolerated by pregnant dams and did not affect litter size or pup survival to weaning. However, this exposure concentration induced significant numbers of reproductive tract and testicular malformations in the F_1_ male offspring and perturbed developmental androgen signaling as evidenced by decreased anogenital distance (AGD) and delayed attainment of puberty. In a previous NTP cancer bioassay using Fischer 344 (F344) rats, increased incidences of hepatocellular neoplasms occurred at exposure concentrations of 6,000 and 12,000 ppm DEHP. Together, these data suggest that the selected exposure concentrations are likely to induce a carcinogenic response and adequately challenge developmentally exposed test animals. To facilitate comparison of the results of the two 2-year studies, with and without perinatal exposure, both studies used the same exposure concentrations.

### Perinatal and Postweaning Study in Rats (Study 1)

F_0_ female rats were 12 to 14 weeks old upon receipt. Evidence of mating is defined as gestation day (GD) 1; F_0_ females were received on GD 2 and held for 4 days. F_0_ females were randomly assigned to one of five exposure groups on GD 5 (n = 45/group). Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Co., Cedar Knolls, NJ).

F_0_ females were quarantined for 11 days after receipt. Ten nonmated females received with the time-mated females were designated for disease monitoring 11 days after arrival; samples were collected for serological analyses and the rats were euthanized, necropsied, and examined for the presence of disease or parasites. The health of the F_1_ rats was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). Pinworms (Syphacia spp.) were diagnosed in sentinel animals during routine health monitoring evaluations. Infected animals did not display clinical signs and no pathological lesions were noted in relation to the presence of the pinworms. Study animals did not receive medication for potential pinworm infection. Following this finding, NTP, in coordination with the testing laboratory, developed and implemented a successful plan of pinworm containment and eradication. NTP required the testing laboratories to actively monitor animals to ensure the continued exclusion of pinworms from all studies going forward. All other test results were negative.

Beginning on GD 6, F_0_ time-mated female rats were fed diets containing 0, 300, 1,000, 3,000, or 10,000 ppm DEHP throughout gestation and lactation. Groups of 50 F_1_ rats/sex/exposure concentration continued on in the study after weaning and were fed diets containing the same respective DEHP concentration for 2 years.

F_0_ female rats were housed individually during gestation and with their respective litters during lactation. Water and dosed feed were available ad libitum. F_0_ females were weighed on GDs 5, 6, 9, 12, 15, 18, and 21 and on lactation days (LDs) 1, 4, 7, 14, and 21. During gestation, feed consumption was continuously measured over 3-day intervals from GD 6 through GD 21 (GD 6–9, 9–12, 12–15, 15–18, and 18–21). The day of parturition was considered to be LD 0. On apparent GD 26, all time-mated female rats that failed to deliver were euthanized and the uteri were examined and stained for evidence of implantation. Total litter weight and litter weights by sex were collected on postnatal day (PND) 1. Individual F_1_ pups were weighed on PNDs 4, 7, 14, and 21. Clinical observations and survival were evaluated throughout lactation. During lactation, feed consumption was continuously measured over 3-day intervals from LD 1 through LD 21 (LD 1–4, 4–7, 7–10, 10–14, 14–17, 17–21).

Select dams and their litters were removed on GD 18 to quantify mono(2-ethylhexyl) phthalate plasma and tissue concentrations. On GD 18, blood was collected from the retroorbital sinus of randomly selected dams (n = 5 per exposure group). Blood samples were collected in tubes containing K_3_ EDTA (tripotassium ethylene diamine tetraacetic acid), centrifuged, and the plasma harvested. Amniotic fluid was collected and pooled by dam, and each dam’s fetuses were collected and pooled by litter. All samples were flash frozen in liquid nitrogen and stored frozen at approximately −20°C before shipment to RTI International (Research Triangle Park, NC). All samples were analyzed using a validated analytical method (Appendix E).

On PND 4, all litters with surviving pups were retained. Before weaning, two males and two females per litter from 25 litters in the 0, 300, 1,000, and 3,000 ppm groups and from 21 litters in the 10,000 ppm group were randomly assigned to continue on in the 2-year postweaning phase of the study. To complete assignment in the 10,000 ppm group, two male pups and three female pups were selected from two litters, and two male pups and one female pup were selected from two additional litters. After assignments to the 2-year study were complete, 20 pups per sex from the remaining control pups were randomly selected as the sentinel animals. On the day the last litter reached PND 18, litters were randomly selected and F_1_ pups from these litters were randomly selected for the 2-year study. On the day the last litter reached PND 21, dams were removed and the pups were weaned. Weaning marked the beginning of the 2-year chronic phase of the study.

After weaning, F_1_ pups were housed up to two (males) or four (females) per cage. Dosed feed and water were available ad libitum. Feed consumption was measured weekly for the first 13 weeks and at 4-week intervals thereafter. Cages were changed weekly through PND 4, then changed at least twice weekly. Racks were changed and rotated at least every 2 weeks. Further details of animal maintenance are given in Table 1.

Table 1 Experimental Design and Materials and Methods in the Two-year Feed Studies of Di(2-ethylhexyl) Phthalate

Perinatal and Postweaning Study (Study 1) | Postweaning-only Study (Study 2)
Study Laboratory
Battelle (Columbus, OH) | Same as Study 1
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats | Same as Study 1
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) | Same as Study 1
Time Held Before Studies
F_0_ female rats: 4 days | 14 or 15 days
Average Age When Studies Began
F_0_ female rats: 13 to 15 weeks | 6 to 7 weeks
Date of First Exposure
F_0_ female rats: May 20, 2011 | February 17 (males) or 18 (females), 2011
F_1_ rats: June 27 (males) or 28 (females), 2011
Duration of Exposure
F_0_ female rats: GD 6 to LD 21 | 2 years
F_1_: Perinatal plus 2 years
Date of Last Exposure
F_0_ female rats: June 27, 2011 | February 21 (males) or 27 (females), 2013
F_1_ rats: June 27 (males) or July 3 (females), 2013
Necropsy Dates
F_1_ rats: June 24 to 27 (males) or June 28 to July 3 (females), 2013 | February 18 to 21 (males) or February 22 to 27 (females), 2013
Average Age at Necropsy
F_1_ rats: 2 years | 2 years
Size of Study Groups
F_0_ female rats: 45 | 50/sex
F_1_ rats: 50/sex
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights | Same as Study 1
Animals per Cage
F_0_ female rats: 1 (with litter) | 2 (males) or 4 (females)
F_1_ rats: 2 (males) or 4 (females)
Method of Animal Identification
F_0_ female rats: Cage card and tail marking with permanent pen | Cage card and tail tattoo
F_1_ (pups): Limb tattoo
F_1_ rats (2-year study): Cage card and tail tattoo
Diet
Irradiated NIH-07 meal feed (perinatal phase) or irradiated NTP-2000 meal feed (2-year study) (Zeigler Brothers, Inc, Gardners, PA), available ad libitum, changed twice weekly | Irradiated NTP-2000 meal feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed twice weekly
Water
Tap water (Columbus municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as Study 1
Cages
Solid polycarbonate (Lab Products, Inc., Seaford, DE); changed weekly through PND 4, then at least twice weekly; rotated every 2 weeks | Solid polycarbonate (Lab Products, Inc., Seaford, DE); changed twice weekly; rotated every 2 weeks
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed with cage changes | Same as Study 1
Rack Filters
Spun-bonded polyester (Snow Filtration Company, Cincinnati, OH, or National Media Filter Corporation, Olive Branch, MS), changed every 2 weeks | Same as Study 1
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated at least every 2 weeks | Same as Study 1
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Same as Study 1
Exposure Concentrations
0, 300, 1,000, 3,000, and 10,000 ppm in feed | Same as Study 1
Type and Frequency of Observation
F_0_ female rats: Observed twice daily. Weighed on GDs 5, 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 14, and 21. Feed consumption was measured over 3-day intervals from GD 6 to GD 21 and LD 1 to LD 21. F_1_ rats: Observed twice daily. Litter data (total litter weight, litter weights by sex, and litter observations) were recorded on PND 1. Pup survival was evaluated and recorded. Individual pups were weighed on PNDs 4, 7, 14, and 21, weekly for the first 13 weeks after weaning, every 4 weeks thereafter, and at the end of the study. Clinical findings were recorded every 4 weeks beginning on day 36 and at the end of the study. Feed consumption was recorded weekly for the first 13 weeks and at 4-week intervals thereafter. | Observed twice daily. Body weights were recorded initially, weekly for the first 13 weeks, every 4 weeks thereafter, and at the end of the study. Clinical findings were recorded every 4 weeks beginning at week 5 and at the end of the study. Feed consumption was recorded weekly for the first 13 weeks and at 4-week intervals thereafter.
Method of Euthanasia
Carbon dioxide | Same as Study 1
Necropsy
Necropsies were performed on all F_1_ animals. | Necropsies were performed on all animals.
Histopathology
Complete histopathology was performed on all rats. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidneys, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, uterus, and vagina. | Same as Study 1
Internal Dose Assessment
Maternal plasma, amniotic fluid, and fetal (pooled by litter) mono(2-ethylhexyl) phthalate concentrations were measured at GD 18. | None

GD = gestation day; LD = lactation day; PND = postnatal day.

Two diets were utilized in this study: (1) NIH-07 during the perinatal phase, and (2) NTP-2000 during the postweaning phase. The NIH-07 diet is a higher protein diet that supports reproduction and lactation in rodents, whereas the NTP-2000 diet is a lower protein diet that decreases the incidence of chronic nephropathy in adult rats. Information on feed composition and contaminants for both diets is provided in Appendix B.

### Postweaning-only Study in Rats (Study 2)

Male and female rats were 4 to 5 weeks old upon receipt and quarantined for 13 days prior to study start. Rats were randomly assigned to one of five exposure groups (n = 50 rats/sex/exposure group). Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Cedar Knolls, NJ). Rats were 6 to 7 weeks old on the first day of the study and were provided DEHP in dosed feed for 2 years at one of five exposure concentrations (0, 300, 1,000, 3,000, or 10,000 ppm).

Five male and five female rats were designated for disease monitoring 13 days after arrival; samples were collected for serological analyses, and the rats were euthanized, necropsied, and examined for the presence of disease or parasites. The health of the rats was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). Pinworms (Syphacia spp.) were diagnosed in sentinel animals during routine health monitoring evaluations. All other test results were negative.

Rats were housed up to two (males) or four (females) per cage. Water and dosed feed were available ad libitum. Feed consumption was measured weekly for the first 13 weeks and at 4-week intervals thereafter. Cages were changed at least twice weekly. Racks were changed and rotated at least every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is given in Appendix B.

### Clinical Examinations and Pathology

In both of the 2-year studies, animals were observed twice daily for morbidity and moribundity. Animals were weighed initially, weekly for the next 13 weeks, every 4 weeks thereafter, and at study termination. Beginning on study day 36 (Study 1) or study week 5 (Study 2), clinical observations were recorded every 4 weeks and at the end of the studies.

Complete necropsies and microscopic examinations were performed on all F_1_ rats in Study 1 and all rats in Study 2. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin except for eyes, testes, vaginal tunics, and epididymides, which were first fixed in Davidson’s solution or modified Davidson’s solution. Tissues were processed and trimmed, embedded in paraffin, sectioned at a thickness of 4 to 6 μm, and stained with hematoxylin and eosin (H&E) for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. In the original evaluation of the uterus, a transverse section through each uterine horn, approximately 0.5 cm cranial to cervix, was collected for histopathology evaluation. For the residual tissue evaluation of the uterus, all remaining uterine, including the cervix, and vaginal tissue was sectioned longitudinally and examined histologically. Results from the residual uterine evaluation were combined with those from the original, transverse section of uterus. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by quality assessment (QA) pathologists at a pathology laboratory independent of the study laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For both 2-year studies, the QA pathologists evaluated slides from all neoplasms and all potential target organs, which included the liver, pancreas, kidney, heart, bone marrow, and pituitary gland of rats; testes and epididymis of male rats; and the uterus of female rats. Kidney pathology is reported only for Study 1. Additional sex-specific target tissues identified in Study 1 included the prostate glands, gubernacula, phallus, prepuce, seminal vesicles, and vagina.

The QA report and the reviewed slides were submitted to the NTP Pathology Working Group (PWG) coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the QA/PWG coordinators to the PWG for review. The PWG consisted of the QA pathologists and other pathologists experienced in rodent toxicological pathology. The PWG examined the tissues without any knowledge of exposure groups. When the PWG consensus diagnosis differed from that of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^166^ and Boorman et al.^167^ For subsequent analyses of the pathology data, the decision whether or not to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^168^

### Benchmark Dose Analysis

Benchmark doses (BMDs) were calculated using the EPA Benchmark Dose Software (BMDS), version 3.1.2.^169^ and are presented in Appendix F. The dose variable for the models was the amount of DEHP consumed in mg/kg body weight/day (mg/kg/day). Numbers of animals per exposure group were poly-3-adjusted survival numbers. The response variable was the incidence of the endpoint being modeled.

All of the frequentist dichotomous models in the BMDS were used. The logistic, log-probit, and probit models were used with no parameter restrictions. Other models (dichotomous Hill, gamma, log-logistic, multistage, and Weibull) were used with default restrictions on the ranges of some of the parameters, as described in the BMDS User Guide.^170^

The benchmark response (BMR) used in the models was 0.1 (10%) extra risk, with estimated background levels. The benchmark dose lower confidence limit (BMDL) was calculated using a 95% confidence interval. The decision logic used to recommend one model from the fitted models was the default logic.^170^

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^171^ and is presented graphically. Animals surviving to the end of the observation period are treated as censored observations, as are animals dying from unnatural causes within the observation period. Animals dying from natural causes are included in analyses and are treated as uncensored observations. For the postweaning-only study (Study 2), exposure concentration-related trends are identified with Tarone’s life-table test,^172^ and pairwise exposure concentration-related effects are assessed using Cox’s method.^173^ For the perinatal and postweaning study (Study 1), exposure concentration-related trends and pairwise exposure-related effects on survival are assessed using a Cox proportional hazards model^173^ with a random litter effect. All reported p values for the survival analyses are two-sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented as the numbers of animals bearing such lesions at a specific anatomic site. For calculation of incidence rates, the denominator for most neoplasms and all nonneoplastic lesions is the number of animals where the site was examined microscopically. When macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, however, the denominator consists of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominator consists of the number of animals on which a necropsy was performed. Additional study data also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidence

Statistical analyses of neoplasm and nonneoplastic lesion incidence considered two features of the data. Some animals did not survive the entire 2 years of the study, so survival differences between groups had to be considered. Also, up to two animals per sex were randomly selected from each litter to participate in the study, except for the 10,000 ppm group in the perinatal and postweaning study (Study 1) for which additional males and females were needed to populate the study. The statistical analysis of lesion incidence used the Poly-3 test to account for survival differences, with a Rao-Scott adjustment for litter effects, as described below.

The Poly-k test^174-176^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to account for survival differences. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is 1 if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died before terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only on the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^174^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^174^ after an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344 rats and B6C3F1 mice.^177^ Bailer and Portier^174^ showed that the Poly-3 test provided valid results if the true value of k is anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^178^ Poly-3 tests used the continuity correction described by Nam.^179^

Littermates tend to be more like each other than like fetuses/pups in other litters. Failure to account for correlation within litters leads to underestimates of variance in statistical tests, resulting in higher probabilities of Type I errors (“false positives”). Because up to two pups per sex per litter were present in the perinatal and postweaning study (Study 1), the Poly-3 test was modified to accommodate litter effects using the Rao-Scott approach.^180^ The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Poly-3 test as recommended by Fung et al.,^181^ formula ₸_RS2_.

Tests of significance included pairwise comparisons of each exposed group with control groups and a test for an overall exposure concentration-related trend. Continuity-corrected Rao-Scott-adjusted Poly-3 tests were used in the analysis of lesion incidence and reported p values are one-sided. The significance of a lower incidence or negative trend in lesions is approximated as 1 − p with the letter N added (e.g., p = 0.99 is presented as p = 0.01N). For neoplasms and nonneoplastic lesions observed without litter structure (e.g., at the interim evaluation), Poly-3 tests that included the continuity correction, but without adjustment for potential litter effects, were used for trend and pairwise comparisons to the control group.

To evaluate incidence rates by litter, the proportions of litters affected by each lesion type were tested among groups. The Cochran-Armitage trend test and Fisher’s exact test^182^ were used to test for trends and pairwise differences from the control group, respectively.

### Analysis of Continuous Variables

Before statistical analysis, extreme values identified by the outlier test of Dixon and Massey,^183^ for small samples (n < 20), and Tukey’s outer fences method,^184^ for large samples (n ≥ 20), were examined by NTP personnel, and implausible values were eliminated from the analysis. Organ and body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^185^ and Williams.^186,187^ Dam gestational and lactational feed consumption, litter sizes, pup survival, implantations, number of resorptions, and proportions of male pups per litter for all studies were analyzed using the nonparametric multiple comparison methods of Shirley^188^ [as modified by Williams^189^] and Dunn^190^ given that these endpoints typically have skewed distributions. For all quantitative endpoints unaffected by litter structure, the Jonckheere test^191^ was used to assess the significance of exposure concentration-related trends and to determine, at the 0.01 level of significance, whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure concentration-related trend (the Dunnett or Dunn test).

Postweaning body weights were measured on two pups/sex/litter in most cases in the perinatal and postweaning study (Study 1); more than two pups/sex/litter were common in preweaning body weight measurements. The analyses of pup mean body weights and mean body weights adjusted for litter size (described below) of these animals took litter effects into account using a mixed model with litter as a random effect. To adjust for multiple comparisons, a Dunnett-Hsu adjustment was used.^192^ Dam mean body weights during gestation and lactation were analyzed with the parametric multiple comparison procedures of Dunnett^185^ and Williams,^186,187^ depending on whether the Jonckheere test indicated the use of a trend-sensitive test. P values for these analyses are two-sided.

### Analysis of Gestational and Fertility Indices

Cochran-Armitage trend tests were used to test the significance of trends in gestational and fertility indices across exposure groups. Fisher’s exact test was used to conduct pairwise comparisons of each exposed group with the control group. P values for these analyses are two-sided.

### Body Weight Adjustments

To adjust preweaning pup body weights for live litter size, a linear model was fit to body weights as a function of exposure concentration and litter size. The estimated coefficient of litter size was then used to adjust each pup body weight on the basis of the difference between its litter size and the mean litter size. Preweaning pup body weights were adjusted for PND 1 live litter size. After adjustment, mean body weights were analyzed with a linear mixed model with a random litter effect.

### Historical Control Data

The concurrent control group is the most valid comparison to the exposed groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential exposure-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control data must be generally similar. Significant factors that can affect the background incidence of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period,^193-195^ including the concurrent control for comparison across multiple technical reports. In general, the historical control data for a given study includes studies using the same route of administration, and the overall incidence of neoplasms in control animals for all routes of administration are included for comparison, including the current study.

## Quality Assurance Methods

Both the perinatal and postweaning study (Study 1) and the postweaning-only study (Study 2) were conducted in compliance with the Food and Drug Administration Good Laboratory Practice Regulations.^196^ In addition, both study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

A large number of genetic toxicity tests for DEHP were conducted by NTP. The genetic toxicity data presented here are the culmination of several NTP evaluations of DEHP that have not been previously published. The protocols used for the conduct and evaluation of the in vivo chromosomal aberrations and micronucleus tests are described in detail in Appendix D.

The genetic toxicity studies have evolved from an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on numerous considerations, including the molecular structure of the chemical and its observed effects in short-term in vitro and in vivo genetic toxicity tests (structure-activity relationships). The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage on the basis of the relationship between electrophilicity and mutagenicity^197^ and the somatic mutation theory of cancer.^198,199^ It should be noted, however, that not all cancers arise through genotoxic mechanisms.

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^200^ Information from other in vitro genotoxicity assays does not appear to increase the predictivity of the bacterial mutation assay for rodent carcinogenicity, but these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation. Positive results seen in in vivo assays that measure induction of chromosomal damage have been shown to have a high correlation with rodent carcinogenicity.^201^