# Introduction

Figure 1

Di(2-ethylhexyl) Phthalate (CASRN 117-81-7; Chemical Formula: C_24_H_38_O_4_; Molecular Weight: 390.6).

Synonyms: Bis(2-ethylhexyl)phthalate; dioctyl phthalate; phthalic acid di(2-ethylhexyl) ester; bis(2-ethylhexyl) 1,2-benzenedicarboxylate; 1,2-benzenedicarboxylic acid bis(2-ethylhexyl) ester.

Trade names: Platinol DOP; Octoil; Silicol 150; Bisoflex 81; Eviplast 80.

## Chemical and Physical Properties

Di(2-ethylhexyl) phthalate (DEHP) is the diester of phthalic acid and the branched-chain 2-ethylhexanol. DEHP is a pale-yellow to colorless viscous liquid at room temperature and can have a slight odor. DEHP has a boiling point of 384°C, a melting point of −55°C, and a flash point of 215°C.^1^ At 25°C, DEHP has a limited water solubility of approximately 0.3 mg/L and a vapor pressure ranging from 1.42 × 10^−7^ to 9.75 × 10^−6^ mm Hg.^2^ DEHP has an estimated log K_ow_ of 7.6^3^ and is miscible in organic solvents, such as hexane.

## Production, Use, and Human Exposure

DEHP is a widely used member of the phthalate ester chemical class. Phthalates are employed predominantly as plasticizers to provide flexibility in products composed of polyvinyl chloride (PVC) plastic or vinyl chloride resins. DEHP is produced by the esterification of phthalic anhydride with 2-ethylhexanol in the presence of an acid catalyst, such as sulfuric acid or para-toluenesulfonic acid.^4^ DEHP is considered a high-production volume chemical with an estimated 10 to 50 million pounds produced in the United States in 2015, as reported to the U.S. Environmental Protection Agency (EPA),^5^ a production level consistent with annual production reports from 1986 to 2014, indicating that DEHP use remained consistent.

Globally, between 90% and 95% of DEHP is used as a plasticizer in the manufacture of PVC polymers and corresponding products.^6,7^ DEHP is used in a variety of plastic consumer products, including construction materials, shower curtains, garden hoses, floor tiles, automobile upholstery, and food packaging materials. Plastics may contain 1% to 40% DEHP by weight, with materials that exhibit increased softness or flexibility likely containing higher levels of DEHP or other phthalates. DEHP is used in the production of medical devices, such as blood bags, enteral/parenteral nutrition bags, peritoneal dialysis bags, and medical tubing.^8,9^ Because DEHP is not covalently bonded to the PVC polymer, potential exists for DEHP to leach into contact media. Migration from PVC storage bags into collected blood, blood products, and other biological products is likely associated with the lipophilic nature of DEHP.

Exposure to DEHP can occur via numerous pathways, such as contact with DEHP-containing plastic products, consumption of foods packaged in plastics, drinking of well water near waste sites, workplace/indoor inhalation of aerosols or particulates containing DEHP, or exposure during certain medical procedures.^4^ The most common exposure pathway is through ingestion of food contaminated with DEHP, which typically occurs because of contact with plastic packaging materials. Migration efficiency of DEHP into foodstuffs from packaging materials is likely associated with the lipophilic nature of DEHP and the contact surface area with the packing materials. In the United States, average daily DEHP exposure from food is estimated to be 0.3 mg/day with a maximum of 2.0 mg/day per individual.^10^ Higher DEHP concentrations (≥300 μg/kg) have been noted in poultry, cooking oil, and cream-based dairy products relative to other assessed foodstuffs.^11^ In water, DEHP exhibits low solubility, suggesting a lower relative contribution of drinking water to estimated total daily exposure.^12,13^ Additionally, the low vapor pressure of DEHP indicates a limited capacity for DEHP to volatilize into the air; however, it can readily adsorb to dust particles that can then be respired or ingested. Fromm et al. measured concentrations of DEHP in indoor air and vacuum cleaner dust samples.^14^ The median indoor air DEHP concentration was 156 ng/m^3^ (95th percentile, 390 ng/m^3^) and 703.4 mg/kg (95th percentile, 1,542 mg/kg) in dust samples.

Measurable urinary DEHP metabolite concentrations from participants in the National Health and Nutrition Examination Survey (NHANES) indicate widespread exposure to DEHP in the U.S. population, but have been declining over the years.^15^ Urinary concentration (50th percentile) of a DEHP metabolite, mono(2-ethylhexyl) phthalate (MEHP) (2015–2016) was 1.24 μg/g of creatinine (95th percentile, 5.93 μg/g of creatinine).^15^ Using the NHANES data, researchers estimated a median cumulative DEHP exposure of 0.17 μg DEHP/kg body weight/day (μg/kg/day) (95th percentile, 12.0 μg/kg/day).^16^ Urinary concentrations of DEHP and its metabolites are higher in exposed workers relative to unexposed workers and are detected at higher concentrations in postshift relative to preshift samples.^14,17,18^ High exposures have been documented in workers in countries other than the United States and observed in various industries.^19-22^ Newborns and infants may be at risk for higher DEHP exposure relative to the general population due to differences in metabolic capacity, increased food, water, and air intake per unit body weight, and behaviors such as crawling and mouthing, which can increase exposure to contaminants present in soil, house dust, and consumer products.^23^ Additionally, DEHP and its metabolites have been detected in breast milk and baby formula. Average DEHP exposure in nursing infants has been estimated at between 6 and 24 µg/kg/day.^24,25^ Multiple DEHP metabolites have also been measured in human amniotic fluid samples, indicating exposure can occur in utero.^26^

DEHP exposure has been associated with certain medical procedures that use PVC plastic bags and tubing is thought to be much higher than from other anticipated environmental exposures. Parenteral exposure to DEHP can occur in patients undergoing medical procedures, such as intravenous administration of drugs, total parenteral nutrition, transfusion of blood or blood products, cardiopulmonary bypass, and extracorporeal membrane oxygenation.^8,27-29^

## Regulatory Status

Numerous regulatory statutes and guidelines are concerned with DEHP levels in consumer products, allowable environmental levels, and limits of occupational exposure. In the Consumer Product and Safety Improvement Act of 2008, issued by Congress, and in a final ruling by the U.S. Consumer Product Safety Commission in 2017, any children’s toy or childcare articles are prohibited from containing concentrations of more than 0.1% of eight designated phthalates, including DEHP.^30,31^ FDA regulates the use of DEHP as an indirect food additive used in food-contact materials. DEHP can be used in semi-rigid and rigid acrylic plastic materials at levels up to 3% by weight.^32^ Additionally, DEHP can be a component of cellophane food packaging materials if DEHP levels alone or in combination with other phthalates do not exceed 5% by weight.^33^ EPA established a maximum contaminant level for DEHP in drinking water at 6 μg/L and an oral reference dose of 0.02 mg/kg/day on the basis of increased relative liver weights in exposed guinea pigs.^34-36^ Due to the potential for increased exposure via inhalation in occupational settings, the Occupational Safety and Health Administration (OSHA) has set an 8-hour time-weighted average permissible exposure limit of 5 mg/m^3^, which is equivalent to the limits recommended by the American Conference of Governmental Industrial Hygienists and the National Institute for Occupational Safety and Health.^37^ The short-term (15-minute) exposure limit allowable by OSHA is 10 mg/m^3^. The Agency for Toxic Substances and Disease Registry developed DEHP minimal risk levels of 0.1 and 0.06 mg/kg/day via an oral exposure route for intermediate and chronic exposure durations, respectively.^4^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Numerous studies have evaluated the absorption, distribution, metabolism, and excretion (ADME) properties of DEHP. High levels of hydrolase activity present in the intestinal tract of various mammalian species hydrolyze DEHP to its monoester form, MEHP, and 2-ethylhexanol. Endogenous hydrolytic activity has been shown to vary between species.^38-41^ In general, investigators believed that most of consumed DEHP is efficiently hydrolyzed to its monoester form prior to absorption in the intestinal tract, and that absorption of the diester form is associated with high-exposure levels that exceed the hydrolytic capacity of the intestinal pancreatic lipases. Albro et al.^40^ found no DEHP in the livers of rats after oral administration of DEHP at low doses (<0.4 g/kg), but did find detectable levels after administration of higher doses (>0.5 g/kg). Comparative studies in which male Sprague Dawley rats were administered DEHP by intraperitoneal injection (4 g/kg) or oral gavage (2 g/kg) revealed that approximately 80% of the oral dose undergoes mono-de-esterification compared to only 1% of the parenteral dose.^42^ Co-administration of a pancreatic lipase inhibitor (S,S,S-tributylphosphorothionate) resulted in a marked inhibition of DEHP intestinal absorption, suggesting MEHP is more readily absorbed than its parent molecule, DEHP.

In adult Wistar rats following a single oral administration of [^14^C]-DEHP (2.9 mg/kg), the dose was excreted primarily in the urine (42%) and feces (57%) by 7 days postadministration, with an estimated absorbed dose of 50% from the gastrointestinal tract.^43^ Dermal absorption efficiency of [^14^C]-DEHP is limited. Only an estimated 6.5% of a single 30–40 mg/kg dose in ethanol was absorbed by 7 days postapplication on exposed skin of male Fischer 344 (F344) rats.^44^ Numerous studies report little retention of radiolabeled DEHP or its metabolites in isolated tissues.^38,45,46^ However, elevated concentrations have been detected in rodent liver, adipose tissue, kidney, bladder, testis, and lungs; these findings may be associated with variables of study design such as the administered dose, route of exposure, or duration of exposure prior to necropsy.^47-49^ A comparative study in adult male Sprague Dawley rats, male dogs (beagles), and male miniature pigs (Hormel strain) reported differential DEHP excretion profiles following dietary exposure to 50 mg/kg/day for 21–28 days before administration of a single dose of [^14^C]-DEHP (50 mg/kg).^46^ Excretion of radioactivity in urine and feces by 24 hours postadministration was 27% and 57% (rats), 12% and 56% (dogs), and 37% and 0.1% (pigs), respectively; and after 4 days was 37% and 53% (rats), 21% and 75% (dogs), and 79% and 26% (mini-pigs), respectively. Overall elimination of radioactivity was complete by postadministration day 4 in all species and was most rapid in rats, followed by dogs, and least rapid in mini-pigs. Sjöberg et al.^50^ investigated the kinetics of DEHP and MEHP in Sprague Dawley rats following a single oral gavage of 1,000 mg/kg DEHP. In blood samples collected at 1, 3, 7, 9, 12, 15, 24, and 30 hours after dosing, DEHP was only detectable within the first 7 hours after dosing. The maximal plasma concentration (C_max_) of MEHP occurred within 1 hour of dosing (C_max_ of 0.093 μg/mL), and a plasma elimination half-life of approximately 2.8–3.9 hours was determined. In another study, plasma C_max_ of DEHP (8.8 μg/mL) and MEHP (63.2 μg/mL plasma) were reached within 6 hours of a single oral administration of DEHP in male Wistar rats (2.8 g/kg).^51^ In the same study, daily dosing for a week resulted in no accumulation of DEHP or MEHP in plasma.

Additional studies suggest that differential ADME properties during gestational and juvenile development could increase exposure in these sensitive subgroups. DEHP is able to cross the placental barrier,^52,53^ and maternal transfer of DEHP and its metabolites can occur via lactation.^54^ Increased intestinal tissue surface area relative to body weight and higher relative blood flow to the intestines may contribute to higher absorption rates in neonate/juvenile animals than in adults.^55^

Following hydrolysis of DEHP to MEHP by pancreatic lipases in the intestinal tract, MEHP can be further metabolized through oxidation to additional products and undergo subsequent conjugation with glucuronic acid. Interspecies variation in metabolic competencies can lead to distinct urinary metabolite profiles. Oral gavage of DEHP or MEHP to Sprague Dawley or F344 rats resulted in identification of over 20 distinct urinary metabolites.^39,40^ Phthalic diacids typically constitute most metabolites identified in rat urine.^40^ Rats differ from other tested species in that they display extensive oxidative metabolism of DEHP, but little capacity to conjugate these metabolites. In mice, exposure to MEHP resulted in detectable concentrations of MEHP and metabolite glucuronide conjugates in urine.^56,57^ Primates generally display reduced pancreatic lipase activity in the intestinal tract compared with rodents, leading to reduced conversion of DEHP to MEHP.^58^ Additionally, primates exhibit a reduced capacity to oxidize DEHP metabolites, but an increased capacity to conjugate (glucuronidate) MEHPmetabolites.^58^ Therefore, primates predominately excrete glucuronides of MEHP and metabolites with hydroxyl side chains that require limited oxidative metabolism.^40^

### Humans

Studies have been conducted investigating DEHP toxicokinetic properties in humans. Similar to laboratory mammals, humans hydrolyze DEHP to MEHP by pancreatic lipases in the lumen of the intestinal tract, generate further oxidative metabolites, and conjugate these metabolites for excretion in urine and feces. In a study by Koch et al., urinary and serum concentrations of DEHP metabolites were determined from a human male volunteer following a single oral dose (0.64 mg/kg) of deuterium-labeled DEHP.^59^ Peak concentrations of three DEHP metabolites [MEHP, mono(2-ethyl-5-hydroxyhexyl) phthalate (MEHHP), and mono(2-ethyl-5-oxohexyl) phthalate (MEOHP)] were reached in serum after 2 hours and in urine after 4 hours. In serum, DEHP metabolites were unconjugated and contained high concentrations of MEHP relative to MEHP oxidation products. Urine samples contained higher concentrations of polar MEHP oxidation products than MEHP. Estimated serum elimination half-lives were <2 hours for the three measured DEHP metabolites. In a follow-up study, five DEHP urinary metabolites were identified [MEHP, MEHHP, MEOHP, mono(2-ethyl-5-carboxypentyl) phthalate (MECPP), and mono(2-[carboxymethyl]hexyl) phthalate (MCMHP)] that could be used as biomarkers for more accurate estimations of DEHP exposure (Figure 2).^60^ An additional three oxidative metabolites—mono(2-ethyl-3-carboxypropyl) phthalate (MECPrP), mono-2-(1-oxoethylhexyl) phthalate (MOEHP), and mono(2-ethyl-4-carboxybutyl) phthalate (MECBP)—were reported in human biomonitoring studies (Figure 2).^61^ Most of these metabolites undergo phase 2 metabolism to form glucuronide conjugates. Urinary concentrations of MEHHP and MEOHP have been detected at 10-fold higher concentrations than MEHP in 127 paired human samples, suggesting these metabolites may be more sensitive measures of DEHP exposure in the general population.^62^ Given these findings, DEHP exposure could be significantly underestimated in studies that measure only MEHP concentrations to predict human exposure. Other numerous oxidative metabolites of DEHP have also been proposed.^61^

Figure 2

Di(2-ethylhexyl) Phthalate (DEHP) and Metabolites Used to Quantify DEHP Exposure

MCMHP = mono(2-[carboxymethyl]hexyl) phthalate; MECBP = mono(2-ethyl-4-carboxybutyl) phthalate; MECPP = mono(2-ethyl-5-carboxypentyl) phthalate; MECPrP = mono(2-ethyl-3-carboxypropyl) phthalate; MEHHP = mono(2-ethyl-5-hydroxyhexyl) phthalate; MEHP = mono(2-ethylhexyl) phthalate; MEOHP = mono(2-ethyl-5-oxohexyl) phthalate; MOEHP = mono-2-(1-oxoethylhexyl) phthalate.

## Toxicity

### Experimental Animals

Extensive literature exists on the toxicity of DEHP in numerous animal models. Acute oral median lethal dose (LD_50_) values for DEHP range from 9,800 to >40,000 mg/kg in rats,^4,63-65^ and 9,860 to >31,360 mg/kg in mice,^4,63,66^ LD_50_ values of 33,900 mg/kg in rabbits^64^ and 26,300 mg/kg in guinea pigs have also been reported.^63,67^ Neonatal and young animals may be more sensitive, however, to the acute effects of DEHP. Mortality was observed in 6- to 21-day-old male Sprague Dawley rats administered five daily oral doses of 1,000 or 2,000 mg DEHP/kg, whereas no mortality occurred in rats age 6 weeks or older when administered the same five daily doses.^68^

NTP has reported findings from studies investigating the acute, subchronic, and chronic toxicities of DEHP in rodent models.^69^ No effect on survival was observed in F344 rats or B6C3F1 mice during a 14-day observation period following a single administration of DEHP by oral gavage (800 to 20,000 mg/kg for rats; 1,252 mg/kg for mice). In 13-week feeding studies, F344 rats were administered a diet containing 0, 1,600, 3,100, 6,300, 12,500, or 25,000 ppm DEHP. Significantly reduced mean body weight gains were observed in male and female rats exposed to 25,000 ppm, and testicular atrophy was observed in males exposed to dietary concentrations of 12,500 ppm or higher. B6C3F1 mice exposed to 0, 800, 1,600, 3,100, 6,300, or 12,500 ppm DEHP in the diet for 13 weeks showed similar effects on body weight at the higher concentrations. Decreased mean body weight gains (≥10% relative to the control groups) were noted in male mice exposed to 3,100 ppm DEHP or higher and in all DEHP-exposed female mice, except the 1,600 ppm group. In a 2-year study, F344 rats were exposed to 0, 6,000, or 12,000 ppm DEHP in the diet, resulting in mean daily chemical intakes of 322 and 674 mg/kg body weight (mg/kg) for males, respectively; and 394 and 774 mg/kg for females, respectively. At the end of the 2-year study, mean body weights of exposed rats were up to 20% lower in the high-exposure groups compared to the control groups. In a companion 2-year study, B6C3F1 mice were exposed to 0, 3,000, or 6,000 ppm DEHP in the diet, resulting in mean daily chemical intakes of 672 and 1,325 mg/kg for males, respectively, and 799 and 1,821 mg/kg for females, respectively. At the end of the 2-year study, mean body weights were 7% and 10% lower in the 3,000 and 6,000 mg/kg male groups, and 21% and 33% lower in the 3,000 and 6,000 mg/kg female groups, respectively, relative to the control groups. The incidence of testicular tubule degeneration or atrophy was significantly elevated in high-exposure group male rats (approximately 90%) and male mice (approximately 14%) relative to the control groups.

Numerous laboratory animal studies have reported reductions in body weight and body weight gain following repeated exposures to DEHP, and common target organs of DEHP toxicity include the testis, kidney, and liver. Toxic effects of phthalates on the male reproductive tract are well characterized and are addressed in a subsequent section of this Introduction. DEHP effects on the kidney include reduced creatinine clearance, increased absolute and relative kidney weights, increased incidence and/or severity of mineralization of renal papilla, increased incidence and/or severity of tubule cell pigment, and increased incidence and/or severity of chronic progressive nephropathy.^70-72^ Liver enlargement due to both hepatocyte hyperplasia and hypertrophy, with associated morphological changes such as increased size and number of peroxisomes and corresponding increases in fatty-acid metabolism, are known hallmarks of DEHP toxicity in rodents. Activation of the peroxisome proliferator-activated receptor alpha (PPARα) in hepatocytes is recognized as a key molecular initiating event by which DEHP induces adverse effects in the liver.^73^ PPARα-deficient mice did not exhibit characteristic liver toxicity following 24 weeks of DEHP exposure but did exhibit moderate kidney and testicular toxicity.^74^ These findings suggest that while DEHP-induced liver toxicity is associated with PPARα status, renal and testicular toxicities likely manifest via alternative mechanisms.

Decreased severity of hepatic effects in nonrodent species may be related to interspecies differences in PPARα expression, binding, localization, and downstream molecular signaling pathways.^41^ DEHP metabolites such as MEHP have been reported to be more potent activators of human and mouse PPARα relative to its parent molecule.^75^ Therefore, interspecies differences in pancreatic lipase activity, which converts DEHP to MEHP, may influence observed DEHP toxicities. Additionally, routes of administration that bypass first pass metabolism in the intestinal tract and liver (intravenous), reducing hydrolysis of DEHP to its metabolites, could influence subsequent toxicity.

### Humans

The health effects of DEHP have been evaluated extensively in animal models, but data that address the relationship between human health effects or adverse outcomes and exposure to DEHP are limited. Shaffer et al.^64^ presented a case report in which two male subjects had ingested single DEHP doses of 5 g and 10 g, respectively.^64^ The individual who consumed the 10 g dose presented with symptoms of mild gastric disturbance and moderate diarrhea, whereas no effects were observed at the lower dose.

## Reproductive and Developmental Toxicity

### Experimental Animals

Studies with laboratory rodents demonstrate that DEHP exposure can cause adverse effects on reproduction and development. In adult rats, oral DEHP exposure is associated with numerous deleterious effects on the male reproductive tract, including decreased weights of the testes, prostate, seminal vesicles, and epididymis; degeneration and atrophy of the seminiferous tubules; altered sperm parameters; and reduced fertility.^4,13^ The testes are considered a primary target tissue of DEHP toxicity. Decreased testicular weight and increased incidence of tubular atrophy have been observed in numerous rodent studies in which doses exceeded 100 mg/kg/day.^69,76-82^ Within the testes, DEHP appears to preferentially target Sertoli cell populations and directly or indirectly Leydig cell populations, which can impair spermatogenesis and fertility.^78,83,84^ Irregular seminiferous tubule structure and altered spermatogenesis were evident in male rats ingesting DEHP at 2,000 mg/kg/day via the diet for 15 days.^85^ In these rats, few spermatozoa were present in the lumen of the tubules, and damaged spermatogenic cells were observed in the tubular space. Significantly increased incidences of bilateral aspermatogenesis were observed at lower exposure concentrations (29 mg/kg/day) in male rats fed DEHP-supplemented diets for 2 years.^86^ Prepubertal rodents appear to be more sensitive to DEHP-mediated effects on the testes relative to sexually mature rodents.^76,82^ In contrast to studies in rodents, no changes in testes/epididymides weight or testicular histology were observed in cynomolgus monkeys following administration of 500 mg/kg/day DEHP by gavage for 14 consecutive days.^87^ Decreased fertility also has been observed in female rodents exposed to DEHP, and may be related to DEHP-induced disruption of normal estrous/ovulatory cycles.^88^

DEHP is a developmental toxicant in rodents, producing embryotoxic, fetotoxic, and teratogenic effects. Decreased fetal/pup body weight, increased rates of abortion and fetal resorptions, and malformations (hydronephrosis, cardiovascular malformations, and tail malformations) have been reported in rat dams and corresponding litters after exposure to DEHP during pregnancy/gestation.^89,90^ Exposure to DEHP during the perinatal period (gestation and/or lactation) can induce abnormal development of the male reproductive tract and other androgen-sensitive tissues. Although the exact mechanism is unknown, DEHP acts as an endocrine disruptor via an antiandrogenic mode of action and decreases insulin-like hormone 3 production by Leydig cells. Normally, during the window of fetal male sexual differentiation (gestation days 15.5–21.5), androgen-dependent masculinization of the fetal reproductive tract occurs, resulting in differentiation of the internal (epididymis, vas deferens, seminal vesicles, prostate) and external (penis, scrotum, perineum) genitalia.^91,92^ Exposure to DEHP during this critical window of susceptibility decreases fetal testosterone synthesis leading to structural malformations and functional alterations of the male reproductive system.^93,94^ Reduced anogenital distance (AGD), retained nipples, penile morphological abnormalities (hypospadias), undescended testes (cryptorchidism), small/absent sex accessory glands, delays in onset of pubertal landmarks (preputial separation), and histopathological alterations in testes and epididymides have been observed in male rats following perinatal DEHP exposure.^93,95-97^ Dysmorphogenic effects in the testes include microscopic disorganization of the seminiferous tubules with detachment of the spermatogonial cells from the basal membrane and absence of spermatocytes.^98^ The term “phthalate syndrome” is often used to describe the compendium of reproductive tract malformations observed in male test animals following in utero phthalate exposure.^99^

The reproductive and developmental effects of DEHP exposure were comprehensively investigated by NTP in a multigenerational reproductive assessment by continuous breeding study.^100^ In this study, DEHP was administered in the diet at concentrations of 1.5 (control), 10, 30, 100, 300, 1,000, 7,500, or 10,000 ppm to Sprague Dawley rats over multiple successive generations (F_0_, F_1_, F_2_, and F_3_) throughout the breeding, gestational, lactational, and postweaning intervals. Measured feed consumption and body weights informed the calculation of approximate daily doses of 0.12, 0.78, 2.4, 7.9, 23, 77, 592, and 775 mg/kg/day in the F_0_ animals; 0.09, 0.48, 1.4, 4.9, 14, 48, 391, and 543 mg/kg/day in the F_1_ animals; and 0.1, 0.47, 1.4, 4.8, 14, 46, and 359 mg/kg/day in the F_2_ animals. The 10,000 ppm group was removed from the study following the F_1_ generation due to the inability to produce offspring (F_2_ generation). Adverse reproductive and developmental effects such as decreased pregnancy index, decreased male AGD, delayed onset of pubertal landmarks (testes descent, vaginal opening, and balanopreputial separation), sperm counts, small male reproductive organs (testes, epididymis, and caudal epididymis), and seminiferous tubule atrophy were observed in all generations in the 7,500 and 10,000 ppm groups. No reproductive toxicity was evident at exposure concentrations <7,500 ppm; however, increased incidences of small testes and prostates were noted in 300 and 1,000 ppm male rats. After further review of animal studies by NTP’s Center for the Evaluation of Risks to Human Reproduction (CERHR) expert panel, a developmental no-observed-effect level of 1,000 ppm was suggested and calculated to be no more than 46 mg/kg/day based on the average dose over three generations.^13^

### Humans

Given the results from animal studies, there is significant concern that DEHP can adversely affect human reproduction and male development. FDA’s CDRH concluded that “children undergoing certain medical procedures may represent a population at increased risk for the effects of DEHP.” A similar conclusion was reached by NTP’s CERHR, which found cause for “serious concern” that certain medical treatments may result in DEHP exposure levels that could adversely affect the development of the reproductive tract in male infants.^13^ Numerous epidemiological studies have found no significant association of DEHP or its metabolites with sperm abnormalities, circulating hormone concentrations, or indications of infertility.^101-105^ Other studies have reported associations between maternal urinary DEHP metabolite concentrations and effects on several markers of human male genital development. In complementary studies by Swan et al., measures of AGD and penile width in male infants were significantly associated with exposure to DEHP and three of its metabolites.^106,107^ Many parallels exist between the “phthalate syndrome” suite of effects in animal models and descriptions of human testicular dysgenesis syndrome. This syndrome is characterized by increased incidences of reproductive tract malformations in male newborns (cryptorchidism, hypospadias) and adverse effects in young adults (low sperm counts, testicular germ cell cancer) and is likely related to in utero exposure to environmental chemicals.^108,109^

## Immunotoxicity

### Experimental Animals

Several studies have been conducted to assess the potential of DEHP or MEHP to modulate immune function. Studies by Larsen et al. found subcutaneous injections of MEHP (100 μg) to induce an immunosuppressive effect characterized by a reduction in immunoglobulin E (IgE) and IgG1 antibody production in BALB/cJ mice following co-administration of ovalbumin antigen.^110^ However, in the same study, lower doses of MEHP (1 μg) induced an adjuvant effect characterized by increased IgE production. Administration of DEHP to male F344 rats via the diet (12 ppm) for 21 days resulted in a suppressed hepatic T-helper Type 1 (Th1) immune response initiated via intraperitoneal exposure to Mycobacterium bovis purified protein derivative.^111^ The authors hypothesized that this effect was associated with biotransformation of DEHP to MEHP and subsequent activation of PPARα. Further studies investigating the mixed T-helper cell adjuvant properties of DEHP found that this effect occurred independent of PPARα status in mouse models.^112^ Differential effects on the immune system have been noted in studies that use a developmental exposure paradigm. Increased sensitivity to DEHP exposure, characterized by altered immune parameters (T-dependent antigen response, natural killer cell activity, and tumor necrosis factor-alpha [TNF-α] production), was observed in male Wistar rats administered DEHP (0, 1, 3, 10, 30, 100, 300, or 1,000 mg/kg/day) by oral gavage during their juvenile period (postnatal day [PND] 10–50) relative to adult-only exposure (PND 50–90).^113^ In contrast, no persistent effects on numerous assessed immune parameters were noted in a study by Piepenbrink et al. in which CD rats were gestationally exposed to DEHP (0, 37.5, 75, 150, or 300 mg/kg/day).^114^ In the same study, no DEHP-associated immunotoxicity was noted in nulliparous exposed adults. Topical DEHP administration in adult B6C3F1 female mice did not increase serum concentrations of IgE, interleukin-4 (IL-4), or IL-13, suggesting a limited potential to induce allergic asthma.^115^ Additional studies report dose-dependent increases in some inflammatory cell numbers (macrophages, eosinophils, neutrophils, and/or lymphocytes) in bronchoalveolar lavage fluid in BALB/c or BALB/cJ mice following inhalation exposure to MEHP aerosols.^116,117^ Using median residential indoor air and worst-case exposure concentrations of 0.04 μg and 1.2 μg DEHP/m^3^, respectively, Hansen et al. estimated a margin of exposure between 2,500–75,000, suggesting that immune effects from inhalation exposures are only expected at air concentrations that are well in excess of environmental inhalation exposures typically encountered by humans.^116^

### Humans

Numerous case reports and epidemiological studies suggest a link between phthalate exposure from PVC products and development of allergies and/or asthma.^118^ In a study of 39 PVC-processing plant workers, a higher prevalence of asthma, rhinitis, and eye and respiratory symptoms was observed in individuals exposed to PVC pyrolysis products and phthalates relative to an unexposed reference group.^119^ In a population-based incident case-control study of 521 new asthma cases and 932 control cases, asthma risk was related to the presence of plastic wall materials.^120^ Two epidemiological studies suggest childhood exposure to phthalates via house dust is related to the onset of allergy and/or asthma. In a nested case-control study within a 10,852 child cohort (198 persistent allergic cases, 202 control cases), higher median concentrations of DEHP (cases – 0.828 mg/g dust; control group – 0.723 mg/g dust) in house dust were significantly (p = 0.022) associated with asthma.^121^ In a separate study in Bulgarian preschool-age children (n = 102), wheezing was associated with higher DEHP concentrations in dust samples collected from children’s rooms (1.24 mg/g dust for children with wheezing, rhinitis, and/or eczema versus 0.86 mg/g dust for nonsymptomatic) in the preceding 12-month time interval.^122^ A greater understanding of human exposure relative to animal effect levels and additional mechanistic studies are needed to support a causal inference between DEHP exposure and immunomodulatory effects in humans.

## Carcinogenicity

### Experimental Animals

Multiple rodent studies were identified in the literature that examined the carcinogenic activity of DEHP, all of which initiated exposure once test animals had reached adulthood. Increased incidences of hepatocellular neoplasms have been corroborated across multiple rodent studies, along with reports of increased incidences of testicular Leydig cell tumors and pancreatic acinar adenomas in male rats following chronic exposure to DEHP. In 2-year cancer bioassays conducted by NTP, F344 rats and B6C3F1 mice were administered diets containing 0, 6,000, or 12,000 ppm DEHP and 0, 3,000, or 6,000 ppm DEHP, respectively.^69,123^ DEHP was found to be carcinogenic in both F344 rats and B6C3F1 mice on the basis of increased incidences of hepatocellular adenomas/carcinomas or neoplastic nodules in both males and females. Significantly increased incidences of hepatocellular adenoma or carcinoma (combined) in F344 rats and B6C3F1 mice were observed at lower DEHP exposure concentrations (male rats: 2,500 ppm; male mice: 500 ppm; female mice: 1,500 ppm) in chronic studies by David et al.^86,124,125^ Additionally, incidences of pancreatic acinar adenomas were increased in male F344 rats at the highest tested exposure concentration (12,500 ppm).^86^ A 159-week study in male Sprague Dawley (SD-CD) rats found that the high-exposure concentration of DEHP (6,000 ppm, or 300 mg/kg/day) increased the incidence of benign Leydig cell tumors.^126^

In rats, the combination of hepatocellular, pancreatic, and testicular tumors is often referred to as the “tumor triad” and is associated with sustained peroxisome proliferator activity.^127^ Although the definitive mode of action of DEHP-mediated carcinogenesis is undetermined, several key events, including activation of PPARα, perturbation of cellular proliferation and apoptosis, selective clonal expansion, and oxidative stress, are hypothesized to contribute to the onset of tumorigenesis.

### Humans

The carcinogenic activity of DEHP in humans has been reviewed by numerous federal and international agencies. In the 14th Report on Carcinogens published by NTP, DEHP was listed as reasonably anticipated to be a human carcinogen based on sufficient evidence of carcinogenicity in experimental animals.^128^ EPA classified DEHP as a Group B2 carcinogen, probable human carcinogen, based on clear evidence of DEHP-mediated induction of liver tumors in rodent models.^35^ The International Agency for Research on Cancer (IARC) previously classified DEHP as “not classifiable as to its carcinogenicity to humans” (Group 3).^73^ The IARC determination was based on two assumptions: (1) that DEHP-induced hepatocellular cancer in rodents occurred as a result of induced peroxisome proliferation activity, and (2) that this mechanism is not relevant to humans due to lower PPARα expression and lack of observable peroxisome proliferation phenotypes in humans following exposure to known PPAR ligands. However, in light of new information about mechanisms of action, in 2011 IARC reclassified DEHP as a Group 2B carcinogen, indicating that there is “sufficient evidence of carcinogenicity in experimental animals” in combination with “no or limited epidemiological data.”^129^ The reevaluation included consideration of recent studies with novel transgenic mouse models, such as PPARα-null mice, humanized PPARα mice, and mice that express a constitutively active PPARα isoform in hepatocytes.^130-132^ These studies indicate that DEHP can induce hepatocarcinogenesis through a PPARα-independent mechanism, and that other molecular signaling pathways, not just activation of PPARα, likely contribute to the development of cancer.

Epidemiological studies that investigate a link between DEHP exposure and cancer endpoints are limited. In a case-control study of female breast cancer patients, increased cancer risk was associated with elevated urinary concentrations of the DEHP metabolite MECPP, but not other identified DEHP metabolites.^133^ Additional cancer epidemiology studies have been conducted in occupational groups where subjects had worked in PVC processing and plastic manufacturing facilities where increased exposure to phthalate plasticizers was probable.^134-140^ However, many of these studies lacked analytical assessment of exposure to specific phthalates, limiting the ability to determine a causal relationship between DEHP exposure and human cancer.

## Genetic Toxicity

The genetic toxicity of DEHP has been extensively investigated and reviewed over many years (e.g., Huber et al., IARC, and Caldwell).^141-143^ Overall, DEHP shows limited evidence of genotoxic potential, and for the sporadic positive results that have been reported, associations are weak, not reproducible, obtained in a nonstandard test system, or qualified to some degree by the authors. MEHP, one of the main DEHP metabolites, does elicit positive responses, however, in some genotoxicity assays. An early study reported increases in revertant colonies in Salmonella typhimurium strain TA100 and Escherichia coli strain WP2 B/r treated with 2.5 and 5.0 mM MEHP, doses that induced marked cytotoxicity.^144^ More recently, MEHP was reported to generate reactive oxygen species and, consequently, DNA strand breaks in cultured AS52 cells^145^ as well as in cultured mouse Leydig tumor cells and in human prostate adenocarcinoma cells as measured by the comet assay.^146,147^ In both cell lines in the latter two studies, the parent compound DEHP (3 mM for 24 hours) was also reported to induce DNA damage, although the concentration tested was 1,000 times higher than the concentration tested of MEHP (3 uM). Similarly, DNA damage, measured by the comet assay, was also reported for DEHP in cultured HeLa cells treated with 96.6 µM DEHP for 24 hours.^148^

NTP has conducted several in vitro and in vivo genotoxicity assays with DEHP. Unpublished NTP data are included in Appendix D of this report. Published NTP studies, results of which are consistent with most published studies, showed no induction of gene mutations in any of several strains of S. typhimurium^149,150^ or in cultured mouse lymphoma L5178Y tk^+/−^ cells.^151^ Additional bacterial mutation studies also reported negative results (e.g., Simon et al.^152^). Cytogenetic studies in cultured Chinese hamster ovary cells were negative for induction of chromosomal aberrations and were either positive or equivocal for induction of sister chromatid exchanges.^153^ In vitro chromosomal aberration studies, not conducted by NTP, in human leukocytes and human fetal lung cells with DEHP also showed no significant increases in chromosomally aberrant cells,^154^ as did chromosome aberration studies in Chinese hamster cells.^155-157^ Studies that assessed the ability of DEHP to induce sex-linked recessive lethal mutations in germ cells of male Drosophila melanogaster after exposure of either adults (via injection) or larvae (via feeding) were negative.^158,159^

Although sporadic reports of DNA damage or chromosomal effects following in vitro exposure to DEHP exist, results from in vivo studies are almost uniformly negative. In an in vivo comet assay conducted as part of the Japanese led multi-laboratory international validation effort for the assay, DEHP, administered by gavage at a top dose of 2,000 mg/kg/day for 3 days, did not induce DNA damage in cells obtained from the stomach, liver, and bone marrow of male Sprague Dawley rats.^160^ In addition, bone marrow samples from those rats showed no increase in the percentage of micronucleated erythrocytes, which are biomarkers of chromosomal damage. In another study, no increases in the frequencies of gpt and Spi(-) mutations were seen in DNA extracted from liver cells of gpt transgenic rats (both F344 and Sprague Dawley backgrounds) with exposure of up to 12,000 ppm DEHP exposure in the diet for 4 weeks, a concentration that produced generalized toxicity (e.g., increased liver weights).^161^ Similarly, an earlier study found that a 13-week Sprague Dawley gpt delta transgenic rats exposed to 12,000 ppm DEHP in the diet resulted in no increases in mutations in liver cell DNA.^162^

A study designed to investigate the potential for DEHP to induce unscheduled DNA synthesis (UDS) in liver cells of male B6C3F1 mice—a species that is sensitive to tumor induction by DEHP—found that exposures up to 500 mg/kg DEHP acutely or 6,000 ppm in the diet for up to 28 days did not induce UDS, measured using autoradiographic methods.^163^ The investigators also treated primary mouse hepatocytes in culture with up to 1.0 mM DEHP and observed no UDS at time points ranging from 12–48 hours posttreatment.

The negative results from the in vivo studies described above contrast with an earlier study by Singh et al. that reported a weak positive response in an in vivo rodent dominant lethal test using ICR mice. In that study, DEHP was administered via intraperitoneal injection at 66% of the acute LD_50_ dose, determined as 38.35 mL/kg.^164^ However, Jäckh et al.^165^ reported that a second rodent dominant lethal test that used similar doses of DEHP but administered the chemical via oral gavage showed no induction of dominant lethal mutations. They therefore suggested that the weak positive response in the Singh et al. study was likely related to nongenotoxic mechanisms, as covalent binding to DNA was not detected in liver cells of rats administered ^14^C- and ^3^H-labeled DEHP (500 mg/kg) by gavage.^165^

## Study Rationale

In response to data gaps related to in utero and early life phthalate exposure and resultant adverse reproductive, developmental, and carcinogenic effects, NTP initiated a cancer hazard assessment for lifetime exposure to environmental phthalates. For DEHP, studies in rodents have established the gestational period as the time of greatest sensitivity to adverse developmental effects, specifically dysmorphogenesis of the male reproductive system. DEHP is a known rodent carcinogen; however, no previous cancer assessments have included exposure during the perinatal period (gestation and lactation). Therefore, it is unknown whether the carcinogenic response is altered when lifetime exposure encompasses these critical developmental windows.

NTP designed two 2-year studies in rats to evaluate whether DEHP lifetime exposure, including during the perinatal developmental period, would alter the dose response of the carcinogenic response relative to postweaning-only exposure. In these studies, DEHP was administered in dosed feed to mimic a common route of human exposure.