# Appendix H Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TR-601.^202^

## H.1 Perinatal and Postweaning Study in Rats (Study 1)

### H.1.1 Data Tables

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E08 – Feed Water and Compound Consumption Table

Gestational Body Weights

Gestational Food Consumption

Gestational and Lactational Chemical Consumption

Lactational Body Weights

Lactational Food Consumption

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions – Litter based

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P22 – Cause of Death Summary

P40 – Survival Curves

PA46Rs – Summary of Gross Pathology with Litter Incidence

PA48 – Summary of Tissue Concentration

PND 1 Litter Data

PND 4 Litter Size and Survival Data

Pup Body Weights

R02 – Reproductive Performance Summary

R23 – Gubernaculum Length Summary

### H.1.2 Individual Animal Data

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Body Weight Data All Animals – Lactation

Female Individual Animal Body Weight Data All Animals – Gestation

Female Individual Animal Clinical Observations

Female Individual Animal Neoplastic Pathology Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Survival Data – Gestation

Female Individual Animal Survival Data – Lactation

Female Individual Animal Terminal Body Weight Data

Female Individual Animal Terminal Body Weight Data – Gestation

Female Individual Animal Terminal Body Weight Data – Lactation

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal DamID and PupID Data

Individual Animal Reproductive Performance Data

Individual Animal Tissue Concentration Data

Individual Pup Census and Litter Weight by Sex Data

Gubernaculum and Urogenital Findings Data

## H.2 Postweaning-only Study in Rats (Study 2)

### H.2.1 Data Tables

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P22 – Cause of Death Summary

P40 – Survival Curves

### H.2.2 Individual Animal Data

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Clinical Observations

Female Individual Animal Neoplastic Pathology Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

## H.3 Benchmark Dose Analysis

### H.3.1 Results Summary

Summary of BMD Results

### H.3.2 Perinatal and Postweaning Study in Rats (Study 1)

Perinatal Female Liver BMD Analysis

Perinatal Female Pancreas BMD Analysis

Perinatal Female Uterus BMD Analysis

Perinatal Male Liver BMD Analysis

Perinatal Male Pancreas BMD Analysis

Perinatal Male Testes BMD Analysis

### H.3.3 Postweaning-only Study in Rats (Study 2)

Adult Female Liver BMD Analysis

Adult Female Pancreas BMD Analysis

Adult Female Uterus BMD Analysis

Adult Male Liver BMD Analysis

Adult Male Pancreas BMD Analysis

Adult Male Testes BMD Analysis

## H.4 Genetic Toxicology

### H.4.1 In Vivo Peripheral Blood Micronucleus Study A04384 (Dosed Feed)

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### H.4.2 In Vivo Peripheral Blood Micronucleus Study A15851 (Dermal)

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data

### H.4.3 Rodent Chromosome Aberrations Study A15927 (Dosed Feed)

Data can be found here: https://manticore.niehs.nih.gov/cebssearch/genetox/002-01969-0036-0000-6/

### H.4.4 In Vivo Bone Marrow Micronucleus Study A15927 (Dosed Feed)

G04 – In Vivo Micronucleus Summary Data

Individual Animal In Vivo Micronucleus Data