# Appendix F Benchmark Dose Analysis

## F.1 Methods

Benchmark doses (BMDs) were calculated using the EPA Benchmark Dose Software (BMDS), version 3.1.2.^169^ The dose variable for the models was the amount of di(2-ethylhexyl) phthalate (DEHP) consumed/kg body weight/day (mg/kg/day). Numbers of animals per exposure group were poly-3-adjusted survival numbers. The response variable was the incidence of the endpoint being modeled.

All of the frequentist dichotomous models in the BMDS were used. The logistic, log-probit, and probit models were used with no parameter restrictions. Other models (dichotomous Hill, gamma, log-logistic, multistage, and Weibull) were used with default restrictions on the ranges of some of the parameters, as described in the BMDS User Guide.^170^

The benchmark response (BMR) used in the models was 0.1 (10%) extra risk, with estimated background levels. The benchmark dose lower confidence limit (BMDL_10_) was calculated using a 95% confidence interval. The decision logic used to recommend one model from the fitted models was the default logic.^170^

## F.2 Results

### F.2.1 Hepatocellular Adenoma or Carcinoma (Combined; Male Rats)

#### F.2.1.1 Perinatal and Postweaning Study

All models provided an adequate fit to the data as assessed by a chi-square goodness-of-fit test (p ≥ 0.1) and by visual inspection of the respective plots of observed versus predicted values from the various models (Table F-1; Figure F-1). The dichotomous Hill, logistic, and probit models provided similar fits to the data. The probit model was judged to provide the best model fit based on the lowest Akaike information criterion (AIC) value. The BMDS dichotomous results for the probit and other models are available as supplemental data (Appendix H).

#### F.2.1.2 Postweaning-only Study

All models except for the dichotomous Hill and multistage degree 1 models provided an adequate fit to the data as assessed by a chi-square goodness-of-fit test (p ≥ 0.1) and by visual inspection of the respective plots of observed versus predicted values from the various models (Table F-1; Figure F-1). The multistage degree 4 and multistage degree 3 models provided similar fits to the data. The multistage degree 4 model was judged to provide the best model fit based on the lowest AIC value. The BMDS dichotomous results for the multistage degree 4 and other models are available as supplemental data (Appendix H).

### F.2.2 Hepatocellular Adenoma or Carcinoma (Combined; Female Rats)

#### F.2.2.1 Perinatal and Postweaning Study

All models except for the logistic and probit models provided adequate fits of the data as assessed by a chi-square goodness-of-fit test (p ≥ 0.1) and by visual inspection of the respective plots of observed versus predicted values from the various models (Table F-2; Figure F-2). The log-logistic and log-probit models provided similar fits of the data. The log-logistic model was judged to provide the best model fit based on the lowest AIC value. The BMDS dichotomous results for the log-logistic and other models are available as supplemental data (Appendix H).

#### F.2.2.2 Postweaning-only Study

All models provided adequate fits of the data as assessed by a chi-square goodness-of-fit test (p ≥ 0.1) and by visual inspection of the respective plots of observed versus predicted values from the various models (Table F-2; Figure F-2). The multistage degree 4, multistage degree 2, logistic, and probit models provided similar fits of the data. The multistage degree 4 model was judged to provide the best model fit based on the lowest AIC value. The BMDS dichotomous results for the multistage degree 4 and other models are available as supplemental data (Appendix H).

### F.2.3 Pancreatic Acinar Adenoma or Carcinoma (Combined; Male Rats)

#### F.2.3.1 Perinatal and Postweaning Study

All models had poor goodness of fit (p < 0.1). In addition, all models other than dichotomous Hill, log-logistic, and log-probit had high residuals near the BMD_10_. Of the models without high residuals near the BMD_10_, the dichotomous Hill model had the best fit based on AIC and was the only model with chi-square p value >0.0001 (Table F-3; Figure F-3). The dichotomous Hill model provided the best model fit based on the highest chi-square p value and lowest AIC value. The BMDS dichotomous results for the dichotomous Hill model and other models are available as supplemental data (Appendix H).

#### F.2.3.2 Postweaning-only Study

Only dichotomous Hill, log-logistic, and log-probit models provided adequate fits of the data as assessed by a chi-square goodness-of-fit test (p ≥ 0.1) and visual inspection of the respective plots of observed versus predicted values from the various models (Table F-3; Figure F-3). The dichotomous Hill, log-logistic, and log-probit models provided similar fits of the data. The log-logistic model provided the best model fit based on the highest chi-square p value and lowest AIC value. The BMDS dichotomous results for the log-logistic model and other models are available as supplemental data (Appendix H).

### F.2.4 Uterine (Including Cervix) Adenocarcinoma, Adenoma, Squamous Cell Carcinoma, or Squamous Cell Papilloma (Combined; Female Rats)

#### F.2.4.1 Perinatal and Postweaning Study

All models provided adequate fits of the data as assessed by a chi-square goodness-of-fit test (p ≥ 0.1) and visual inspection of the respective plots of observed versus predicted values from the various models (Table F-4; Figure F-4). The multistage degree 1, logistic, and probit models provided similar fits of the data. The logistic model provided the best model fit based on the lowest AIC value. The BMDS dichotomous results for the logistic and other models are available as supplemental data (Appendix H).

#### F.2.4.2 Postweaning-only Study

All models provided adequate fits of the data as assessed by a chi-square goodness-of-fit test (p ≥ 0.1) and visual inspection of the respective plots of observed versus predicted values from the various models (Table F-4; Figure F-4). The multistage degree 1, logistic, and probit models provided similar fits of the data. The probit model provided the best model fit based on the lowest AIC value. The BMDS dichotomous results for the probit and other models are available as supplemental data (Appendix H).

Table F-1 Benchmark Dose Modeling Results for Hepatocellular Adenoma or Carcinoma (Combined) in Male Rats in the Two-year Feed Studies of Di(2-ethylhexyl) Phthalate

Model | Chi-square P Value^a^ | AIC | BMD_10_ (mg/kg/day) | BMDL_10_ (mg/kg/day) | BMDS Recommendation^b^
Perinatal and Postweaning Study (Study 1)
Dichotomous Hill | 0.55 | 92.9 | 199.5 | 168.2 | Viable–alternate
Gamma | 0.48 | 93.4 | 328.0 | 199.7 | Viable–alternate
Log-logistic | 0.48 | 93.4 | 326.1 | 194.6 | Viable–alternate
Multistage Degree 4 | 0.45 | 93.6 | 356.5 | 198.5 | Viable–alternate
Multistage Degree 3 | 0.45 | 93.6 | 356.5 | 198.5 | Viable–alternate
Multistage Degree 2 | 0.45 | 93.6 | 356.5 | 198.5 | Viable–alternate
Multistage Degree 1 | 0.38 | 93.6 | 249.9 | 161.3 | Viable–alternate
Weibull | 0.47 | 93.5 | 336.2 | 198.8 | Viable–alternate
Logistic | 0.61 | 92.0 | 413.6 | 335.9 | Viable–alternate
Log-probit | 0.52 | 93.2 | 302.0 | 188.6 | Viable–alternate
Probit | 0.63 | 91.8 | 382.9 | 306.1 | Viable–recommended
Postweaning-only Study (Study 2)
Dichotomous Hill | 0.04 | 91.6 | 223.1 | 177.2 | Questionable
Gamma | 0.14 | 89.6 | 416.2 | 262.1 | Viable–alternate
Log-logistic | 0.14 | 89.6 | 428.0 | 259.7 | Viable–alternate
Multistage Degree 4 | 0.26 | 87.6 | 434.4 | 263.5 | Viable–recommended
Multistage Degree 3 | 0.26 | 87.61 | 434.4 | 263.5 | Viable–alternate
Multistage Degree 2 | 0.19 | 88.0 | 375.0 | 248.1 | Viable–alternate
Multistage Degree 1 | 0.07 | 91.0 | 273.0 | 173.8 | Questionable
Weibull | 0.14 | 89.6 | 436.3 | 263.0 | Viable–alternate
Logistic | 0.18 | 87.9 | 421.5 | 349.6 | Viable–alternate
Log-probit | 0.13 | 89.6 | 393.9 | 250.8 | Viable–alternate
Probit | 0.15 | 88.1 | 395.2 | 321.4 | Viable–alternate

AIC = Akaike information criterion; BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk; BMDS = Benchmark Dose Software.

^a^ Chi-square p value = p value from the chi-square test for lack of fit. Values <0.1 fail to meet conventional goodness-of-fit criteria.

^b^ Bold text indicates the model selected for each response.

Table F-2 Benchmark Dose Modeling Results for Hepatocellular Adenoma or Carcinoma (Combined) in Female Rats in the Two-year Feed Studies of Di(2-ethylhexyl) Phthalate

Model | | Chi-square P Value^a^ | AIC | BMD_10_ (mg/kg/day) | BMDL_10_ (mg/kg/day) | BMDS Recommendation^b^
Perinatal and Postweaning Study (Study 1)
Dichotomous Hill | | 0.14 | 143.1 | 77.6 | 41.5 | Viable–alternate
Gamma | | 0.14 | 142.7 | 153.7 | 105.9 | Viable–alternate
Log-logistic | | 0.24 | 141.5 | 122.9 | 79.7 | Viable–recommended
Multistage Degree 4 | | 0.14 | 142.7 | 153.7 | 105.9 | Viable–alternate
Multistage Degree 3 | | 0.14 | 142.7 | 153.7 | 105.9 | Viable–alternate
Multistage Degree 2 | | 0.14 | 142.7 | 153.7 | 105.9 | Viable–alternate
Multistage Degree 1 | | 0.14 | 142.7 | 153.7 | 105.9 | Viable–alternate
Weibull | | 0.14 | 142.7 | 153.7 | 105.9 | Viable–alternate
Logistic | | 0.02 | 148.2 | 348.5 | 274.2 | Questionable
Log-probit | | 0.27 | 142.1 | 92.0 | 41.5 | Viable–alternate
Probit | | 0.03 | 147.6 | 321.7 | 251.3 | Questionable
Postweaning-only Study (Study 2)
Dichotomous Hill | 0.34 | | 79.9 | 277.3 | 180.7 | Viable–alternate
Gamma | 0.36 | | 79.9 | 275.7 | 183.2 | Viable–alternate
Log-logistic | 0.34 | | 79.9 | 277.3 | 180.7 | Viable–alternate
Multistage Degree 4 | 0.81 | | 77.0 | 383.6 | 208.0 | Viable–recommended
Multistage Degree 3 | 0.58 | | 79.1 | 348.2 | 205.4 | Viable–alternate
Multistage Degree 2 | 0.69 | | 77.5 | 302.0 | 197.2 | Viable–alternate
Multistage Degree 1 | 0.49 | | 78.6 | 217.2 | 147.6 | Viable–alternate
Weibull | 0.38 | | 79.8 | 286.6 | 186.7 | Viable–alternate
Logistic | 0.69 | | 77.9 | 428.7 | 354.6 | Viable–alternate
Log-probit | 0.36 | | 80.2 | 338.5 | 168.0 | Viable–alternate
Probit | 0.69 | | 77.7 | 392.9 | 321.3 | Viable–alternate

AIC = Akaike information criterion; BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk; BMDS = Benchmark Dose Software.

^a^ Chi-square p value = p value from the chi-square test for lack of fit. Values <0.1 fail to meet conventional goodness-of-fit criteria.

^b^ Bold text indicates the model selected for each response.

Table F-3 Benchmark Dose Modeling Results for Pancreatic Acinar Adenoma or Carcinoma (Combined) in Male Rats in the Two-year Feed Studies of Di(2-ethylhexyl) Phthalate

Model | Chi-square P Value^a^ | AIC | BMD_10_ (mg/kg/day) | BMDL_10_ (mg/kg/day) | BMDS Recommendation^b^
Perinatal and Postweaning Study (Study 1)
Dichotomous Hill | 0.08 | 227.8 | 85.9 | 56.8 | Questionable
Gamma | <0.0001 | 257.0 | 52.9 | 37.9 | Questionable
Log-logistic | <0.0001 | 252.2 | 28.2 | 17.7 | Questionable
Multistage Degree 4 | <0.0001 | 257.0 | 52.9 | 37.9 | Questionable
Multistage Degree 3 | <0.0001 | 257.0 | 52.9 | 37.9 | Questionable
Multistage Degree 2 | <0.0001 | 257.0 | 52.9 | 37.9 | Questionable
Multistage Degree 1 | <0.0001 | 257.0 | 52.9 | 37.9 | Questionable
Weibull | <0.0001 | 257.0 | 52.9 | 37.9 | Questionable
Logistic | <0.0001 | 264.6 | 110.6 | 84.1 | Questionable
Log-probit | <0.0001 | 251.5 | 33.1 | 13.5 | Questionable
Probit | <0.0001 | 264.6 | 110.9 | 86.3 | Questionable
Postweaning-only Study (Study 2)
Dichotomous Hill | 0.11 | 205.1 | 70.2 | 20.4 | Viable–alternate
Gamma | 0.07 | 205.3 | 44.7 | 35.0 | Questionable
Log-logistic | 0.13 | 204.6 | 31.0 | 20.2 | Viable–recommended
Multistage Degree 4 | 0.07 | 205.3 | 44.7 | 35.0 | Questionable
Multistage Degree 3 | 0.07 | 205.3 | 44.7 | 35.0 | Questionable
Multistage Degree 2 | 0.07 | 205.3 | 44.7 | 35.0 | Questionable
Multistage Degree 1 | 0.07 | 205.3 | 44.7 | 35.0 | Questionable
Weibull | 0.07 | 205.3 | 44.7 | 35.0 | Questionable
Logistic | 0.00 | 218.6 | 122.5 | 100.6 | Questionable
Log-probit | 0.11 | 204.9 | 32.6 | 15.3 | Viable–alternate
Probit | 0.00 | 217.6 | 115.8 | 96.9 | Questionable

AIC = Akaike information criterion; BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk; BMDS = Benchmark Dose Software.

^a^ Chi-square p value = p value from the chi-square test for lack of fit. Values <0.1 fail to meet conventional goodness-of-fit criteria.

^b^ Bold text indicates the model selected for each response.

Table F-4 Benchmark Dose Modeling Results for Uterine (Including Cervix) Adenocarcinoma, Adenoma, Squamous Cell Carcinoma, or Squamous Cell Papilloma (Combined) in Female Rats in the Two-year Feed Studies of Di(2-ethylhexyl) Phthalate

Model | Chi-square P Value^a^ | AIC | BMD_10_ (mg/kg/day) | BMDL_10_ (mg/kg/day) | BMDS Recommendation^b^
Perinatal and Postweaning Study (Study 1)
Dichotomous Hill | 0.21 | 107.8 | 224.7 | 169.7 | Viable–alternate
Gamma | 0.42 | 106.0 | 560.0 | 289.2 | Viable–alternate
Log-logistic | 0.42 | 106.0 | 558.7 | 276.0 | Viable–alternate
Multistage Degree 4 | 0.41 | 106.0 | 594.6 | 286.7 | Viable–alternate
Multistage Degree 3 | 0.41 | 106.0 | 594.6 | 286.7 | Viable–alternate
Multistage Degree 2 | 0.41 | 106.0 | 594.6 | 286.7 | Viable–alternate
Multistage Degree 1 | 0.52 | 104.4 | 520.3 | 275.4 | Viable–alternate
Weibull | 0.42 | 106.0 | 566.6 | 288.7 | Viable–alternate
Logistic | 0.60 | 104.1 | 594.2 | 432.2 | Viable–recommended
Log-probit | 0.43 | 105.9 | 524.7 | 254.6 | Viable–alternate
Probit | 0.60 | 104.10 | 578.3 | 405.4 | Viable–alternate
Postweaning-only Study (Study 2)
Dichotomous Hill | 0.33 | 147.6 | 180.6 | 116.6 | Viable–alternate
Gamma | 0.25 | 148.4 | 273.3 | 144.1 | Viable–alternate
Log-logistic | 0.25 | 148.4 | 267.5 | 127.5 | Viable–alternate
Multistage Degree 4 | 0.25 | 148.5 | 272.6 | 143.1 | Viable–alternate
Multistage Degree 3 | 0.25 | 148.5 | 272.9 | 143.1 | Viable–alternate
Multistage Degree 2 | 0.25 | 148.5 | 272.6 | 143.1 | Viable–alternate
Multistage Degree 1 | 0.41 | 146.6 | 224.4 | 141.7 | Viable–alternate
Weibull | 0.25 | 148.4 | 272.6 | 143.9 | Viable–alternate
Logistic | 0.39 | 146.7 | 344.0 | 268.9 | Viable–alternate
Log-probit | 0.26 | 148.2 | 260.3 | 96.7 | Viable–alternate
Probit | 0.41 | 146.6 | 324.1 | 249.0 | Viable–recommended

AIC = Akaike information criterion; BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk; BMDS = Benchmark Dose Software.

^a^ Chi-square p value = p value from the chi-square test for lack of fit. Values <0.1 fail to meet conventional goodness-of-fit criteria.

^b^ Bold text indicates the model selected for each response.

Figure F-1

Benchmark Dose Modeling Results for Hepatocellular Adenoma or Carcinoma (Combined) in Male Rats in the Two-year Feed Studies of Di(2-ethylhexyl) Phthalate

BMR = benchmark response; BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk.

Figure F-2

Benchmark Dose Modeling Results for Hepatocellular Adenoma or Carcinoma (Combined) in Female Rats in the Two-year Feed Studies of Di(2-ethylhexyl) Phthalate

BMR = benchmark response; BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk.

Figure F-3

Benchmark Dose Modeling Results for Pancreatic Adenoma or Carcinoma (Combined) in Male Rats in the Two-year Feed Studies of Di(2-ethylhexyl) Phthalate

BMR = benchmark response; BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk.

Figure F-4

Benchmark Dose Modeling Results for Uterine (Including Cervix) Adenocarcinoma, Adenoma, Squamous Cell Carcinoma, or Squamous Cell Papilloma (Combined) in Female Rats in the Two-year Feed Studies of Di(2-ethylhexyl) Phthalate

BMR = benchmark response; BMD_10_ = benchmark dose corresponding to a 10% extra risk; BMDL_10_ = 95% lower bound on the benchmark dose corresponding to a 10% extra risk.