# Appendix E Mono(2-ethylhexyl) Phthalate Internal Dose Assessment

## E.1 Sample Collection

Select dams and their litters were removed on gestation day (GD) 18 to quantify mono(2-ethylhexyl) phthalate (MEHP) plasma and tissue concentrations. On GD 18, blood was collected from the retroorbital sinus of randomly selected dams (n = 5 per exposure group). Blood samples were collected in tubes containing K_3_ EDTA (tripotassium ethylene diamine tetraacetic acid), centrifuged, and the plasma harvested. Amniotic fluid was collected and pooled by dam, and each dam’s fetuses were collected and pooled by litter. All samples were flash frozen in liquid nitrogen and stored frozen at approximately −20°C before shipment to RTI International (Research Triangle Park, NC) for analysis.

## E.2 Sample Analysis

MEHP, a metabolite of di(2-ethylhexyl) phthalate, was measured in dam plasma, amniotic fluid, and fetal homogenate using a validated analytical method. The analyte stability in each matrix was also confirmed; corresponding data are given in Table E-1.

MEHP stock solutions were prepared in methanol at 0.5 mg/mL and diluted in water to prepare working standard solutions. A working internal standard (deuterated MEHP ([^2^H_4_]MEHP), C/D/N Isotopes Inc., Pointe-Claire, Canada) solution was prepared similarly at 1 µg/mL.

Plasma calibration standards were prepared at seven concentrations (25 to 5,000 ng/mL) by spiking 25 µL of plasma with an appropriate concentration of working MEHP standards. Plasma, amniotic fluid, and fetal homogenate quality control (QC) standards were prepared similarly at 100 and 2,500 ng/mL. Fetal homogenates were prepared by homogenizing fetuses in deionized water (1 g fetus in 3 mL water, equivalent to 250 mg/mL homogenate). Matrix blanks, method blanks, and study samples were prepared similarly to the matrix standards above but using 25 µL of water in place of the MEHP working standard solution. To all samples, 25 μL of internal standard solution and 425 µL acetonitrile were added, vortexed, and centrifuged at approximately 8,000 g for 10 minutes at 4°C. The supernatant was transferred to clean vials for analysis. Study samples with responses greater than the highest calibration standard were diluted with corresponding extracted blank matrix to the validated range prior to analysis.

## E.3 Instrumentation and Quantitation

All samples were analyzed by ultra-performance liquid chromatography (UPLC) tandem mass spectrometry (MS/MS) using Waters ACQUITY UPLC (Milford, MA) coupled to an Applied Biosystems 4000 QTRAP (Sciex, Framingham, MA) mass spectrometer. Chromatography was performed using Waters ACQUITY UPLC BEH C18 column (2.1 × 50 mm, 1.8 μm). Mobile phases A (water) and B (acetonitrile) were run with a linear gradient from 20% B to 95% B in 4.5 minutes at a flow rate of 0.5 mL/minute. The electrospray ion source was operated in negative ion mode with a voltage of −4,500 volts and source temperature of 450°C. Transitions monitored for MEHP and [^1^H_4_] were 277.1 → 133.8 and 281.0 → 137.8, respectively.

Calibration curves relating the response ratio of analyte to internal standard and the concentration of MEHP in a matrix were constructed using a 1/X^2^ weighted linear regression. The concentrations of MEHP in the samples were calculated using response ratio, the regression equation, initial sample weight or volume, and dilution when applicable. The concentration was reported as ng/mL for plasma and amniotic fluid. The fetal homogenate concentration estimated in ng/mL of fetal homogenate was converted to ng/g fetus by using a conversion factor of 4 (i.e., 4 mL homogenate = 1 g of fetus).

The performance of the calibration curve was evaluated before the analysis of each sample set. A successful calibration was indicated by the following: correlation coefficient (r) ≥ 0.99; relative standard deviation (RSD) ≤ ± 15% (except at the limit of quantitation [LOQ] where RSD is ≤ ± 20%); relative error (RE) ≤ ± 15% (except at the LOQ where RE is ≤ ± 20%). Data from study samples were considered valid if they were bracketed by valid QC sets. In general, each sample set, method blanks, and controls were bracketed by two QC sets, which consisted of a calibration blank and two concentrations of calibration standards (QC low and QC high). A QC set passed when the measured concentration for QC standards was within 15% of its nominal value. If the QC standard failed, it was necessary to reanalyze the bracketed samples. Correlation coefficient, r, for all calibration curves was ≥0.99. All QC standards were within 15% of nominal concentrations for plasma, amniotic fluid, and fetal homogenates.

Low concentrations of MEHP were observed in plasma, amniotic fluid, and fetal homogenates used as blank matrices, some of which were attributed to background contributions from the reagents and vials used in the assay. The background contribution from the reagents/vials did not affect the quantitation of study samples because matrix calibration standards and study samples were prepared and quantified similarly. In general, the background concentrations estimated in amniotic fluid and fetal homogenates were slightly higher than those observed in plasma, although the reason is not clear.

Table E-1 Analytical Method Validation and Stability Data for Mono(2-ethylhexyl) Phthalate in Plasma, Amniotic Fluid, and Fetal Homogenate^a^

Validation Parameter | Dam Plasma | Amniotic Fluid | Fetal Homogenate
Matrix Concentration Range (ng/mL) | 25–5,000 | – | –
LOQ (ng/mL or ng/g) | 25.0 | 50.0 | 200
LOD^b^ (µg/g) | 5.2 | 12.0 | 10
Correlation Coefficient (r) | ≥0.998 | – | –
Selectivity (%)^c^ | 40 | 53 | 54
Recovery (%)^d^ | 95.0–102.0 | – | –
Precision and Accuracy^e,f^
Intra-day % RSD | ≤4.1 | ≤4.2 | ≤7.1
Intra-day % RE | ≤ ± 2.9 | ≤ ± 4.7 | ≤ ± 5.6
Inter-day % RSD | ≤5.2 | – | –
Inter-day % RE | ≤ ± 5.8 | – | –
Dilution Verification (50,000 ng/mL)
% RSD | 0.8 | – | –
% RE | 1.7 | – | –
Extracted Sample Storage Stability (% of Day 0)^f^
Ambient | 102–105 | – | –
Refrigerator | 97–107 | – | –
Freeze-thaw (3 cycles) | 103–106 | – | –
Matrix Storage Stability (% of Day 0)^g^ | 80–113 | 80–115 | 84–113

LOQ = limit of quantitation; LOD = limit of detection; RSD = relative standard deviation; RE = relative error.

^a^ Method was fully validated in Harlan Sprague Dawley rat plasma and assessed in amniotic fluid and fetal homogenate using quality control samples prepared in each matrix at three concentrations (100, 500, and 2,500 ng/g).

^b^ Estimated as the standard error of LOQ.

^c^ Estimated using six replicate blank matrix response relative to LOQ response.

^d^ Estimated by comparing response of matrix standards to solvent standards over the concentration range 25 to 5,000 ng/mL.

^e^ Precision was estimated as % RSD. Accuracy was estimated as % RE.

^f^ Determined for three replicate quality controls at three levels (100, 500, and 2,500 ng/mL) for up to 3 days.

^g^ Determined for three replicate quality controls at two levels (100 and 3,750 ng/mL) stored at −20°C for up to 62 days.