# Appendix D Genetic Toxicology

## D.1 Rodent Chromosome Aberrations Test

### D.1.1 Methods

Female B6C3F1 mice (four animals per exposure group) were exposed to di(2-ethylhexyl) phthalate (DEHP) (0, 3,000, 6,000, or 12,000 ppm) in dosed feed for 14 days. The animals were subcutaneously implanted with a bromodeoxyuridine (BrdU) tablet^241^ 18 hours before the scheduled harvest to allow selection of the appropriate cell population for scoring.^242,243^ Chromosomal aberrations induced by test article administration are present in maximum number at the first metaphase following exposure; they decline in number during subsequent nuclear divisions due to cell death. Two hours before sacrifice, the animals received an intraperitoneal injection of colchicine in saline. The animals were euthanized 18 hours after BrdU dosing. One or both femurs were removed, and the marrow was flushed out with phosphate-buffered saline (pH 7.0). Cells were treated with a hypotonic salt solution, fixed, and dropped onto chilled slides. After a 24-hour drying period, the slides were stained (with a modified fluorescence-plus-Giemsa technique) and scored.

Fifty first-division metaphase cells were scored from each animal. Responses were evaluated as the percentage of aberrant metaphase cells, excluding gaps. The data were analyzed by a trend test^244^ with p ≤ 0.025 considered to be significant. Pairwise comparisons of each exposure group to the corresponding solvent control group were considered significant for p ≤ 0.025/3 (the number of DEHP-exposed groups).

### D.1.2 Results

In vivo, no significant increases were observed in chromosomal aberrations in bone marrow cells of female B6C3F1 mice following administration of DEHP (3,000–12,000 ppm) in dosed feed for 14 days (Table D-1).

Table D-1 Chromosomal Aberrations in Mice Exposed to Di(2-ethylhexyl) Phthalate in Feed for 14 Days^a,b^

| n | Percent Cells with Aberrations | P Value (Pairwise)
DEHP (ppm)
0 | 4 | 1.25 ± 0.48 | 0.0000
3,000 | 4 | 2.75 ± 1.11 | 0.0649
6,000 | 4 | 0.50 ± 0.29 | 0.8726
12,000 | 4 | 1.50 ± 0.87 | 0.3807
Trend^c^ | | p = 0.6617

DEHP = di(2-ethylhexyl) phthalate.

^a^ Data are presented as the mean frequency of aberrant cells ± standard error. Gaps were not included in the calculation of the mean frequency of chromosomally aberrant cells.

^b^ Pairwise comparisons to the vehicle control group performed using a t-test (p ≤ 0.025/number of exposed groups).

^c^ Exposure-related trends evaluated using the Cochran-Armitage trend test (p ≤ 0.025).

## D.2 In Vivo Micronucleus Test

### D.2.1 Methods

#### D.2.1.1 Bone Marrow

Female B6C3F1 mice (10 animals per exposure group) were exposed to DEHP (0, 3,000, 6,000, or 12,000 ppm) in dosed feed for 14 days. Bone marrow smears were prepared from cells obtained from the femurs as described for the chromosomal aberrations assay. Air-dried smears were fixed and stained with acridine orange; 1,000 polychromatic erythrocytes (PCEs) were scored per animal for the frequency of micronucleated cells.

The results were tabulated as the mean of the pooled results from all animals within an exposure group ± the standard error of the mean. The frequency of micronucleated cells among PCEs was analyzed for positive trend over the four exposure groups using a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each exposed group and the concurrent control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. For a test to be considered positive, the trend test p value ≤0.025 is required, along with at least one significant exposure group (p ≤ 0.025 divided by the number of exposed groups). Ultimately, the final call is determined by scientific staff after considering the results of statistical analyses, the reproducibility of any effects observed, and the magnitudes of those effects.

#### D.2.1.2 Peripheral Blood

A detailed discussion of this assay is presented by MacGregor et al.^245^ Two 26-week exposure protocols were used. In the first study, male and female TgAC (FVB/N) transgenic mice were exposed to DEHP (0, 1,500, 3,000, or 6,000 ppm) in dosed feed. In the second study, male and female TgAC (FVB/N) transgenic mice were exposed to DEHP (0, 100, 200, or 400 mg/kg) via dermal application. In both studies, at the end of the 26-week exposure period, peripheral blood samples were obtained. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronuclei in 1,000 normochromatic erythrocytes (NCEs) and 1,000 PCEs per animal.

The results were tabulated as the mean of the pooled results from all animals within an exposure group ± the standard error of the mean. The frequency of micronucleated NCEs was analyzed as described above for the bone marrow micronucleus test.

#### D.2.1.3 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay, and differing results were obtained among aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. For in vitro assays conducted with and without exogenous metabolic activation, results from each testing condition are evaluated and reported separately. The summary table in the abstract of this Technical Report presents a result that represents a scientific judgement of the overall evidence for activity of the chemical in an assay.

### D.2.2 Results

DEHP was tested in three independent erythrocyte micronucleus tests and produced varying results (Table D-2, Table D-3, Table D-4). In an in vivo bone marrow micronucleus test, B6C3F1 female mice were exposed to DEHP (3,000–12,000 ppm) in dosed feed for 14 days; results were judged to be equivocal (Table D-2). In a second test, DEHP (1,500–6,000 ppm) induced an equivocal response in male TgAC (FVB/N) mice and a positive response in female TgAC (FVB/N) mice following exposure via dosed feed for 26 weeks (Table D-3). Another 26-week exposure test in TgAC (FVB/N) mice using dermal application of DEHP (100–400 mg/kg) produced negative results in both male and female mice (Table D-4).

Table D-2 Frequency of Micronuclei in the Bone Marrow of Female B6C3F1 Mice Exposed to Di(2-ethylhexyl) Phthalate in Feed for 14 Days

| Micronucleated PCEs/1,000 PCEs^a^ | P Value^b^ | Micronucleated NCEs/1,000 NCEs^a^ | P Value^b^
n | 10 | 10 | 10 | 10
DEHP (ppm)
0 | 1.90 ± 0.43 | | 0.70 ± 0.26
3,000 | 1.20 ± 0.33 | 0.8958 | 0.90 ± 0.31 | 0.3085
6,000 | 1.10 ± 0.38 | 0.9281 | 1.50 ± 0.37 | 0.0440
12,000 | 1.50 ± 0.34 | 0.7538 | 2.00 ± 0.42 | 0.0061
Trend^c^ | p = 0.6970 | | p = 0.0020

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte; DEHP = di(2-ethylhexyl) phthalate.

^a^ Data are presented as mean ± standard error.

^b^ Pairwise comparisons to the vehicle control group performed using a t-test (p ≤ 0.025/number of exposed groups).

^c^ Exposure-related trends evaluated by the Cochran-Armitage trend test (p ≤ 0.025).

Table D-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female TgAC (FVB/N) Mice Exposed to Di(2-ethylhexyl) Phthalate in Feed for 26 Weeks

| Micronucleated PCEs/1,000 PCEs^a^ | n | P Value^b^ | Micronucleated NCEs/1,000 NCEs^a^ | n | P Value^b^ | PCEs (%)^a^
Male
DEHP (ppm)
0 | 2.00 ± 0.39 | 12 | | 2.83 ± 0.44 | 12 | | 3.46 ± 0.16
1,500 | – | – | | 2.18 ± 0.40 | 11 | 0.7975 | –
3,000 | – | – | | 3.00 ± 0.58 | 13 | 0.4182 | –
6,000 | 3.67 ± 0.76 | 9 | 0.0108 | 4.33 ± 1.17 | 9 | 0.0610 | 3.10 ± 0.14
Trend^c^ | p = 0.0110 | | | p = 0.0260
Female
DEHP (ppm)
0 | 2.50 ± 0.56 | 10 | | 1.40 ± 0.27 | 10 | | 3.47 ± 0.63
1,500 | – | – | | 2.31 ± 0.38 | 13 | 0.0592 | –
3,000 | – | – | | 1.50 ± 0.43 | 6 | 0.4358 | –
6,000 | 1.27 ± 0.33 | 11 | 0.9804 | 3.27 ± 0.51 | 11 | 0.0027 | 3.18 ± 0.18
Trend^c^ | p = 0.9800 | | | p = 0.0040

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte; DEHP = di(2-ethylhexyl) phthalate.

^a^ Data are presented as mean ± standard error.

^b^ Pairwise comparisons to the vehicle control group performed using a t-test (p ≤ 0.025/number of exposed groups).

^c^ Exposure-related trends evaluated by the Cochran-Armitage trend test (p ≤ 0.025).

Table D-4 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female TgAC (FVB/N) Mice Following Dermal Application of Di(2-ethylhexyl) Phthalate for 26 Weeks

| Micronucleated PCEs/1,000 PCEs^a^ | n | P Value^b^ | Micronucleated NCEs/1,000 NCEs^a^ | n | P Value^b^ | PCEs (%)^a^
Male
DEHP (mg/kg)
0 | 2.45 ± 0.51 | 11 | | 3.45 ± 0.59 | 11 | | 4.20 ± 0.34
100 | – | – | | 3.17 ± 0.34 | 12 | 0.6480 | –
200 | – | – | | 3.36 ± 0.37 | 14 | 0.5522 | –
400 | 3.86 ± 0.67 | 7 | 0.0467 | 2.71 ± 0.68 | 7 | 0.8056 | 3.21 ± 0.28
Trend^c^ | p = 0.0470 | | | p = 0.7700
Female
DEHP (mg/kg)
0 | 2.55 ± 0.47 | 11 | | 1.64 ± 0.36 | 11 | | 4.86 ± 0.34
100 | – | – | | 1.91 ± 0.41 | 11 | 0.3153 | –
200 | – | – | | 2.36 ± 0.49 | 11 | 0.1137 | –
400 | 4.09 ± 0.56 | 11 | 0.0231 | 2.55 ± 0.45 | 11 | 0.0700 | 4.24 ± 0.19
Trend^c^ | p = 0.0230 | | | p = 0.0590

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte; DEHP = di(2-ethylhexyl) phthalate.

^a^ Data are presented as mean ± standard error.

^b^ Pairwise comparisons to the vehicle control group performed using a t-test (p ≤ 0.025/number of exposed groups).

^c^ Exposure-related trends evaluated by the Cochran-Armitage trend test (p ≤ 0.025).