# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that might affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals are from the same production source and weanling groups as the animals used for the studies of test compounds.

For these toxicology and carcinogenesis studies, blood samples were collected from each sentinel animal, allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for endoparasites and Helicobacter species. All samples were processed appropriately with serology and Helicobacter testing performed by IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO, for determination of the presence of pathogens. Evaluation for endo- and ectoparasites was performed in-house by the testing laboratory.

The laboratory methods and agents for which testing was performed are tabulated in Table C-1, Table C-2 below; the times at which samples were collected during the studies are also listed.

## C.2 Results

### C.2.1 Perinatal and Postweaning Study (Study 1)

Rats: Positive for endoparasites, pinworms (Syphacia spp.). All other test results were negative.

### C.2.2 Postweaning-only Study (Study 2)

Rats: Positive for endoparasites, pinworms (Syphacia spp.). All other test results were negative.

Table C-1 Methods and Results for Sentinel Animal Testing in Male and Female Rats (Study 1)

Collection Time Points | Quarantine^a^ | 3.5 Weeks^b^ | 4 Weeks Post-Study Start^c^ | 6 Months | 12 Months | 18 Months | End of Study
Number Examined (Males/Females) | 0/10 | 0/10 | 5/5 | 5/5 | 6/6^d^ | 5/6^e^ | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | − | − | − | − | − | − | −
Mycoplasma pulmonis | − | − | − | − | − | − | −
Parvo NS-1 | − | − | − | − | − | − | −
Pneumonia virus of mice (PVM) | − | − | − | − | − | − | −
Rat coronavirus/ sialodacryoadenitis virus (RCV/SDA) | − | − | − | − | − | − | −
Rat minute virus (RMV) | − | − | − | − | − | − | −
Rat parvo virus (RPV) | − | − | − | − | − | − | −
Rat theilovirus (RTV) | − | − | − | − | − | − | −
Sendai | − | − | − | − | − | − | −
Theiler’s murine encephalomyelitis virus (TMEV) | − | − | − | − | − | − | −
Toolan’s H-1 | − | − | − | − | − | − | −
Immunofluorescence Assay (IFA)
Pneumocystis carinii | NT | NT | NT | − | NT | NT | NT
In-house Evaluation
Endoparasite evaluation (evaluation of cecal content) | − | NT | NT | NT | + | + | NT
Ectoparasite evaluation (evaluation of perianal surface) | − | NT | NT | NT | − | − | NT

− = negative; + = positive; NT = not tested.

^a^ Age-matched nonpregnant females.

^b^ Time-mated females that did not have a litter; 3.5 weeks after arrival.

^c^ F_1_ sentinel animals tested 4 weeks after 2-year study start.

^d^ Includes samples from one male and one female euthanized as moribund.

^e^ Includes samples from one female euthanized as moribund.

Table C-2 Methods and Results for Sentinel Animal Testing in Male and Female Rats (Study 2)

Collection Time Points | 4 Weeks^a^ | 6 Months | 12 Months | 18 Months | End of Study
Number Examined (Males/Females) | 5/5 | 5/5 | 5/5 | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | − | − | − | − | −
Mycoplasma pulmonis | − | − | − | − | −
Parvo NS-1 | − | − | − | − | −
Pneumonia virus of mice (PVM) | − | − | − | − | −
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | − | − | − | − | −
Rat minute virus (RMV) | − | − | − | − | −
Rat parvo virus (RPV) | − | − | − | − | −
Rat theilovirus (RTV) | − | − | − | − | −
Sendai | − | − | − | − | −
Theiler’s murine encephalomyelitis virus (TMEV) | − | − | − | − | −
Toolan’s H-1 | − | − | − | − | −
Immunofluorescence Assay (IFA)
Kilham rat virus (KRV) | − | NT | NT | NT | NT
Pneumocystis carinii | NT | − | NT | NT | NT
Number Examined (Males/Females) | 0/0 | 0/0 | 6/5 | 6/5 | 0/0
Method/Test
In-house Evaluation
Endoparasite evaluation (evaluation of cecal content) | NT | NT | + | + | NT
Ectoparasite evaluation (evaluation of perianal surface) | NT | NT | + | + | NT

− = negative; + = positive; NT = not tested.

^a^ Postquarantine.