# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization of Di(2-ethylhexyl) Phthalate

Di(2-ethylhexyl) phthalate (DEHP) was obtained from Aldrich Chemical Company Inc. (St. Louis, MO) in a single lot (lot 01514TH) received in two shipments. The first shipment (10 L) was received on December 12, 2008 and used for chemical characterization. The second shipment (250 L) was received on November 4, 2009 and used for the dose formulations in the 2-year studies and chemical reanalysis. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at RTI International (Research Triangle Park, NC). Reports on analyses performed in support of the DEHP studies are on file at the National Institute of Environmental Health Sciences.

The appearance (clear liquid) and density of lot 01514TH (0.976 g/mL at 21.9°C) matched that of DEHP (0.985 g/mL at 25°C). Galbraith Laboratories (Knoxville, TN) performed the boiling point and elemental analyses of lot 01514TH. While the elemental analysis confirmed the anticipated relative ratios, the experimental boiling point (330.9°C) was considerably lower than that reported in the literature (384°C). Using a different method, the results (335°C, 760 mm Hg) from RTI International were consistent with Galbraith Laboratories. A precise molecular mass was measured using research-grade high-resolution mass spectrometry (HRMS) at the University of South Carolina Mass Spectrometry Facility (Columbia, SC). The observed mass values (390.2772) were within acceptable limits (≤5 ppm) of the calculated mass (390.2770).

The identity of lot 01514TH was confirmed using infrared (IR) spectroscopy, ^1^H and ^13^C nuclear magnetic resonance (NMR) spectroscopy, and gas chromatography (GC) with MS detection. The IR spectrum was in good agreement with the structure of DEHP and with the reference spectrum from the National Institute of Advanced Industrial Science and Technology Spectral Database for Organic Compounds (SDBS No. 2266) for DEHP (Figure A-1). ^1^H and ^13^C NMR spectra (Figure A-2, Figure A-3) were consistent with the structure of DEHP and the prediction from the Advanced Chemistry Development Spectral Prediction Program (Version 10.02, Toronto, Ontario, Canada) for DEHP. GC/MS identified the major peak from the 10 L shipment of lot 01514TH as DEHP using fragmentation pattern analysis and comparison with the National Institute of Standards and Technology (NIST) reference spectrum (No. 311338) for DEHP (Table A-1, System A). The GC/MS spectra correlated well with the structure of DEHP.

The moisture content of lot 01514TH was determined by Karl Fisher titration. The purity was determined using ultra-performance liquid chromatography (UPLC) with photodiode array detector (PDA) and using GC with flame ionization detection (FID) (Table A-1, Systems B and C, respectively). The Karl Fisher titration yielded a water content of 0.145%. UPLC/PDA analysis demonstrated one major peak accounting for 99.7% and one minor peak accounting for 0.2% of the total integrated area. GC/FID analysis also found one major peak accounting for 99.7% and one minor peak accounting for 0.3% of the total integrated area. An additional GC/MS analysis of the test chemical was performed in an attempt to identify the minor component in the chromatographic profile (Table A-1, System A). The fragmentation of the minor impurity peak agreed with the NIST reference spectrum (No. 312137) for mono(2-ethylhexyl) phthalate.

Accelerated stability studies were conducted by the analytical chemistry laboratory using samples of lot 01514TH stored at ambient temperature (approximately 22°C), refrigerated temperature (approximately 5°C), and elevated temperature (approximately 60°C) in amber vials sealed with foil-lined caps. After 14 days, samples were analyzed by GC/FID (Table A-1, System C). Stability of DEHP was confirmed for at least 2 weeks when stored in sealed glass vials at temperatures from 5°C to 60°C.

Upon receipt of the 250 L shipment used for the 2-year studies, the bulk chemical of lot 01514TH was homogenized by shaking each of the 5 50 L plastic jugs for approximately 2 minutes and transferred to 70 4 L amber glass storage bottles, which were stored at room temperature.

Prior to using the bulk chemical from the 250 L shipment of lot 01514TH for dose formulations, the identity was confirmed using the same GC/MS system with comparison to the reference spectrum and an aliquot of the test article from the 10L shipment (Table A-1, System A). The GC/MS analysis of the 250 L shipment of lot 01514TH demonstrated one major peak accounting for 99.9% of the total integrated area. Periodic reanalysis of the bulk chemical lot 01514TH was performed prior to and during the animal studies by the laboratory using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection (Table A-1, System D), and no degradation of the test chemical was detected.

## A.2 Preparation and Analysis of Dose Formulations

The base diet was meal feed purchased from Zeigler Brothers, Inc. (Gardners, PA). The perinatal and postweaning study (Study 1) utilized NIH-07 feed (2 lots milled March and April 2011) in addition to NTP-2000 feed (25 lots milled April 2011–March 2013). The postweaning-only study (Study 2) utilized NTP-2000 feed (25 lots milled December 2010–December 2012). In addition to determining the suitability of the vehicles for feeding the animals, analysis of the NTP-2000 feed extract performed by the study laboratory using liquid chromatography mass spectrometry (LC/MS) confirmed that the vehicle did not contain the test article DEHP.

Dose formulations were prepared monthly by mixing DEHP with feed (Table A-2). For the perinatal and postweaning study, formulations were prepared at concentrations of 0, 300, 1,000, 3,000, and 10,000 ppm in both NIH-07 feed (May 4, May 24, and June 15, 2011) and in NTP-2000 feed (31 formulations; June 2011–June 2013). For the postweaning-only study, formulations were prepared in NTP-2000 feed at concentrations of 0, 300, 1,000, 3,000, and 10,000 ppm (31 formulations; February 2011–February 2013). The plastic bags used by the study laboratory in the preparation and storage of blank and dosed feed were determined to have no levels of DEHP above the limit of detection of the assay (1.27 ppm).

Homogeneity studies were performed on the 25 and 10,000 ppm dose formulations in both 25-kg NIH-07 feed batch sizes and 25-kg NTP-2000 feed batch sizes by the analytical chemistry laboratory using UPLC/PDA (Table A-1, System B). Additional homogeneity studies of the 300 and 10,000 ppm dose formulations in a 72-kg NIH-07 feed batch size and 300, 3,000, and 10,000 ppm dose formulations in a 92-kg NTP-2000 feed batch sizes were performed before the animal studies by the study laboratory using HPLC/UV (Table A-1, System D). All formulations analyzed were determined to be homogenous and of appropriate concentration.

Stability studies conducted by the chemistry laboratory of the 25 ppm NIH-07 and 25 ppm NTP-2000 dose formulations confirmed the stability of DEHP after 42 days at room, refrigerated, or frozen temperatures. Stability was also confirmed under simulated dosing conditions (room temperature, exposure to air and light for 7 days, in absence of excreta, and in presence of excreta). Control and dosed formulations were stored in individual plastic bag-lined containers at room temperature (approximately 25°C) and were used within 42 days of preparation.

Periodic analyses of the preadministration dose formulations of DEHP were conducted by the study laboratory every 1 to 3 months to determine purity, while postadministration (animal room) samples were analyzed about every 1 to 7 months (Table A-3, Table A-4). All preadministration formulations were within 10% of the target concentrations. For the perinatal and postweaning study, all postadministration dose formulations of DEHP were within 10% of target concentrations. For the postweaning-only study (Study 2), all postadministration dose formulations of DEHP were within 10% of target concentrations except for the 1,000 ppm dose formulation prepared on July 30, 2012, collected from residual feed in the feeder that was 12.3% below the target concentration.

Table A-1 Chromatography Systems Used in the Two-year Feed Studies of Di(2-ethyhexyl) Phthalate

Chromatography | Detection System | Column | Mobile Phase
System A
Gas chromatography | Mass selective detector | J&W DB-1 (25 m × 0.32 mm ID, 0.25 μm film thickness) | Helium, 1.65 mL/min flow rate
System B
Ultra-performance liquid chromatography | Photodiode array detector (205 to 400 nm, extracted at 225 nm) | Waters Acquity UPLC BEH Phenyl (50 mm × 2.1 mm ID, 1.7 μm particle size), with Waters Acquity In-Line Filter (0.2 μm) | A: Methanol B: Water Gradient program: A:B 25:75 to 75:25 in 3 min, hold at 78:22 for 1 min, ramp to 100:0 in 1 min, hold at 100:0 for 1 min, reverse to 25:75 in 0.5 min, hold at 25:75 for 1.5 min 0.6 mL/min flow rate
System C
Gas chromatography | Flame ionization detection (325°C) | J&W HP-5 (30 m × 0.32 mm ID, 0.25 μm film thickness) | Helium, 1 mL/min flow rate
System D
High-performance liquid chromatography | Ultraviolet (225 nm) | Thermo Scientific Hypersil Phenyl (250 mm × 4.6 mm ID, 5 μm particle size) with Hypersil Phenyl guard (5 μm particle size) | A: Methanol B: ASTM Type I Water Gradient program: A:B 70:30 to 85:15 in 5 min, ramp to 100:0 in 4 min, hold at 100:0 for 4 min, reverse to 70:30 in 0.1 min, hold at 70:30 for 10.9 min 1.0 mL/min flow rate

ID = internal diameter; UPLC = ultra-performance liquid chromatography; ASTM = American Society for Testing and Materials.

Table A-2 Preparation and Storage of Dose Formulations in the Two-year Feed Studies of Di(2-ethylhexyl) Phthalate

Preparation
Stock solutions of di(2-ethylhexyl) phthalate (DEHP) were created by weighing an appropriate amount of lot 01514TH and adding it to a volumetric flask. Acetone was used to bring the solution to volume. Flasks of stocks solution were sealed and shaken until the chemical was dissolved (at least 10 inversions). An initial formulation premix was created by weighing an appropriate amount of feed (NIH-07 or NTP-2000) into a mixing bowl. A portion of the stock DEHP solution was slowly poured onto the feed and then stirred for 2 minutes at a low setting using a Hobart mixer. The mixer was stopped, and the remaining stock solution was poured onto the feed. The stock container was rinsed with acetone twice and the rinses were poured onto the feed. The premix feed was stirred under a nitrogen stream with a flow rate of 10 liters per minute for approximately an hour to encourage cyclonic flow and to ensure complete evaporation of the acetone. The formulation blends were prepared by adding half of the required blank feed to a twin shell blender and then evenly covering with the premix. The sides were “rinsed” twice with the remaining blank feed and added to the blender. The final formulation was mixed in the blender for 15 minutes. The dose formulations were prepared approximately every 4 weeks.
Chemical Lot Number
01514TH
Maximum Storage Time
42 days
Storage Conditions
Stored in sealed plastic bag-lined container at ~25°C
Study Laboratory
Battelle (Columbus, OH)

Table A-3 Results of Analyses of Dose Formulations Administered to Rats in the Perinatal and Postweaning Two-year Feed Study of Di(2-ethylhexyl) Phthalate

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
May 4, 2011 | May 5, 2011 | 0 | BLOQ | NA
May 4, 2011 | May 5, 2011 | 300 | 309 ± 5 | 3.0
May 4, 2011 | May 5, 2011 | 1,000 | 1,020 ± 20 | 2.0
May 4, 2011 | May 5, 2011 | 3,000 | 3,170 ± 70 | 5.7
May 4, 2011 | May 5, 2011 | 10,000 | 10,200 ± 100 | 2.0
June 6, 2011 | June 6, 2011 | 0 | BLOQ | NA
June 6, 2011 | June 6, 2011 | 300 | 291.5 | −2.8
June 6, 2011 | June 6, 2011 | 1,000 | 959.5 | −4.1
June 6, 2011 | June 6, 2011 | 3,000 | 2,885 | −3.8
June 6, 2011 | June 6, 2011 | 10,000 | 9,790 | −2.1
August 17, 2011 | August 19, 2011 | 0 | BLOQ | NA
August 17, 2011 | August 19, 2011 | 300 | 292.5 | −2.5
August 17, 2011 | August 19, 2011 | 1,000 | 982.5 | −1.8
August 17, 2011 | August 19, 2011 | 3,000 | 2,930 | −2.3
August 17, 2011 | August 19, 2011 | 10,000 | 9,805 | −2.0
October 31, 2011 | November 3, 2011 | 0 | BLOQ | NA
October 31, 2011 | November 3, 2011 | 300 | 287.5 | −4.2
October 31, 2011 | November 3, 2011 | 1,000 | 922 | −7.8
October 31, 2011 | November 3, 2011 | 3,000 | 2,875 | −4.2
October 31, 2011 | November 3, 2011 | 10,000 | 9,560 | −4.4
January 12, 2012 | January 13, 2012 | 0 | BLOQ | NA
January 12, 2012 | January 13, 2012 | 300 | 305 | 1.7
January 12, 2012 | January 13, 2012 | 1,000 | 993 | −0.7
January 12, 2012 | January 13, 2012 | 3,000 | 2,990 | −0.3
January 12, 2012 | January 13, 2012 | 10,000 | 10,100 | 1.0
March 26, 2012 | March 29, 2012 | 0 | BLOQ | NA
March 26, 2012 | March 29, 2012 | 300 | 307.5 | 2.5
March 26, 2012 | March 29, 2012 | 1,000 | 1,020 | 2.0
March 26, 2012 | March 29, 2012 | 3,000 | 3,045 | 1.5
March 26, 2012 | March 29, 2012 | 10,000 | 10,350 | 3.5
June 6, 2012 | June 7, 2012 | 0 | BLOQ | NA
June 6, 2012 | June 7, 2012 | 300 | 295 | −1.7
June 6, 2012 | June 7, 2012 | 1,000 | 983 | −1.7
June 6, 2012 | June 7, 2012 | 3,000 | 2,990 | −0.3
June 6, 2012 | June 7, 2012 | 10,000 | 9,850 | −1.5
July 30, 2012 | August 1, 2012 | 0 | BLOQ | NA
July 30, 2012 | August 1, 2012 | 300 | 300.5 | 0.2
July 30, 2012 | August 1, 2012 | 1,000 | 997.5 | −0.3
July 30, 2012 | August 1, 2012 | 3,000 | 3,040 | 1.3
July 30, 2012 | August 1, 2012 | 10,000 | 10,200 | 2.0
October 8, 2012 | October 8, 2012 | 0 | BLOQ | NA
October 8, 2012 | October 8, 2012 | 300 | 314.5 | 4.8
October 8, 2012 | October 8, 2012 | 1,000 | 998 | −0.2
October 8, 2012 | October 8, 2012 | 3,000 | 2,860 | −4.7
October 8, 2012 | October 8, 2012 | 10,000 | 9,895 | −1.1
December 18, 2012 | December 18, 2012 | 0 | BLOQ | NA
December 18, 2012 | December 18, 2012 | 300 | 292 | −2.7
December 18, 2012 | December 18, 2012 | 1,000 | 971 | −2.9
December 18, 2012 | December 18, 2012 | 3,000 | 3,015 | 0.5
December 18, 2012 | December 18, 2012 | 10,000 | 9,845 | −1.6
March 4, 2013 | March 5, 2013 | 0 | BLOQ | NA
March 4, 2013 | March 5, 2013 | 300 | 302 ± 2 | 0.7
March 4, 2013 | March 5, 2013 | 1,000 | 998 ± 3 | −0.2
March 4, 2013 | March 5, 2013 | 3,000 | 3,000 ± 40 | 0.0
March 4, 2013 | March 5, 2013 | 10,000 | 10,000 ± 200 | 0.0
April 22, 2013 | April 22, 2013 | 0 | BLOQ | NA
April 22, 2013 | April 22, 2013 | 300 | 299 ± 3 | −0.3
April 22, 2013 | April 22, 2013 | 1,000 | 995 ± 2 | −0.5
April 22, 2013 | April 22, 2013 | 3,000 | 2,970 ± 10 | −1.0
April 22, 2013 | April 22, 2013 | 10,000 | 9,840 ± 30 | −1.6
Animal Room Samples
May 4, 2011 | June 13, 2011 (feeder) | 0 | BLOQ | NA
May 4, 2011 | June 13, 2011 (feeder) | 300 | 279 ± 1 | −6.9
May 4, 2011 | June 13, 2011 (feeder) | 1,000 | 939 ± 3 | −6.1
May 4, 2011 | June 13, 2011 (feeder) | 3,000 | 2,870 ± 30 | −4.5
May 4, 2011 | June 13, 2011 (feeder) | 10,000 | 9,480 ± 50 | −5.2
May 4, 2011 | June 13, 2011 (bucket) | 0 | BLOQ | NA
May 4, 2011 | June 13, 2011 (bucket) | 300 | 294 ± 1 | −2.1
May 4, 2011 | June 13, 2011 (bucket) | 1,000 | 957 ± 24 | −4.3
May 4, 2011 | June 13, 2011 (bucket) | 3,000 | 2,920 ± 130 | −2.7
May 4, 2011 | June 13, 2011 (bucket) | 10,000 | 9,560 ± 120 | −4.4
June 6, 2011 | July 19, 2011 (feeder) | 0 | BLOQ | NA
June 6, 2011 | July 19, 2011 (feeder) | 300 | 295 ± 2 | −1.8
June 6, 2011 | July 19, 2011 (feeder) | 1,000 | 960 ± 1 | −4.0
June 6, 2011 | July 19, 2011 (feeder) | 3,000 | 2,880 ± 20 | −4.0
June 6, 2011 | July 19, 2011 (feeder) | 10,000 | 10,000 ± 0 | 0.0
June 6, 2011 | July 19, 2011 (bucket) | 0 | BLOQ | NA
June 6, 2011 | July 19, 2011 (bucket) | 300 | 302 ± 1 | 0.5
June 6, 2011 | July 19, 2011 (bucket) | 1,000 | 1,000 ± 10 | 0.3
June 6, 2011 | July 19, 2011 (bucket) | 3,000 | 3,000 ± 30 | 0.1
June 6, 2011 | July 19, 2011 (bucket) | 10,000 | 9,770 ± 120 | −0.3
January 12, 2012 | February 23, 2012 (feeder) | 0 | BLOQ | NA
January 12, 2012 | February 23, 2012 (feeder) | 300 | 298 ± 1 | −0.6
January 12, 2012 | February 23, 2012 (feeder) | 1,000 | 958 ± 5 | −4.2
January 12, 2012 | February 23, 2012 (feeder) | 3,000 | 2,750 ± 30 | −8.3
January 12, 2012 | February 23, 2012 (feeder) | 10,000 | 9,270 ± 120 | −7.3
January 12, 2012 | February 23, 2012 (bucket) | 0 | BLOQ | NA
January 12, 2012 | February 23, 2012 (bucket) | 300 | 297 ± 3 | −0.9
January 12, 2012 | February 23, 2012 (bucket) | 1,000 | 980 ± 6 | −2.0
January 12, 2012 | February 23, 2012 (bucket) | 3,000 | 2,900 ± 30 | −3.4
January 12, 2012 | February 23, 2012 (bucket) | 10,000 | 9,360 ± 130 | −6.4
July 30, 2012 | September 5, 2012 (feeder) | 0 | BLOQ | NA
July 30, 2012 | September 5, 2012 (feeder) | 300 | 288 ± 1 | −4.1
July 30, 2012 | September 5, 2012 (feeder) | 1,000 | 1,020 ± 60 | 2.2
July 30, 2012 | September 5, 2012 (feeder) | 3,000 | 2,840 ± 60 | −5.3
July 30, 2012 | September 5, 2012 (feeder) | 10,000 | 9,190 ± 110 | −8.1
July 30, 2012 | September 5, 2012 (bucket) | 0 | BLOQ | NA
July 30, 2012 | September 5, 2012 (bucket) | 300 | 288 ± 2 | −4.1
July 30, 2012 | September 5, 2012 (bucket) | 1,000 | 1,000 ± 80 | 0.0
July 30, 2012 | September 5, 2012 (bucket) | 3,000 | 2,830 ± 130 | −5.7
July 30, 2012 | September 5, 2012 (bucket) | 10,000 | 9,920 ± 280 | −0.8
March 4, 2013 | April 15, 2013 (feeder) | 0 | BLOQ | NA
March 4, 2013 | April 15, 2013 (feeder) | 300 | 281 ± 2 | −6.2
March 4, 2013 | April 15, 2013 (feeder) | 1,000 | 909 ± 4 | −9.1
March 4, 2013 | April 15, 2013 (feeder) | 3,000 | 2,740 ± 20 | −8.6
March 4, 2013 | April 15, 2013 (feeder) | 10,000 | 9,510 ± 20 | −4.9
March 4, 2013 | April 15, 2013 (bucket) | 0 | BLOQ | NA
March 4, 2013 | April 15, 2013 (bucket) | 300 | 289 ± 0 | −3.7
March 4, 2013 | April 15, 2013 (bucket) | 1,000 | NS | NA
March 4, 2013 | April 15, 2013 (bucket) | 3,000 | 2,910 ± 70 | −3.0
March 4, 2013 | April 15, 2013 (bucket) | 10,000 | 10,200 ± 200 | 2.0

BLOQ = below the limit of quantification; NA = not applicable; NS = no sample collected.

^a^ Preadministration samples are an average of triplicate analysis on two sample collections from the same preparation date. Animal room samples are an average and standard deviation of triplicate analysis of a single sample.

Table A-4 Results of Analyses of Dose Formulations Administered to Rats in the Postweaning-only Two-year Feed Study of Di(2-ethylhexyl) Phthalate

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
February 2, 2011 | February 5, 2011 | 0 | BLOQ | NA
February 2, 2011 | February 5, 2011 | 300 | 295 ± 5 | −1.7
February 2, 2011 | February 5, 2011 | 1,000 | 987 ± 38 | −1.3
February 2, 2011 | February 5, 2011 | 3,000 | 3,040 ± 10 | 1.3
February 2, 2011 | February 5, 2011 | 10,000 | 10,300 ± 300 | 3.0
March 28, 2011 | March 28, 2011 | 0 | BLOQ | NA
March 28, 2011 | March 28, 2011 | 300 | 300 ± 3 | 0.0
March 28, 2011 | March 28, 2011 | 1,000 | 991 ± 3 | −0.9
March 28, 2011 | March 28, 2011 | 3,000 | 2,990 ± 10 | −0.3
March 28, 2011 | March 28, 2011 | 10,000 | 9,880 ± 190 | −1.2
June 6, 2011 | June 6, 2011 | 0 | BLOQ | NA
June 6, 2011 | June 6, 2011 | 300 | 291.5 | −2.8
June 6, 2011 | June 6, 2011 | 1,000 | 959.5 | −4.1
June 6, 2011 | June 6, 2011 | 3,000 | 2,885 | −3.8
June 6, 2011 | June 6, 2011 | 10,000 | 9,790 | −2.1
August 17, 2011 | August 19, 2011 | 0 | BLOQ | NA
August 17, 2011 | August 19, 2011 | 300 | 292.5 | −2.5
August 17, 2011 | August 19, 2011 | 1,000 | 982.5 | −1.8
August 17, 2011 | August 19, 2011 | 3,000 | 2,930 | −2.3
August 17, 2011 | August 19, 2011 | 10,000 | 9,805 | −2.0
October 31, 2011 | November 3, 2011 | 0 | BLOQ | NA
October 31, 2011 | November 3, 2011 | 300 | 287.5 | −4.2
October 31, 2011 | November 3, 2011 | 1,000 | 922 | −7.8
October 31, 2011 | November 3, 2011 | 3,000 | 2,875 | −4.2
October 31, 2011 | November 3, 2011 | 10,000 | 9,560 | −4.4
January 12, 2012 | January 13, 2012 | 0 | BLOQ | NA
January 12, 2012 | January 13, 2012 | 300 | 305 | 1.7
January 12, 2012 | January 13, 2012 | 1,000 | 993 | −0.7
January 12, 2012 | January 13, 2012 | 3,000 | 2,990 | −0.3
January 12, 2012 | January 13, 2012 | 10,000 | 10,100 | 1.0
March 26, 2012 | March 29, 2012 | 0 | BLOQ | NA
March 26, 2012 | March 29, 2012 | 300 | 307.5 | 2.5
March 26, 2012 | March 29, 2012 | 1,000 | 1,020 | 2.0
March 26, 2012 | March 29, 2012 | 3,000 | 3,045 | 1.5
March 26, 2012 | March 29, 2012 | 10,000 | 10,350 | 3.5
June 6, 2012 | June 7, 2012 | 0 | BLOQ | NA
June 6, 2012 | June 7, 2012 | 300 | 295 | −1.7
June 6, 2012 | June 7, 2012 | 1,000 | 983 | −1.7
June 6, 2012 | June 7, 2012 | 3,000 | 2,990 | −0.3
June 6, 2012 | June 7, 2012 | 10,000 | 9,850 | −1.5
July 30, 2012 | August 1, 2012 | 0 | BLOQ | NA
July 30, 2012 | August 1, 2012 | 300 | 300.5 | 0.2
July 30, 2012 | August 1, 2012 | 1,000 | 997.5 | −0.3
July 30, 2012 | August 1, 2012 | 3,000 | 3,040 | 1.3
July 30, 2012 | August 1, 2012 | 10,000 | 10,200 | 2.0
October 8, 2012 | October 8, 2012 | 0 | BLOQ | NA
October 8, 2012 | October 8, 2012 | 300 | 314.5 | 4.8
October 8, 2012 | October 8, 2012 | 1,000 | 998 | −0.2
October 8, 2012 | October 8, 2012 | 3,000 | 2,860 | −4.7
October 8, 2012 | October 8, 2012 | 10,000 | 9,895 | −1.1
December 18, 2012 | December 18, 2012 | 0 | BLOQ | NA
December 18, 2012 | December 18, 2012 | 300 | 292 | −2.7
December 18, 2012 | December 18, 2012 | 1,000 | 971 | −2.9
December 18, 2012 | December 18, 2012 | 3,000 | 3,015 | 0.5
December 18, 2012 | December 18, 2012 | 10,000 | 9,845 | −1.6
Animal Room Samples
February 2, 2011 | March 17, 2011 (feeder) | 0 | BLOQ | NA
February 2, 2011 | March 17, 2011 (feeder) | 300 | 293 ± 6 | −2.2
February 2, 2011 | March 17, 2011 (feeder) | 1,000 | 933 ± 4 | −6.7
February 2, 2011 | March 17, 2011 (feeder) | 3,000 | 2,830 ± 30 | −5.6
February 2, 2011 | March 17, 2011 (feeder) | 10,000 | 9,430 ± 280 | −5.7
February 2, 2011 | March 17, 2011 (bucket) | 0 | BLOQ | NA
February 2, 2011 | March 17, 2011 (bucket) | 300 | 294 ± 6 | −1.9
February 2, 2011 | March 17, 2011 (bucket) | 1,000 | 972 ± 11 | −2.8
February 2, 2011 | March 17, 2011 (bucket) | 3,000 | 2,890 ± 40 | −3.6
February 2, 2011 | March 17, 2011 (bucket) | 10,000 | 9,460 ± 140 | −5.4
June 6, 2011 | July 19, 2011 (feeder) | 0 | BLOQ | NA
June 6, 2011 | July 19, 2011 (feeder) | 300 | 283 ± 3 | −5.7
June 6, 2011 | July 19, 2011 (feeder) | 1,000 | 973 ± 3 | −2.7
June 6, 2011 | July 19, 2011 (feeder) | 3,000 | 2,950 ± 10 | −1.7
June 6, 2011 | July 19, 2011 (feeder) | 10,000 | 9,780 ± 10 | −2.2
June 6, 2011 | July 19, 2011 (bucket) | 0 | BLOQ | NA
June 6, 2011 | July 19, 2011 (bucket) | 300 | 302 ± 1 | 0.5
June 6, 2011 | July 19, 2011 (bucket) | 1,000 | 1,000 ± 10 | 0.3
June 6, 2011 | July 19, 2011 (bucket) | 3,000 | 3,000 ± 30 | 0.1
June 6, 2011 | July 19, 2011 (bucket) | 10,000 | 9,770 ± 120 | −0.3
January 12, 2012 | February 23, 2012 (feeder) | 0 | BLOQ | NA
January 12, 2012 | February 23, 2012 (feeder) | 300 | 299 ± 4 | −0.2
January 12, 2012 | February 23, 2012 (feeder) | 1,000 | 925 ± 1 | −7.5
January 12, 2012 | February 23, 2012 (feeder) | 3,000 | 2,790 ± 30 | −6.9
January 12, 2012 | February 23, 2012 (feeder) | 10,000 | 9,260 ± 110 | −7.4
January 12, 2012 | February 23, 2012 (bucket) | 0 | BLOQ | NA
January 12, 2012 | February 23, 2012 (bucket) | 300 | 297 ± 3 | −0.9
January 12, 2012 | February 23, 2012 (bucket) | 1,000 | 980 ± 6 | −2.0
January 12, 2012 | February 23, 2012 (bucket) | 3,000 | 2,900 ± 30 | −3.4
January 12, 2012 | February 23, 2012 (bucket) | 10,000 | 9,360 ± 130 | −6.4
July 30, 2012 | September 5, 2012 (feeder) | 0 | BLOQ | NA
July 30, 2012 | September 5, 2012 (feeder) | 300 | 282 ± 4 | −6.1
July 30, 2012 | September 5, 2012 (feeder) | 1,000 | 877 ± 35 | −12.3
July 30, 2012 | September 5, 2012 (feeder) | 3,000 | 2,850 ± 10 | −5.1
July 30, 2012 | September 5, 2012 (feeder) | 10,000 | 9,200 ± 250 | −8.0
July 30, 2012 | September 5, 2012 (bucket) | 0 | BLOQ | NA
July 30, 2012 | September 5, 2012 (bucket) | 300 | 288 ± 2 | −4.1
July 30, 2012 | September 5, 2012 (bucket) | 1,000 | 1,000 ± 80 | 0.0
July 30, 2012 | September 5, 2012 (bucket) | 3,000 | 2,830 ± 130 | −5.7
July 30, 2012 | September 5, 2012 (bucket) | 10,000 | 9,920 ± 280 | −0.8

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Preadministration samples are an average of triplicate analysis on two sample collections from the same preparation date. Animal room samples are an average and standard deviation of triplicate analysis of a single sample.

Figure A-1

Reference Infrared Absorption Spectrum of Di(2-ethylhexyl) Phthalate

Reference spectra: National Institute of Advanced Industrial Science and Technology Spectral Database for Organic Compounds. SDBS No. 2266, https://sdbs.db.aist.go.jp/sdbs/cgi-bin/landingpage?spcode=IR-NIDA-08692 (accessed Mar 19, 2009).

Figure A-2

Fourier Transformed ^1^H Nuclear Magnetic Resonance Spectrum of Sample of Di(2-ethylhexyl) Phthalate (Lot 01514TH)

Reference spectra: National Institute of Advanced Industrial Science and Technology Spectral Database for Organic Compounds. SDBS No. 2266, https://sdbs.db.aist.go.jp/sdbs/cgi-bin/landingpage?spcode=NMR-HSP-03-645 (accessed Sep 22, 2009).

Figure A-3

Fourier Transformed ^13^C Nuclear Magnetic Resonance Spectrum of Sample of Di(2-ethylhexyl) Phthalate (Lot 01514TH)

Reference spectra: National Institute of Advanced Industrial Science and Technology Spectral Database for Organic Compounds. SDBS No. 2266, https://sdbs.db.aist.go.jp/sdbs/cgi-bin/landingpage?spcode=NMR-CDS-05-148 (accessed Sep 22, 2009).