# Overview

Phthalates are plasticizers typically used to provide flexibility to products composed of polyvinyl chloride plastic or vinyl chloride resins. Significant concerns have been raised about in utero and early-life phthalate exposure and resultant adverse reproductive, developmental, and carcinogenic effects.

Previous hazard assessments of phthalates typically did not assess the effects of exposure throughout the perinatal period (gestation and lactation), and no carcinogenicity assessments of phthalates have used a lifetime exposure paradigm that includes the perinatal period. Thus, whether developmental exposure would alter lifetime phthalate-associated carcinogenic risk is unknown. Exposure during these critical periods of development and growth might be relevant for the evaluation of lifetime toxicological and carcinogenic risk.

In response to these data gaps, the National Toxicology Program initiated a broad program of work to provide toxicity data and a cancer hazard assessment for lifetime exposure to environmental phthalates. The program would also provide critical data to inform cumulative and aggregate risk characterization efforts for multiple phthalates including di(2-ethylhexyl) phthalate, di-isobutyl phthalate, and di-n-butyl phthalate.