# References

1 Agency for Toxic Substance and Disease Registry (ATSDR). Toxicological profile for di-n-butyl phthalate. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service; 2001.
2 Hamilton DJ. Gas chromatographic measurement of volatility of herbicide esters. J Chromatogr A. 1980; 195(1):75–83. 10.1016/S0021-9673(00)81544-7 7391223
3 Cadogan D, Howick C. Plasticizers In: Kroschwitz J, Howe-Grant M, editors. Kirk-Othmer Encyclopedia of Chemical Technology. New York, NY: John Wiley & Sons Inc.; 1996. p. 258–290.
4 U.S. Environmental Protection Agency (USEPA). Chemical Data Reporting Database. 2012.
5 National Toxicology Program (NTP). NTP-CERHR monograph on the potential human reproductive and developmental effects of di-n-butyl phthalate (DPB). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2003.
6 European Chemicals Bureau (ECB). European Union risk assessment report for dibutyl phthalate. 2003.
7 International Programme for Chemical Safety (IPCS). Environmental health criteria for di-n-butyl phthalate. 1997.
8 Koo HJ, Lee BM. Estimated exposure to phthalates in cosmetics and risk assessment. J Toxicol Environ Health A. 2004; 67(23-24):1901–1914. 10.1080/15287390490513300 15513891
9 Al-Saleh I, Elkhatib R. Screening of phthalate esters in 47 branded perfumes. Environ Sci Pollut Res Int. 2016; 23(1):455–468. 10.1007/s11356-015-5267-z 26310707
10 Guo Y, Kannan K. A survey of phthalates and parabens in personal care products from the United States and its implications for human exposure. Environ Sci Technol. 2013; 47(24):14442–14449. 10.1021/es4042034 24261694
11 Broe A, Ennis ZN, Pottegard A, Hallas J, Ahern T, Damkier P. Population exposure to phthalate-containing drugs. Basic Clin Pharmacol Toxicol. 2017; 121(3):153–158. 10.1111/bcpt.12781 28371296
12 Hauser R, Duty S, Godfrey-Bailey L, Calafat AM. Medications as a source of human exposure to phthalates. Environ Health Perspect. 2004; 112(6):751–753. 10.1289/ehp.6804 15121520
13 Wang Y, Zhu H, Kannan K. A review of biomonitoring of phthalate exposures. Toxics. 2019; 7(2). 10.3390/toxics7020021 30959800
14 Centers for Disease Control and Prevention (CDC). National Health and Nutrition Examination Survey data. Hyattsville, MD: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Center for Health Statistics; 2013-2014. https://wwwn.cdc.gov/nchs/nhanes/continuousnhanes/default.aspx?BeginYear=2013
15 Petrovičová I, Kolena B, Šidlovská M, Pilka T, Wimmerová S, Trnovec T. Occupational exposure to phthalates in relation to gender, consumer practices and body composition. Environ Sci Pollut Res Int. 2016; 23(23):24125–24134. 10.1007/s11356-016-7394-6 27640056
16 Frederiksen H, Jorgensen N, Andersson AM. Correlations between phthalate metabolites in urine, serum, and seminal plasma from young Danish men determined by isotope dilution liquid chromatography tandem mass spectrometry. J Anal Toxicol. 2010; 34(7):400–410. 10.1093/jat/34.7.400 20822678
17 Kolatorova L, Vitku J, Vavrous A, Hampl R, Adamcova K, Simkova M, Parizek A, Starka L, Duskova M. Phthalate metabolites in maternal and cord plasma and their relations to other selected endocrine disruptors and steroids. Physiol Res. 2018; 67 Suppl 3:S473–S487. 10.33549/physiolres.933962 30484674
18 Silva MJ, Reidy JA, Herbert AR, Preau JL Jr, Needham LL, Calafat AM. Detection of phthalate metabolites in human amniotic fluid. Bull Environ Contam Toxicol. 2004; 72(6):1226–1231. 10.1007/s00128-004-0374-4 15362453
19 Main KM, Mortensen GK, Kaleva MM, Boisen KA, Damgaard IN, Chellakooty M, Schmidt IM, Suomi AM, Virtanen HE, Petersen JH, et al. Human breast milk contamination with phthalates and alterations of endogenous reproductive hormones in infants three months of age. Environ Health Perspect. 2006; 114(2):270–276. 10.1289/ehp.8075 16451866
20 Högberg J, Hanberg A, Berglund M, Skerfving S, Remberger M, Calafat AM, Filipsson AF, Jansson B, Johansson N, Appelgren M, et al. Phthalate diesters and their metabolites in human breast milk, blood or serum, and urine as biomarkers of exposure in vulnerable populations. Environ Health Perspect. 2008; 116(3):334–339. 10.1289/ehp.10788 18335100
21 Fromme H, Gruber L, Seckin E, Raab U, Zimmermann S, Kiranoglu M, Schlummer M, Schwegler U, Smolic S, Volkel W. Phthalates and their metabolites in breast milk—results from the Bavarian Monitoring of Breast Milk (BAMBI). Environ Int. 2011; 37(4):715–722. 10.1016/j.envint.2011.02.008 21406311
22 Kavlock R, Boekelheide K, Chapin R, Cunningham M, Faustman E, Foster P, Golub M, Henderson R, Hinberg I, Little R, et al. NTP Center for the Evaluation of Risks to Human Reproduction: Phthalates expert panel report on the reproductive and developmental toxicity of di-n-butyl phthalate. Reprod Toxicol. 2002; 16(5):489–527. 10.1016/S0890-6238(02)00033-3 12406493
23 Chan PKL, Meek ME. Di-n-butyl phthalate: Evaluation of risks to health from environmental exposure in Canada. J Environ Sci Health C Environ Carcinog Ecotoxicol Rev. 1994; 12(2):257–268. 10.1080/10590509409373444
24 Otake T, Yoshinaga J, Yanagisawa Y. Exposure to phthalate esters from indoor environment. J Expo Anal Environ Epidemiol. 2004; 14(7):524–528. 10.1038/sj.jea.7500352 15039795
25 Hines CJ, Hopf NB, Deddens JA, Silva MJ, Calafat AM. Estimated daily intake of phthalates in occupationally exposed groups. J Expo Sci Environ Epidemiol. 2011; 21(2):133–141. 10.1038/jes.2009.62 20010977
26 Hines CJ, Nilsen Hopf NB, Deddens JA, Calafat AM, Silva MJ, Grote AA, Sammons DL. Urinary phthalate metabolite concentrations among workers in selected industries: A pilot biomonitoring study. Ann Occup Hyg. 2009; 53(1):1–17. 18948546
27 Kwapniewski R, Kozaczka S, Hauser R, Silva MJ, Calafat AM, Duty SM. Occupational exposure to dibutyl phthalate among manicurists. J Occup Environ Med. 2008; 50(6):705–711. 10.1097/JOM.0b013e3181651571 18545098
28 Koniecki D, Wang R, Moody RP, Zhu J. Phthalates in cosmetic and personal care products: Concentrations and possible dermal exposure. Environ Res. 2011; 111(3):329–336. 10.1016/j.envres.2011.01.013 21315328
29 U.S. Consumer Product Safety Commission (CPSC). Consumer Product Safety Improvement Act of 2008. Public Law 110-314. 122 Stat. 3016.; 2008.
30 U.S. Consumer Product Safety Commission (CPSC). 16 CFR Part 1307. [Docket No. CPSC-2014-0033] Prohibition of Children’s Toys and Child Care Articles Containing Specified Phthalates. Final Rule. 2017.
31 Food and Drug Administration (FDA). Guidance for Industry Limiting the Use of Certain Phthalates as Excipients in CDER-Regulated Product. 2012. https://www.fda.gov/regulatory-information/search-fda-guidance-documents/limiting-use-certain-phthalates-excipients-cder-regulated-products
32 Food and Drug Administration (FDA). 21 CFR Parts 175, 176, 177, and 178 [Docket No. FDA-2018-F-3757] Flexible Vinyl Alliance; Filing of Food Additive Petition. Proposed Rule.; 2018.
33 Smith CC. Toxicity of butyl stearate, dibutyl sebacate, dibutyl phthalate, and methoxyethyl oleate. AMA Arch Ind Hyg Occup Med. 1953; 7(4):310–318. 13039587
34 U.S. Environmental Protection Agency (USEPA). Integrated Risk Information System (IRIS), chemical assessment summary, dibutyl phthalate; CASRN 84-74-2. 1987. https://cfpub.epa.gov/ncea/iris/iris_documents/documents/subst/0038_summary.pdf
35 Agency for Toxic Substance and Disease Registry (ATSDR). Minimal risk levels (MRLs). 2020. https://www.atsdr.cdc.gov/mrls/pdfs/ATSDR%20MRLs%20-%20March%202020%20-%20H.pdf
36 Takahashi T, Tanaka A. Biochemical studies on phthalic esters V. Comparative studies on in vitro hydrolysis of di-n-butyl phthalate isomers in rats. Arch Toxicol. 1989; 63(1):72–74. 10.1007/BF00334638 2742505
37 Foster PM, Cook MW, Thomas LV, Walters DG, Gangolli SD. Differences in urinary metabolic profile from di-n-butyl phthalate-treated rats and hamsters. A possible explanation for species differences in susceptibility to testicular atrophy. Drug Metab Dispos. 1983; 11(1):59–61. 6132798
38 White RD, Carter DE, Earnest D, Mueller J. Absorption and metabolism of three phthalate diesters by the rat small intestine. Food Cosmet Toxicol. 1980; 18(4):383–386. 10.1016/0015-6264(80)90194-7 7461517
39 Rowland IR, Cottrell RC, Phillips JC. Hydrolysis of phthalate esters by the gastro-intestinal contents of the rat. Food Cosmet Toxicol. 1977; 15(1):17–21. 10.1016/S0015-6264(77)80257-5 852780
40 Tanaka A, Matsumoto A, Yamaha T. Biochemical studies on phthalic esters. III. Metabolism of dibutyl phthalate (DBP) in animals. Toxicology. 1978; 9(1-2):109–123. 10.1016/0300-483X(78)90036-7 653732
41 Fennell TR, Krol WL, Sumner SC, Snyder RW. Pharmacokinetics of dibutylphthalate in pregnant rats. Toxicol Sci. 2004; 82(2):407–418. 10.1093/toxsci/kfh294 15456918
42 Chang LW, Hou ML, Tsai TH. Pharmacokinetics of dibutyl phthalate (DBP) in the rat determined by UPLC-MS/MS. Int J Mol Sci. 2013; 14(1):836–849. 10.3390/ijms14010836 23344044
43 Saillenfait AM, Payan JP, Fabry JP, Beydon D, Langonne I, Gallissot F, Sabate JP. Assessment of the developmental toxicity, metabolism, and placental transfer of di-n-butyl phthalate administered to pregnant rats. Toxicol Sci. 1998; 45(2):212–224. 10.1093/toxsci/45.2.212 9848128
44 Albro PW, Moore B. Identification of the metabolites of simple phthalate diesters in rat urine. J Chromatogr A. 1974;94:209–218. 10.1016/S0021-9673(01)92368-4 4844611
45 Lake BG, Phillips JC, Linnell JC, Gangolli SD. The in vitro hydrolysis of some phthalate diesters by hepatic and intestinal preparations from various species. Toxicol Appl Pharmacol. 1977; 39(2):239–248. 10.1016/0041-008X(77)90157-0 403636
46 Koch HM, Christensen KL, Harth V, Lorber M, Di Bruning T. -n-butyl phthalate (DnBP) and diisobutyl phthalate (DiBP) metabolism in a human volunteer after single oral doses. Arch Toxicol. 2012; 86(12):1829–1839. 10.1007/s00204-012-0908-1 22820759
47 Seckin E, Fromme H, Volkel W. Determination of total and free mono-n-butyl phthalate in human urine samples after medication of a di-n-butyl phthalate containing capsule. Toxicol Lett. 2009; 188(1):33–37. 10.1016/j.toxlet.2009.03.002 19433267
48 Anderson WA, Castle L, Scotter MJ, Massey RC, Springall C. A biomarker approach to measuring human dietary exposure to certain phthalate diesters. Food Addit Contam. 2001; 18(12):1068–1074. 10.1080/02652030110050113 11761117
49 Silva MJ, Barr DB, Reidy JA, Kato K, Malek NA, Hodge CC, Hurtz D 3rd, Calafat AM, Needham LL, Brock JW. Glucuronidation patterns of common urinary and serum monoester phthalate metabolites. Arch Toxicol. 2003; 77(10):561–567. 10.1007/s00204-003-0486-3 14574443
50 Janjua NR, Frederiksen H, Skakkebaek NE, Wulf HC, Andersson AM. Urinary excretion of phthalates and paraben after repeated whole-body topical application in humans. Int J Androl. 2008; 31(2):118–130. 10.1111/j.1365-2605.2007.00841.x 18194284
51 National Toxicology Program (NTP). NTP technical report on the toxicity studies of dibutyl phthalate (CAS No. 84-74-2) administered in feed to F344/N rats and B6C3F1 mice. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 1995. NTP Toxicity Report No 30. https://ntp.niehs.nih.gov/publications/reports/tox/000s/tox030/index.html?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tox030abs
52 Hardin BD, Schuler RL, Burg JR, Booth GM, Hazelden KP, MacKenzie KM, Piccirillo VJ, Smith KN. Evaluation of 60 chemicals in a preliminary developmental toxicity test. Teratog Carcinog Mutagen. 1987; 7(1):29–48. 10.1002/tcm.1770070106 2884741
53 White RD, Earnest DL, Carter DE. The effect of intestinal esterase inhibition on the in vivo absorption and toxicity of di-n-butyl phthalate. Food Chem Toxicol. 1983; 21(1):99–101. 10.1016/0278-6915(83)90276-4 6681800
54 Li Y, Zhuang M, Li T, Shi N. Neurobehavioral toxicity study of dibutyl phthalate on rats following in utero and lactational exposure. J Appl Toxicol. 2009; 29(7):603–611. 10.1002/jat.1447 19533667
55 Li XJ, Jiang L, Chen L, Chen HS, Li X. Neurotoxicity of dibutyl phthalate in brain development following perinatal exposure: A study in rats. Environ Toxicol Pharmacol. 2013; 36(2):392–402. 10.1016/j.etap.2013.05.001 23736097
56 Farzanehfar V, Naderi N, Kobarfard F, Faizi M. Determination of dibutyl phthalate neurobehavioral toxicity in mice. Food Chem Toxicol. 2016; 94:221–226. 10.1016/j.fct.2016.05.006 27311797
57 Schilling K, Kaufman W, Hildebrand B. Study on the oral toxicity of dibutyl phthalate in Wistar rats—administration via the diet over 3 months. Ludwigshafen, Germany: BASF Corporation; 1992. Microfiche No. OTS0535640; Document ID 86-920000903.
58 British Industrial Biological Research Association (BIBRA). A 21 day feeding study of di-n-butyl phthalate to rats: Effects on the liver and liver lipids. Report to the Chemical Manufacturers Association, Washington, DC. Carshalton, Surrey, UK: The British; 1986.
59 Murakami K, Nishiyama K, Higuti T. Toxicity of dibutyl phthalate and its metabolites in rats. Nippon Eiseigaku Zasshi (Jpn J Hyg). 1986; 41(4):775–781. 10.1265/jjh.41.775 3807024
60 Feige JN, Gerber A, Casals-Casas C, Yang Q, Winkler C, Bedu E, Bueno M, Gelman L, Auwerx J, Gonzalez FJ, et al. The pollutant diethylhexyl phthalate regulates hepatic energy metabolism via species-specific PPARalpha-dependent mechanisms. Environ Health Perspect. 2010; 118(2):234–241. 10.1289/ehp.0901217 20123618
61 Lapinskas PJ, Brown S, Leesnitzer LM, Blanchard S, Swanson C, Cattley RC, Corton JC. Role of PPARalpha in mediating the effects of phthalates and metabolites in the liver. Toxicology. 2005; 207(1):149–163. 10.1016/j.tox.2004.09.008 15590130
62 Kusu R, Oishi A, Kakizawa K, Kimura T, Toda C, Hashizume K, Ueda K, Kojima N. Effects of phthalate ester derivatives including oxidized metabolites on coactivator recruiting by PPARalpha and PPARgamma. Toxicol In Vitro. 2008; 22(6):1534–1538. 10.1016/j.tiv.2008.05.010 18602795
63 Majeed KA, Ur Rehman H, Yousaf MS, Zaneb H, Rabbani I, Tahir SK, Rashid MA. Sub-chronic exposure to low concentration of dibutyl phthalate affects anthropometric parameters and markers of obesity in rats. Environ Sci Pollut Res Int. 2017; 24(32):25462–25467. 10.1007/s11356-017-9952-y 28823096
64 Benjamin S, Masai E, Kamimura N, Takahashi K, Anderson RC, Faisal PA. Phthalates impact human health: Epidemiological evidences and plausible mechanism of action. J Hazard Mater. 2017; 340:360–383. 10.1016/j.jhazmat.2017.06.036 28800814
65 Barlow NJ, McIntyre BS, Foster PM. Male reproductive tract lesions at 6, 12, and 18 months of age following in utero exposure to di(n-butyl) phthalate. Toxicol Pathol. 2004; 32(1):79–90. 10.1080/01926230490265894 14713552
66 Foster PM. Disruption of reproductive development in male rat offspring following in utero exposure to phthalate esters. Int J Androl. 2006; 29(1):140–147, discussion 181–145. 10.1111/j.1365-2605.2005.00563.x 16102138
67 Higuchi TT, Palmer JS, Gray LE Jr, Veeramachaneni DN. Effects of dibutyl phthalate in male rabbits following in utero, adolescent, or postpubertal exposure. Toxicol Sci. 2003; 72(2):301–313. 10.1093/toxsci/kfg036 12655036
68 Wilson VS, Lambright C, Furr J, Ostby J, Wood C, Held G, Gray LE Jr. Phthalate ester-induced gubernacular lesions are associated with reduced insl3 gene expression in the fetal rat testis. Toxicol Lett. 2004; 146(3):207–215. 10.1016/j.toxlet.2003.09.012 14687758
69 McKinnell C, Sharpe RM, Mahood K, Hallmark N, Scott H, Ivell R, Staub C, Jegou B, Haag F, Koch-Nolte F, et al. Expression of insulin-like factor 3 protein in the rat testis during fetal and postnatal development and in relation to cryptorchidism induced by in utero exposure to di (n-Butyl) phthalate. Endocrinology. 2005; 146(10):4536–4544. 10.1210/en.2005-0676 16037377
70 Li LH, Jester WF Jr, Orth JM. Effects of relatively low levels of mono-(2-ethylhexyl) phthalate on cocultured Sertoli cells and gonocytes from neonatal rats. Toxicol Appl Pharmacol. 1998; 153(2):258–265. 10.1006/taap.1998.8550 9878596
71 Mylchreest E, Sar M, Wallace DG, Foster PM. Fetal testosterone insufficiency and abnormal proliferation of Leydig cells and gonocytes in rats exposed to di(n-butyl) phthalate. Reprod Toxicol. 2002; 16(1):19–28. 10.1016/S0890-6238(01)00201-5 11934529
72 Chou CK, Yang YT, Yang HC, Liang SS, Wang TN, Kuo PL, Wang HD, Tsai EM, Chiu CC. The impact of di(2-ethylhexyl)phthalate on cancer progression. Arch Immunol Ther Exp (Warsz). 2018; 66(3):183–197. 10.1007/s00005-017-0494-2 29209738
73 Wolf C, Lambright C, Mann P, Price M, Cooper RL, Ostby J, Gray LE Jr. Administration of potentially antiandrogenic pesticides (procymidone, linuron, iprodione, chlozolinate, p,p′-DDE, and ketoconazole) and toxic substances (dibutyl- and diethylhexyl phthalate, PCB 169, and ethane dimethane sulphonate) during sexual differentiation produces diverse profiles of reproductive malformations in the male rat. Toxicol Ind Health. 1999; 15(1-2):94–118. 10.1191/074823399678846664 10188194
74 Kay VR, Chambers C, Foster WG. Reproductive and developmental effects of phthalate diesters in females. Crit Rev Toxicol. 2013; 43(3):200–219. 10.3109/10408444.2013.766149 23405971
75 Ema M, Amano H, Itami T, Kawasaki H. Teratogenic evaluation of di-n-butyl phthalate in rats. Toxicol Lett. 1993; 69:197–203. 10.1016/0378-4274(93)90104-6 8212061
76 Ema M, Amano H, Ogawa Y. Characterization of the developmental toxicity of di-n-butyl phthalate in rats. Toxicology. 1994; 86:163–174. 10.1016/0300-483X(94)90002-7 8128502
77 Ema M, Miyawaki E, Kawasaki H. Further evaluation of developmental toxicity of di-n-butyl phthalate following administration during late pregnancy in rats. Toxicol Lett. 1998; 98(1-2):87–93. 10.1016/S0378-4274(98)00107-6 9776565
78 Dobrzyńska MM, Tyrkiel EJ, Gajowik A. Three generation study of reproductive and developmental toxicity following exposure of pubescent F0 male mice to di-n-butyl phthalate. Mutagenesis. 2017; 32(4):445–454. 10.1093/mutage/gex011 28472404
79 Ema M, Kurosaka R, Amano H, Ogawa Y. Comparative developmental toxicity of n-butyl benzyl phthalate and di-n-butyl phthalate in rats. Arch Environ Contam Toxicol. 1995; 28:223–228. 10.1007/BF00217620 7710290
80 Ema M, Kurosaka R, Harazono A, Amano H, Ogawa Y. Phase specificity of developmental toxicity after oral administration of mono-n-butyl phthalate in rats. Arch Environ Contam Toxicol. 1996; 31:170–176. 10.1007/BF00212362 8781065
81 Wine RN, Li LH, Barnes LH, Gulati DK, Chapin RE. Reproductive toxicity of di-n-butylphthalate in a continuous breeding protocol in Sprague-Dawley rats. Environ Health Perspect. 1997; 105(1):102–107. 10.1289/ehp.97105102 9074889
82 Fukuoka M, Zhou Y, Tanaka A, Ikemoto I, Machida T. Mechanism of testicular atrophy induced by di-n-butyl phthalate in rats. Part 2. The effects on some testicular enzymes. J Appl Toxicol. 1990; 10(4):285–293. 10.1002/jat.2550100410 2391408
83 Gray TJ, Rowland IR, Foster PM, Gangolli SD. Species differences in the testicular toxicity of phthalate esters. Toxicol Lett. 1982; 11(1-2):141–147. 10.1016/0378-4274(82)90119-9 7090005
84 Gray LE Jr, Laskey J, Ostby J. Chronic di-n-butyl phthalate exposure in rats reduces fertility and alters ovarian function during pregnancy in female Long Evans hooded rats. Toxicol Sci. 2006; 93(1):189–195. 10.1093/toxsci/kfl035 16763070
85 Gray LE Jr, Ostby JS, Mylchreest E, Foster PM, Kelce WR. Dibutyl phthalate (DBP) induces antiandrogenic but not estrogenic in vivo effects in LE hooded rats. Toxicologist. 1998; 42(1-S):176.
86 Ema M, Miyawaki E, Kawashima K. Effects of dibutyl phthalate on reproductive function in pregnant and pseudopregnant rats. Reprod Toxicol. 2000; 14(1):13–19. 10.1016/S0890-6238(99)00066-0 10689199
87 Radke EG, Braun JM, Meeker JD, Cooper GS. Phthalate exposure and male reproductive outcomes: A systematic review of the human epidemiological evidence. Environ Int. 2018; 121(Pt 1):764–793. 10.1016/j.envint.2018.07.029 30336412
88 Radke EG, Glenn BS, Braun JM, Cooper GS. Phthalate exposure and female reproductive and developmental outcomes: A systematic review of the human epidemiological evidence. Environ Int. 2019; 130:104580. 10.1016/j.envint.2019.02.003 31351310
89 Pan Y, Jing J, Dong F, Yao Q, Zhang W, Zhang H, Yao B, Dai J. Association between phthalate metabolites and biomarkers of reproductive function in 1066 Chinese men of reproductive age. J Hazard Mater. 2015; 300:729–736. 10.1016/j.jhazmat.2015.08.011 26296076
90 Hansen JF, Bendtzen K, Boas M, Frederiksen H, Nielsen CH, Rasmussen ÅK, Feldt-Rasmussen U. Influence of phthalates on cytokine production in monocytes and macrophages: A systematic review of experimental trials. PLoS One. 2015; 10(3):e0120083. 10.1371/journal.pone.0120083 25811352
91 Li L, Li HS, Song NN, Chen HM. The immunotoxicity of dibutyl phthalate on the macrophages in mice. Immunopharmacol Immunotoxicol. 2013; 35(2):272–281. 10.3109/08923973.2013.768267 23480346
92 Zheng SJ, Tian HJ, Cao J, Gao YQ. Exposure to di(n-butyl)phthalate and benzo(a)pyrene alters IL-1beta secretion and subset expression of testicular macrophages, resulting in decreased testosterone production in rats. Toxicol Appl Pharmacol. 2010; 248(1):28–37. 10.1016/j.taap.2010.07.008 20655936
93 Wu Y, Li J, Yan B, Zhu Y, Liu X, Chen M, Li D, Lee CC, Yang X, Ma P. Oral exposure to dibutyl phthalate exacerbates chronic lymphocytic thyroiditis through oxidative stress in female Wistar rats. Sci Rep. 2017; 7(1):15469. 10.1038/s41598-017-15533-z 29133889
94 Bornehag CG, Nanberg E. Phthalate exposure and asthma in children. Int J Androl. 2010; 33(2):333–345. 10.1111/j.1365-2605.2009.01023.x 20059582
95 Maestre-Batlle D, Pena OM, Huff RD, Randhawa A, Carlsten C, Bolling AK. Dibutyl phthalate modulates phenotype of granulocytes in human blood in response to inflammatory stimuli. Toxicol Lett. 2018; 296:23–30. 10.1016/j.toxlet.2018.07.046 30059708
96 Jobling S, Reynolds T, White R, Parker MG, Sumpter JP. A variety of environmentally persistent chemicals, including some phthalate plasticizers, are weakly estrogenic. Environ Health Perspect. 1995; 103(6):582–587. 10.1289/ehp.95103582 7556011
97 Zuccarello P, Oliveri Conti G, Cavallaro F, Copat C, Cristaldi A, Fiore M, Ferrante M. Implication of dietary phthalates in breast cancer. A systematic review. Food Chem Toxicol. 2018; 118:667–674. 10.1016/j.fct.2018.06.011 29886235
98 Sun J, Zhang MR, Zhang LQ, Zhao D, Li SG, Chen B. Phthalate monoesters in association with uterine leiomyomata in Shanghai. Int J Environ Health Res. 2016; 26(3):306–316. 10.1080/09603123.2015.1111310 26608625
99 Nymand Ennis Z, Pedersen A, Hansen RM, Pottegard A, Ahern PT, Hallas J, Damkier P. Use of phthalate-containing prescription drugs and the risk of gastric cancer: A Danish nationwide case-control study. Acta Oncol. 2019; 58(6):852–858. 10.1080/0284186X.2019.1585941 30882263
100 Ennis ZN, Pottegard A, Ahern TP, Hallas J, Damkier P. Exposure to phthalate-containing prescription drugs and the risk of colorectal adenocarcinoma: A Danish nationwide case-control study. Pharmacoepidemiol Drug Saf. 2019; 28(4):528–535. 10.1002/pds.4759 30793813
101 Agarwal DK, Lawrence WH, Nunez LJ, Autian J. Mutagenicity evaluation of phthalic acid esters and metabolites in Salmonella typhimurium cultures. J Toxicol Environ Health. 1985; 16(1):61–69. 10.1080/15287398509530719 3906141
102 Florin I, Rutberg L, Curvall M, Enzell CR. Screening of tobacco smoke constituents for mutagenicity using the Ames’ test. Toxicology. 1980; 15(3):219–232. 10.1016/0300-483X(80)90055-4 7008261
103 Kozumbo WJ, Kroll R, Rubin RJ. Assessment of the mutagenicity of phthalate esters. Environ Health Perspect. 1982; 45:103–109. 10.1289/ehp.8245103 6754359
104 Zeiger E, Haworth S, Mortelmans K, Speck W. Mutagenicity testing of di(2-ethylhexyl)phthalate and related chemicals in Salmonella. Environ Mutagen. 1985; 7(2):213–232. 10.1002/em.2860070209 3971959
105 Seed JL. Mutagenic activity of phthalate esters in bacterial liquid suspension assays. Environ Health Perspect. 1982; 45:111–114. 10.1289/ehp.8245111 6754360
106 Shahin MM, Von Borstel RC. Mutagenic and lethal effects of alpha-benzene hexachloride, dibutyl phthalate and trichloroethylene in Saccharomyces cerevisiae. Mutat Res. 1977; 48(2):173–180. 10.1016/0027-5107(77)90157-9 69268
107 Zimmermann FK, von Borstel RC, von Halle ES, Parry JM, Siebert D, Zetterberg G, Barale R, Loprieno N. Testing of chemicals for genetic activity with Saccharomyces cerevisiae: A report of the U.S. Environmental Protection Agency Gene-Tox Program. Mutat Res. 1984; 133(3):199–244. 10.1016/0165-1110(84)90017-4 6374444
108 Barber ED, Cifone M, Rundell J, Przygoda R, Astill BD, Moran E, Mulholland A, Robinson E, Schneider B. Results of the L5178Y mouse lymphoma assay and the Balb/3t3 cell in vitro transformation assay for eight phthalate esters. J Appl Toxicol. 2000; 20(1):69–80. 10.1002/(sici)1099-1263(200001/02)20:1<69::aid-jat630>3.0.co;2-2 10641018
109 Kleinsasser NH, Kastenbauer ER, Weissacher H, Muenzenrieder RK, Harréus UA. Phthalates demonstrate genotoxicity on human mucosa of the upper aerodigestive tract. Environ Mol Mutagen. 2000; 35(1):9–12. 10.1002/(sici)1098-2280(2000)35:1<9::aid-em2>3.0.co;2-1 10692222
110 Kleinsasser NH, Wallner BC, Kastenbauer ER, Muenzenrieder RK, Harréus UA. Comparing the genotoxic sensitivities of human peripheral blood lymphocytes and mucosa cells of the upper aerodigestive tract using the Comet assay. Mutat Res. 2000; 467(1):21–30. 10.1016/S1383-5718(00)00022-X 10771268
111 Abe S, Sasaki M. Chromosome aberrations and sister chromatid exchanges in Chinese hamster cells exposed to various chemicals. J Natl Cancer Inst. 1977; 58(6):1635–1641. 10.1093/jnci/58.6.1635 864744
112 Kim MY, Kim YC, Cho MH. Combined treatment with 4-(N-methyl-N-nitrosamino)-1- (3-pyridyl)-1-butanone and dibutyl phthalate enhances ozone-induced genotoxicity in B6C3F1 mice. Mutagenesis. 2002; 17(4):331–336. 10.1093/mutage/17.4.331 12110630
113 Kim MY, Kim HW, Park JH, Kim JS, Jin H, Moon SH, Eu KJ, Cho HS, Kang G, Kim YS, et al. Molecular analysis of hprt mutation in B6C3F1 mice exposed to ozone alone and combined treatment of 4-(N-methyl-N-nitrosamino)-1-(3-pyridyl)-1-butanone and/or dibutyl phthalate for 32 and 52 weeks. J Vet Sci. 2004; 5(4):379–385. 10.4142/jvs.2004.5.4.379 15613823
114 Tu Z, Mu X, Chen X, Geng Y, Zhang Y, Li Q, Gao R, Liu T, Wang Y, He J. Dibutyl phthalate exposure disrupts the progression of meiotic prophase I by interfering with homologous recombination in fetal mouse oocytes. Environ Pollut. 2019; 252(Pt A):388–398. 10.1016/j.envpol.2019.05.107
115 Silinski MAR, Fernando RA, Robinson VG, Waidyanatha S. Development and validation of an analytical method for quantitation of monobutylphthalate, a metabolite of di-n-butylphthalate, in rat plasma, amniotic fluid, fetuses, and pups by UPLC-MS/MS. J Anal Toxicol. 2020; 44(4):370–377. 10.1093/jat/bkz090 31776566
116 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
117 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
118 McConnell EE, Solleveld HA, Swenberg JA, Boorman GA. Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986; 76(2):283–289. 3456066
119 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
120 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690. 10.1093/biomet/62.3.679
121 Cox DR. Regression models and life‐tables. J R Stat Soc Series B Stat Methodol. 1972; 34(2):187–202. 10.1111/j.2517-6161.1972.tb00899.x
122 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
123 Piegorsch W, Bailer A. Statistics for environmental biology and toxicology: Section 6.3.2. London, UK: Chapman and Hall; 1997.
124 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
125 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
126 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
127 Nam JM. A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987; 43(3):701–705. 10.2307/2532006 3663825
128 Rao JN, Scott AJ. A simple method for the analysis of clustered binary data. Biometrics. 1992; 48(2):577–585. 10.2307/2532311 1637980
129 Fung KY, Krewski D, Rao JN, Scott AJ. Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994; 14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
130 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
131 Dixon W, Massey FJ. Introduction to Statistical Analysis. New York, NY: McGraw Hill Book Company, Inc.; 1957. 10.2307/2332898
132 Tukey J. Easy summaries – numerical and graphical. Exploratory Data Analysis. Reading, MA: Addison-Wesley; 1977. p. 43–44.
133 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
134 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
135 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
136 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
137 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
138 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
139 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2). 10.2307/2333011
140 Hsu JC. The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168.
141 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200. 10.1177/009286159202600210
142 Haseman JK. Data analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995; 21(1):52–59, discussion 81–56. 10.1006/rtph.1995.1009 7784636
143 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
144 Code of Federal Regulations (CFR). 21(Part 58).
145 National Toxicology Program (NTP). TR-600: Pathology tables, survival and growth curves from NTP long-term studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2020. 10.22427/NTP-DATA-TR-600
146 Rudmann D, Cardiff R, Chouinard L, Goodman D, Küttler K, Marxfeld H, Molinolo A, Treumann S, Yoshizawa K. Proliferative and nonproliferative lesions of the rat and mouse mammary, Zymbal’s, preputial, and clitoral glands. Toxicol Pathol. 2012; 40(6_suppl):7S–39S. 10.1177/0192623312454242 22949413
147 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies in Hsd: Sprague Dawley SD rats exposed to whole-body radio frequency radiation at a frequency (900 MHz) and modulations (GSM and CDMA) used by cell phones. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Insitute of Environmental Health Sciences, National Toxicology Program; 2018. NTP Technical Report No 595. https://ntp.niehs.nih.gov/publications/reports/tr/500s/tr595/index.html?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tr595abs
148 Creasy D, Bube A, de Rijk E, Kandori H, Kuwahara M, Masson R, Nolte T, Reams R, Regan K, Rehm S, et al. Proliferative and nonproliferative lesions of the rat and mouse male reproductive system. Toxicol Pathol. 2012; 40(6_suppl):40S–121S. 10.1177/0192623312454337 22949412
149 Kay VR, Bloom MS, Foster WG. Reproductive and developmental effects of phthalate diesters in males. Crit Rev Toxicol. 2014; 44(6):467–498. 10.3109/10408444.2013.875983 24903855
150 Katsikantami I, Tzatzarakis MN, Alegakis AK, Karzi V, Hatzidaki E, Stavroulaki A, Vakonaki E, Xezonaki P, Sifakis S, Rizos AK, et al. Phthalate metabolites concentrations in amniotic fluid and maternal urine: Cumulative exposure and risk assessment. Toxicol Rep. 2020; 7:529–538. 10.1016/j.toxrep.2020.04.008 32368503
151 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of butyl benzyl phthalate (CAS No. 85-68-7) in F334/N rats (feed studies). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 1997. NTP Technical Report No 458. https://ntp.niehs.nih.gov/publications/reports/tr/400s/tr458/index.html?utm_source=direct&utm_medium=prod&utm_campaign=ntpgolinks&utm_term=tr458abs
152 National Toxicology Program (NTP). NTP technical report on the toxicology and carcinogenesis studies of di(2-ethylhexyl) phthalate (CASRN 117-81-7) administered in feed to Sprague Dawley Hsd:Sprague Dawley® SD®) rats. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2020. NTP Technical Report No. 601 [in progress].
153 Biegel LB, Hurtt ME, Frame SR, O’Connor JC, Cook JC. Mechanisms of extrahepatic tumor induction by peroxisome proliferators in male CD rats. Toxicol Sci. 2001; 60(1):44–55. 10.1093/toxsci/60.1.44 11222872
154 Reddy JK, Rao MS. Transplantable pancreatic carcinoma of the rat. Science. 1977; 198(4312):78–80. 10.1126/science.897688 897688
155 Klaunig JE, Babich MA, Baetcke KP, Cook JC, Corton JC, David RM, DeLuca JG, Lai DY, McKee RH, Peters JM, et al. PPARalpha agonist-induced rodent tumors: Modes of action and human relevance. Crit Rev Toxicol. 2003; 33(6):655–780. 10.1080/713608372 14727734
156 Klaunig JE, Hocevar BA, Kamendulis LM. Mode of action analysis of perfluorooctanoic acid (PFOA) tumorigenicity and human relevance. Reprod Toxicol. 2012; 33(4):410–418. 10.1016/j.reprotox.2011.10.014 22120428
157 Obourn JD, Frame SR, Bell RH Jr, Longnecker DS, Elliott GS, Cook JC. Mechanisms for the pancreatic oncogenic effects of the peroxisome proliferator Wyeth-14,643. Toxicol Appl Pharmacol. 1997; 145(2):425–436. 10.1006/taap.1997.8210 9266817
158 Li T, Chiang JYL. Regulation of bile acid and cholesterol metabolism by PPARs. PPAR Res. 2009; 2009:501739. 10.1155/2009/501739 19636418
159 Hurst CH, Waxman DJ. Activation of PPARalpha and PPARgamma by environmental phthalate monoesters. Toxicol Sci. 2003; 74(2):297–308. 10.1093/toxsci/kfg145 12805656
160 Sarath Josh MK, Pradeep S, Amma VKS, Balachandran S, Abdul Jaleel UC, Doble M, Spener F, Benjamin S. Phthalates efficiently bind to human peroxisome proliferator activated receptor and retinoid X receptor alpha, beta, gamma subtypes: An in silico approach. J Appl Toxicol. 2014; 34(7):754–765. 10.1002/jat.2902 23843199
161 Gray LE, Foster PMD. Significance of experimental studies for assessing adverse effects of endocrine-disrupting chemicals. Pure Appl Chem. 2003; 75(11-12):2125–2141. 10.1351/pac200375112125
162 Gray LE Jr, Furr J, Tatum-Gibbs KR, Lambright C, Sampson H, Hannas BR, Wilson VS, Hotchkiss A, Foster PM. Establishing the “biological relevance” of dipentyl phthalate reductions in fetal rat testosterone production and plasma and testis testosterone levels. Toxicol Sci. 2016; 149(1):178–191. 10.1093/toxsci/kfv224 26454885
163 Furr JR, Lambright CS, Wilson VS, Foster PM, Gray LE Jr. A short-term in vivo screen using fetal testosterone production, a key event in the phthalate adverse outcome pathway, to predict disruption of sexual differentiation. Toxicol Sci. 2014; 140(2):403–424. 10.1093/toxsci/kfu081 24798384
164 Kilcoyne KR, Smith LB, Atanassova N, Macpherson S, McKinnell C, van den Driesche S, Jobling MS, Chambers TJ, De Gendt K, Verhoeven G, et al. Fetal programming of adult Leydig cell function by androgenic effects on stem/progenitor cells. Proc Natl Acad Sci USA. 2014; 111(18):E1924–E1932. 10.1073/pnas.1320735111 24753613
165 Fisher JS, Macpherson S, Marchetti N, Sharpe RM. Human ‘testicular dysgenesis syndrome’: A possible model using in-utero exposure of the rat to dibutyl phthalate. Hum Reprod. 2003; 18(7):1383–1394. 10.1093/humrep/deg273 12832361
166 Mahood IK, Hallmark N, McKinnell C, Walker M, Fisher JS, Sharpe RM. Abnormal leydig cell aggregation in the fetal testis of rats exposed to di (n-butyl) phthalate and its possible role in testicular dysgenesis. Endocrinology. 2005; 146(2):613–623. 10.1210/en.2004-0671 15539561
167 van den Driesche S, Kilcoyne KR, Wagner I, Rebourcet D, Boyle A, Mitchell R, McKinnell C, Macpherson S, Donat R, Shukla CJ, et al. Experimentally induced testicular dysgenesis syndrome originates in the masculinization programming window. JCI Insight. 2017; 2(6):e91204. 10.1172/jci.insight.91204 28352662
168 Elmore SA, Carreira V, Labriola CS, Mahapatra D, McKeag SR, Rinke M, Shackelford C, Singh B, Talley A, Wallace SM, et al. Proceedings of the 2018 National Toxicology Program Satellite Symposium. Toxicol Pathol. 2018; 46(8):865–897. 10.1177/0192623318800734
169 Sohval AR. Testicular dysgenesis as an etiologic factor in cryptorchidism. J Urol. 1954; 72(4):693–702. 10.1016/S0022-5347(17)67649-3 13202269
170 Sohval AR. Testicular dysgenesis in relation to neoplasm of the testicle. J Urol. 1956; 75(2):285–291. 10.1016/S0022-5347(17)66809-5 13296128
171 Hoei-Hansen CE, Holm M, Rajpert-De Meyts E, Skakkebaek NE. Histological evidence of testicular dysgenesis in contralateral biopsies from 218 patients with testicular germ cell cancer. J Pathol. 2003; 200(3):370–374. 10.1002/path.1372 12845633
172 Lara NLM, van den Driesche S, Macpherson S, Franca LR, Sharpe RM. Dibutyl phthalate induced testicular dysgenesis originates after seminiferous cord formation in rats. Sci Rep. 2017; 7(1):2521. 10.1038/s41598-017-02684-2 28566680
173 Elmore SA, Cesta MF, Crabbs TA, Janardhan KS, Krane GA, Mahapatra D, Quist EM, Rinke M, Schaaf GW, Travlos GS, et al. Proceedings of the 2019 National Toxicology Program Satellite Symposium. Toxicol Pathol. 2019; 47(8):913–953. 10.1177/0192623319876929
174 Ozaki K, Mahler JF, Haseman JK, Moomaw CR, Nicolette ML, Nyska A. Unique renal tubule changes induced in rats and mice by the peroxisome proliferators 2,4-dichlorophenoxyacetic acid (2,4-D) and WY-14643. Toxicol Pathol. 2001; 29(4):440–450. 10.1080/01926230152499791 11560249