# Conclusions

Under the conditions of these 2-year feed studies, there was equivocal evidence of carcinogenic activity of di-n-butyl phthalate (DBP) in male Hsd:Sprague Dawley^®^ SD^®^ rats based on marginal increases in the incidence of pancreatic acinus adenomas. There was no evidence of carcinogenic activity of DBP in female Hsd:Sprague Dawley^®^ SD^®^ rats at exposure concentrations of 300, 1,000, 3,000, or 10,000 ppm.

There was no evidence of carcinogenic activity of DBP in male or female B6C3F1/N mice at exposure concentrations of 1,000, 3,000, or 10,000 ppm.

Exposure to DBP increased incidences of gross lesions in the male reproductive system in rats and of nonneoplastic microscopic lesions in the male reproductive system (rats and mice), liver (male and female rats and mice), pituitary gland pars distalis (male rats), and kidney (female mice).