# Discussion

The use of di-n-butyl phthalate (DBP) in the manufacture of various consumer products has resulted in widespread exposure, as evidenced by its detection in human urine, plasma, and umbilical cord blood. DBP and other phthalates have well-documented effects on the male reproductive system, particularly with perinatal exposure.^149^ Data to evaluate DBP as a human carcinogen, however, are inadequate. To address this knowledge gap, the National Toxicology Program (NTP) conducted a 2-year bioassay in mice and rats. Given the widespread exposure and known effects of phthalates on male reproduction, perinatal exposure was included in the rat study. To emulate the primary route of exposure in humans, animals were exposed to DBP via feed.

Chemical consumption of DBP was calculated on the basis of feed consumption measurements. Few differences were found in feed consumption between control and exposed groups in rats and mice. Chemical consumption between sexes was similar in both species and increased with increasing exposure concentration in a generally proportional manner. Mice were exposed to twice as much DBP as rats fed the same concentration in feed due to differences in feed consumption.

Even though chemical consumption was linearly related to the exposure concentrations, mono-n-butyl phthalate (MBP) concentrations measured in biological matrices in rats did not increase linearly or in proportion to exposure concentration. For example, MBP concentrations in dam plasma on gestation day (GD) 18 in the 3,000 ppm group were 17-fold higher than concentrations in the 300 ppm group; in the 10,000 ppm group, dam plasma MBP was 36-fold higher than that in the 1,000 ppm group. Because DBP is primarily converted to MBP through first-pass metabolism, the nonproportional increase in MBP concentrations suggests a saturation of phase 2 metabolism and clearance processes at higher exposure concentrations (i.e., less MBP-glucuronide formed) and/or an induction of absorption process transporters. In this study, only unconjugated forms of MBP were assessed. Measuring both unconjugated and conjugated forms of MBP would help to inform the relationship between internal and external dose.

Although no DBP was administered via feed to control animals, MBP was detected in the plasma of some control rats. Because phthalates are ubiquitous in food packaging and many plastics, the presence of MBP in control animals could be due to exposure to background levels of DBP in the feed (although all measurements of DBP in the control diet were below the limit of quantitation). Another possibility is contamination during sample collection or analysis. The concentrations of MBP in control animals, however, were very low (<1% of that in the lowest exposure group) compared to those in exposed animals and are likely not a confounder in the study.

The exposure concentration of DBP and the internal concentration of MBP in rats in this study were much higher than those observed in humans. Given that estimated human intake of DBP is 0–7 μg/kg body weight/day (μg/kg/day)^22^ and that gestational and lactational DBP consumption in this study ranged from 19 to 66 mg/kg/day in the lowest exposure group (300 ppm), the exposure multiple comparing rats to humans is at least 3,000. Similarly, concentrations of MBP measured in the rat plasma were much higher than concentrations observed in human plasma. The GD 18 maternal plasma concentration in rats at the lowest exposure concentration was 263-fold higher than plasma concentrations observed in pregnant Czech women.^17^ Gestational transfer of DBP and/or MBP was observed in this study, consistent with previous studies on gestational transfer in rodents.^41,43^ Lactational transfer also was observed, although less was transferred during lactation than during gestation.

Transfer during gestation and lactation is suggested in humans, as MBP has been detected in human amniotic fluid and breast milk.^18-21,150^ In samples taken from 54 women during routine amniocentesis, the median MBP concentration in amniotic fluid was 5.8 ng/mL with a highest measured value of 263.9 ng/mL.^18^ In another study, amniotic fluid samples from 100 women in Crete, Greece, contained, on average, 12 ng/mL MBP with a maximum of 24.5 ng/mL.^150^ Exposure in this group of women was estimated to be 0.9 μg DBP/kg/day based on questionnaires and on measured urinary metabolite concentrations. Therefore, despite the much higher intake of DBP in rats, the exposure of the rodent fetus to MBP via amniotic fluid from dams in the lowest exposure group (84.5 ng/mL) is within an order of magnitude of the concentrations to which some human fetuses could be exposed.

In the rats, exposure to DBP during gestation had minimal effects on dam mean body weight, dam survival, and littering parameters. During lactation, there were minor decreases in dam mean body weight, mean body weight gain, and feed consumption in the 10,000 ppm group. The lower feed consumption in the later days of lactation could be due to less feed consumption by the pups. Chemical consumption by the pups might have contributed to the lower pup mean body weight at postnatal day (PND) 14 and PND 21 in the 10,000 ppm group, given the higher chemical-to-body-weight concentration in young animals. Findings here are similar to those from perinatal subchronic studies previously reported in NTP Toxicity Report 30 in which F_0_ fertility and gestation length of rats and mice were not affected by exposure at concentrations up to 10,000 ppm, but pup number, dam mean body weight, and pup mean body weight were significantly decreased in the 10,000 ppm group compared to the control group.^51^ These effects were observed in lower exposure groups (1,000 and 5,000 ppm) in the NTP reproductive and continuous breeding studies, particularly in later litters and in the F_1_ generation, suggesting a compounding effect of long-term DBP exposure on reproductive capacity.^81^

During the 2-year study phase, there were no decreases in survival related to DBP exposure. The only differences in mean body weight were observed in the highest dietary exposure groups (10,000 ppm) in rats and mice. In both species, mean body weights of animals in the highest exposure groups were affected, with exposed females having marginally larger deficits in mean body weight than males compared to the respective control groups. Furthermore, female mice had the largest discrepancy in mean body weight compared to the control group. Two other studies have evaluated the chronic effects of DBP exposure (≥1 year) in adult male rats^33^ and in male rats exposed only in utero.^65^ In both studies, no clear dose-dependent changes in mortality were found. In Smith et al.^33^ in which adult rats were administered DBP for 1 year, no differences in body weight due to DBP were reported. In Barlow et al.,^65^ body weight was not reported. Studies in female animals are not available for comparison. Findings from this study suggest that female mice could be more susceptible to DBP effects on body weight than male mice.

DBP exposure might have resulted in an increase in the incidence of pancreatic acinus adenomas in male rats, as a statistically significant positive trend was found. Although the incidence in the 10,000 ppm group was within the historical control range and there was no concurrent increase in the incidence of pancreatic acinus hyperplasia, this positive trend is consistent with reported effects of other phthalates. Pancreatic acinus adenomas and acinus carcinomas have been observed with exposure to other phthalates and peroxisome proliferator-activated receptor alpha (PPARα) agonists. Di-(2-ethylhexyl) phthalate (DEHP) and butyl benzyl phthalate (BBP) induced pancreatic acinus adenomas and acinus carcinomas in male Fischer 334/N rats.^151,152^ These neoplasms and/or acinus hyperplasia were also reported following chronic exposure to other PPARα agonists, such as perfluorooctanoic acid,^153^ Wyeth-14,643,^153^ and nafenopin.^154^ The marginal increase in the incidence of pancreatic acinus adenomas was considered equivocal evidence of carcinogenicity in male rats because of observations of similar pancreatic neoplasms with exposure to other phthalates and other agonists of the proposed mechanistic pathway.

The mode of action underlying the increase in the incidence of pancreatic acinus adenomas is not certain, but studies suggest that PPARα agonists alter bile acid synthesis or decrease bile flow, leading to hepatic cholestasis. The altered bile acids or decreased bile acid flow lead to increased secretion of cholecystokinin, which acts as a growth factor on pancreatic acinar cells in rats.^155-158^ Sustained release of cholecystokinin might lead to increased proliferation of acinar cells. Indeed, phthalates like DEHP, DBP, BBP, and their metabolites (mono(2-ethylhexyl) phthalate [MEHP], MBP, and monobenzyl phthalate [MBzP], respectively) bind to PPARα nuclear receptors.^61,159^ MEHP is the most effective of the phthalate esters in activating mouse and human PPARα, followed by MBzP, and then MBP.^159^ Docking studies have also found DEHP and BBP to have stronger binding affinities to PPARs than DBP.^160^ Therefore, the small increase in the incidence of pancreatic acinus adenomas observed with DBP compared to stronger agonists could be due to the relatively lower binding affinity of DBP for PPARα.

In previous studies conducted by NTP, DBP exposure for 3 months appeared to activate hepatic PPARα in rats. At 5,000 and 10,000 ppm DBP, male and female rats had elevated peroxisome enzyme activity, increased liver weight, and hepatocellular cytoplasmic alterations at the end of the study.^51^ Although peroxisome enzyme activity was not measured in the present study, the increased incidences of hepatocyte cytoplasmic alteration in male and female animals at the highest exposure concentration (10,000 ppm) suggests PPARα activation by DBP. This activation, however, was apparently insufficient to stimulate hepatic neoplasm growth in this study. In support of this hypothesis, chronic exposure to BBP—a weaker PPARα agonist relative to DEHP but stronger than DBP—did not produce hepatic neoplasms in rats.^151^ Hepatic neoplasms have been reported with exposure to DEHP.^152^

In rats and mice of both sexes, cytoplasmic alteration of hepatocytes was present in nearly all animals in the 10,000 ppm groups. This was visible as fine, eosinophilic granules in affected hepatocytes, was graded as minimal severity in all animals. Similar cytoplasmic alteration of hepatocytes was previously reported in the 3-month DBP dosed feed study, and ultrastructural examination suggested the presence of increased numbers of peroxisomes in the cytoplasm.^51^ An increase in the number and size of multinucleated hepatocytes was also observed in the livers of exposed male mice, but the biological relevance of this lesion is unclear.

In utero exposure to DBP and other phthalates has been shown to induce developmental malformations in male rats, collectively referred to as the “phthalate syndrome.”^161^ Phthalate syndrome is characterized by malformations in reproductive tissues and is considered to be androgen-dependent or Insl3-dependent.^162^ Insl3 is a peptide hormone synthesized by fetal Leydig cells. Phthalate syndrome includes malformations of the epididymis, penis (hypospadias), prostate, seminal vesicles, and vas deferens; reduced anogenital distance; retention of nipples/areolae (all considered androgen-dependent), gubernacular abnormalities (considered to be Insl3-dependent), and undescended testes (considered both androgen- and Insl3-dependent).^65,68,162^

Characteristics of phthalate syndrome were observed in this study. Gross pathology findings at necropsy generally were limited to the male reproductive tract in rats (Table 14). These findings included decreased size of testis, epididymis, seminal vesicle, or prostate gland; gubernacular length exceeding 20 mm; segmental or complete agenesis of the epididymis (caput, corpus, or cauda); agenesis of the prostate gland (ventral lobes); testis not present (at necropsy and synonymous with agenesis); vas deferens not present; and undescended (cryptorchid) testes. The most frequently occurring gross findings related to DBP exposure in the rat were undescended testes and small testes, both of which were present in most of the 10,000 ppm male rats. Undescended testes were more frequently seen in abdominal locations than in inguinal ones. Increased gubernacular length, observed in about half the 10,000 ppm males, is associated with failure of testes to fully descend. The undescended testes observed in DBP-exposed male rats were consistent with previously reported decreased androgens and Insl3 in DBP-exposed males; both are involved in testis descent.^65,68,162^ The undescended testes were generally smaller and corresponded to decreased testis weights and, histologically, with germinal epithelial atrophy. In this 2-year study with perinatal exposure in the rats, ascertaining whether the decreased size of testes seen at necropsy is due to testicular atrophy, which is the decrease in size after having attained full size, or from hypoplasia, in which the tissue never developed properly, is difficult. The small epididymides observed grossly corresponded to reduced epididymis weights and hypospermia microscopically. As with the testis, however, the possibility of epididymis hypoplasia cannot be ruled out, especially given the male reproductive tract malformations observed in rats.

The male reproductive tract was a target of DBP exposure in both rats and mice. Lesions were generally more severe in rats (which included perinatal exposure) than in mice. For example, at 10,000 ppm, 42 of 50 male rats had testicular germinal epithelial atrophy (seminiferous tubules containing only Sertoli cells and few or no germ cells), which is the end stage of degeneration. In contrast, the main testicular lesion in male mice at 10,000 ppm was germinal epithelial degeneration (15/50), with far fewer incidences of atrophy and epididymal hypospermia in the mice compared to the rats. In rats, testicular germinal epithelial atrophy was generally concomitant with epididymal hypospermia (42/50 and 40/50, respectively, at 10,000 ppm). In mice, testicular germinal epithelial degeneration was generally concomitant with exfoliated germ cells in the epididymal duct (15/50 and 13/50, respectively, at 10,000 ppm), with few incidences of epididymal hypospermia in mice. In rats, 18 of 42 animals with germinal epithelial atrophy also had edema in the testis, which was observed at a significantly increased incidence in 10,000 ppm male rats than in control animals. Testicular edema was not observed in male mice. This species effect of increased sensitivity of rats compared to mice for testicular toxicity of phthalates has been demonstrated previously.^83^

In addition to testicular atrophy (rats) or degeneration (mice) and their corroborating epididymal lesions, additional microscopic lesions in the male reproductive tracts of rats and mice likely were due to DBP exposure. Incidences of decreased secretory fluid in the prostate gland or seminal vesicles were significantly increased in the 10,000 ppm rats compared to the control rats. Similar incidences of atrophy in the coagulating gland or seminal vesicle were observed in a few exposed mice, but they were not significantly increased compared to the control group. Decreased incidences of secretory fluid or atrophy of the prostate gland or seminal vesicles are commonly found with chronic androgen depletion.^148^ Again, hypoplasia of the accessory glands cannot be ruled out in the perinatal rat study because the diagnostic features of hypoplasia and decreased secretory fluid are similar. In general, however, the overall structure of the prostate glands and seminal vesicles was considered normal rather than malformed; therefore, the diagnosis was decreased secretory fluid rather than hypoplasia.

Lesions suggestive of systemic hormonal disturbance, including disturbance of the hypothalamus-pituitary-gonad axis, included diffuse interstitial (Leydig) cell hyperplasia in the testis and hypertrophy in the pars distalis of the pituitary gland in male rats exposed to DBP. Diffuse testicular interstitial hyperplasia, which was always present in both testes when diagnosed, was seen in one male rat at 1,000 ppm and nine male rats at 10,000 ppm. The pathogenesis of diffuse interstitial cell hyperplasia is generally related to a compensatory physiological response to hormonal imbalance.^148^ Specifically, decreased systemic testosterone can cause a decrease in the normal negative feedback of testosterone on the hypothalamus-pituitary-gonad axis. This, in turn, leads to increased release of gonadotropin-releasing hormone by the hypothalamus and, subsequently, increased luteinizing hormone and follicle-stimulating hormone release by gonadotrophs in the pars distalis of the pituitary gland. This stimulation of gonadotrophs in the pars distalis might have led to the development of the lesion of hypertrophied and, often, vacuolated cells in the pituitary gland pars distalis (“gonadectomy” or “castration” cells) observed in 29 of 50 male rats exposed to 10,000 ppm DBP. Increased luteinizing hormone, owing to lack of the normal negative feedback of testosterone on the pars distalis, might have resulted in a stimulatory response of the Leydig cells, which produce testosterone, resulting microscopically in diffuse interstitial (Leydig) cell hyperplasia. Phthalates have been shown to decrease testosterone production by fetal Leydig cells.^71^ Reductions in fetal testicular testosterone production occurred at doses ≥100 mg/kg/day in another study^163^; these doses produce exposures similar to that experienced by the top two exposure groups in the current study. Reduced intratesticular testosterone production by fetal Leydig cells might result in compromised adult Leydig cell function. In utero exposure of rats to DBP has been demonstrated to reduce the number of adult Leydig stem cells by approximately 40% at birth to adulthood and affect their function by inducing compensated adult Leydig cell failure (low/normal serum testosterone and elevated luteinizing hormone).^164^

Certain microscopic lesions observed in the 2-year perinatal exposure study of DBP in rats are considered developmentally induced lesions resulting from in utero exposure. These lesions, which were not observed in mice, include dysgenesis of the seminiferous tubules and granuloma and fibrosis of the rete testis. These lesions have also been reported in a rat perinatal 2-year study of DEHP.^152^ In the current study of DBP, incidences of testicular seminiferous tubule dysgenesis were significantly increased at 10,000 ppm (9/50), with an additional occurrence at 3,000 ppm (Table 15). Testicular dysgenesis has been described in the literature as having occurred after in utero exposure to various phthalates during the masculinization programming window (embryonic day [E] 15.5–18.5 in rats).^65,165-168^ Seminiferous tubule dysgenesis is characterized as a developmental malformation observed microscopically as aberrant or misshapen seminiferous tubules, either with no lumens or dilated lumens, which are often surrounded by focal Leydig cell aggregates. The Leydig cell aggregates within foci of dysgenesis differ morphologically from the Leydig cells in adenomas. The Leydig cells in the foci of dysgenesis appear to be poorly differentiated, are spindle-shaped, and resemble embryonic Leydig cells, and they do not have the abundant eosinophilic or vacuolated cytoplasm often apparent in hyperplasia or adenoma.^65^ Dysgenetic lesions can occur as one or more small foci per testis, which tend to be located near the center of the testis or may occupy the entire testis.^65^ The malformed tubules can appear to form anastomotic networks. The dysgenetic tubules contain poorly differentiated Sertoli cells, with small, elongated, and sometimes cleaved nuclei and less prominent nucleoli than the typically prominent tripartite nucleoli of mature Sertoli cells. Spermatogenesis is absent in these foci of dysgenesis but can be present elsewhere in the testis. Dysgenetic foci can be present in one or both testes and can be more severe in undescended testes than scrotal testes.^165,167^ In human males, similar microscopic dysgenetic foci have been reported in undescended testes,^169^ in testes also containing testicular cancer (both scrotal and undescended testes^170^), and from testicular biopsies from the contralateral testis in men undergoing orchiectomy for testicular cancer.^171^

The microscopic lesion of dysgenesis appears to originate during gestation but is not evident in the embryonic testis; it becomes evident as malformed tubules only in early postnatal life.^165^ In rats exposed in utero to phthalates, immunohistochemical markers have been used to demonstrate Sertoli cells and gonocytes at ectopic locations within the interstitium and to identify Leydig cells at ectopic locations inside the malformed seminiferous tubules.^165-167,172^ Rats exposed in utero to DBP showed normal formation of seminiferous cords between E 13.5 and E 14.5, followed by abnormal fetal Leydig cell aggregation at E 17.5.^172^ At E 18.5, based on triple staining for Sertoli cells, gonocytes, and peritubular myoid cells, the seminiferous cords in exposed rats appeared to rupture, releasing their contents (i.e., Sertoli cells and gonocytes) into the interstitium. The cords appeared normally formed at one end, with a normal smooth muscle, actin positive, and peritubular myoid layer, and appeared ruptured at the other end, with loss of smooth muscle actin staining.^172^ The ectopic Sertoli cells and gonocytes appear in late gestation and disappear early in postnatal life, but the ectopic intratubular Leydig cells can persist throughout postnatal life.

Additional lesions considered related to in utero DBP exposure include rete testis fibrosis and rete testis sperm granuloma. In this and other DBP studies, sperm stasis in the rete testis appears to lead to formation of sperm granulomas and, subsequently, fibrosis in the rete testis region.^65,173^ Fibrosis of the rete testis is a unique lesion that presumably begins as a sperm granuloma and resolves into a fibrotic lesion with increased fibrous connective tissue containing numerous embedded epithelial-lined profiles of the rete testis.^65,173^ The mechanism is unknown but could occur as a result of toxicity and efferent duct occlusion. The efferent ducts, however, were not evaluated in the current study. The sperm granulomas or fibrosis of the rete testis, which did not always occur together, were co-incident with the lesion of seminiferous tubule dysgenesis in five of the nine animals with dysgenesis, so the rete testis and dysgenetic lesions might be linked to developmental exposure to DBP.

DBP exposure also resulted in a unique renal tubular hyperplastic lesion in female mice but not in male mice or in male or female rats. This lesion has been reported in a previous NTP study on peroxisome proliferators.^174^ Ozaki et al.^174^ reported this lesion in male rats and mice exposed to Wyeth-14,643 (a prototypical peroxisome proliferator) or 2,4-dichlorophenoxyacetic acid (2,4-D, a weak peroxisome proliferator). In contrast to the current study, in which the lesion was not observed in rats, Ozaki et al.^174^ reported that rats were more sensitive to the renal tubular effects of the two peroxisome proliferators tested. Similar to DBP, 2,4-D did not cause hepatic neoplasms typical of peroxisome proliferators.