# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-600.^145^

## Rats

### Two-year Study (Perinatal Phase)

No effects related to di-n-butyl phthalate (DBP) exposure were observed on the pregnancy status, maternal survival, gestation length, or number of dams that littered (Table 2).

Table 2 Summary of the Disposition of F_0_ Female Rats during Perinatal Exposure in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

Reproductive Performance | 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Time-mated Females (GD 6) | 45 | 45 | 45 | 45 | 47^a^
Females Pregnant (%)^b^ | 40 (88.9) | 34 (75.6) | 39 (86.7) | 38 (84.4) | 37 (78.7)
Females Not Pregnant (%) | 5 (11.1) | 11 (24.4) | 6 (13.3) | 7 (15.6) | 10 (21.3)
Dams Not Delivering with Evidence of Pregnancy (%) | 5 (12.5) | 7 (20.6) | 6 (15.4) | 3 (7.9) | 5 (13.5)
Dams with Litters on LD 0 (%) | 35 (87.5) | 27 (79.4) | 33 (84.6) | 35 (92.1) | 32 (86.5)
Gestation Length (Days)^c,d^ | 22.2 ± 0.1 | 22.1 ± 0.1 | 22.0 ± 0.0 | 22.2 ± 0.1 | 22.1 ± 0.1
Litters Poststandardization (LD 4)^e^ | 28 | 25 | 27 | 30 | 27
Weaned Males/Females | 112/112 | 97/102 | 104/111 | 120/120 | 104/111

GD = gestation day; LD = lactation day.

^a^ Two additional time-mated animals were received for the study and were placed in the 10,000 ppm group.

^b^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^d^ Gestation length calculated for sperm-positive females that delivered a litter. Data are presented as mean ± standard error.

^e^ Standardization to eight pups per litter (four pups/sex) when possible.

Maternal mean body weights and body weight gains of exposed dams during gestation were comparable to those of the control group (Table 3). During lactation, minimal differences in mean body weights were noted (<6%) between the highest exposure group (10,000 ppm) and control group, with sporadic differences observed in body weight gains across all exposure groups.

Table 3 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

Parameter^a,b^ | 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Gestation Day
6 | 230.1 ± 2.6 (40) | 231.7 ± 2.0 (34) | 231.4 ± 1.8 (39) | 232.5 ± 1.7 (38) | 226.8 ± 3.1 (37)
9 | 240.1 ± 3.2* (40) | 245.0 ± 2.2 (34) | 244.6 ± 1.6 (39) | 242.8 ± 1.7 (38) | 236.2 ± 2.4 (37)
12 | 259.2 ± 2.3* (40) | 262.1 ± 2.3 (34) | 261.5 ± 1.7 (39) | 261.0 ± 1.4 (38) | 254.1 ± 2.2 (37)
15 | 278.0 ± 2.4 (40) | 279.6 ± 3.4 (34) | 281.9 ± 1.9 (39) | 279.8 ± 2.0 (38) | 275.1 ± 2.5 (37)
18 | 314.7 ± 2.7 (40) | 318.6 ± 3.5 (34) | 317.2 ± 2.7 (39) | 320.3 ± 1.9 (38) | 315.7 ± 3.4 (37)
21^c^ | 355.5 ± 5.0 (35) | 366.6 ± 6.1 (28) | 361.8 ± 4.7 (34) | 366.2 ± 2.5 (34) | 353.6 ± 4.9 (30)
Gestation Weight Change
Gestation Day Interval
6–9 | 10.0 ± 0.9** (40) | 13.3 ± 1.0 (34) | 13.2 ± 0.8 (39) | 10.3 ± 0.8 (38) | 9.4 ± 1.3 (37)
9–12 | 19.1 ± 1.4 (40) | 17.1 ± 1.3 (34) | 16.9 ± 0.6 (39) | 18.2 ± 1.0 (38) | 17.9 ± 1.0 (37)
12–15 | 18.7 ± 0.6* (40) | 17.5 ± 2.0 (34) | 20.4 ± 0.6 (39) | 18.8 ± 1.4 (38) | 21.0 ± 0.7 (37)
15–18 | 36.8 ± 1.1* (40) | 39.0 ± 2.3 (34) | 35.2 ± 1.4 (39) | 40.5 ± 1.6 (38) | 40.6 ± 1.3 (37)
18–21 | 42.2 ± 3.4** (35) | 49.1 ± 2.7 (28) | 45.3 ± 2.0 (34) | 46.9 ± 1.2 (34) | 39.7 ± 1.3 (30)
6–21 | 126.4 ± 4.6 (35) | 136.3 ± 5.8 (28) | 129.6 ± 4.4 (34) | 133.7 ± 2.4 (34) | 127.3 ± 3.7 (30)
Lactation Day
1 | 271.5 ± 2.6 (35) | 277.5 ± 3.3 (27) | 274.4 ± 1.9 (33) | 274.4 ± 1.6 (35) | 270.7 ± 3.1 (32)
4 | 286.6 ± 2.5 (35) | 291.6 ± 2.8 (27) | 294.5 ± 2.2 (33) | 293.7 ± 1.9 (35) | 282.9 ± 2.9 (32)
7^d^ | 297.0 ± 2.6** (28) | 299.6 ± 2.9 (25) | 298.7 ± 2.1 (27) | 294.9 ± 1.9 (30) | 286.4 ± 2.9** (27)
10 | 304.4 ± 3.1** (28) | 311.6 ± 2.7 (25) | 307.4 ± 2.3 (27) | 305.6 ± 2.0 (30) | 291.8 ± 3.3** (27)
14 | 318.4 ± 3.0** (28) | 322.1 ± 3.1 (25) | 317.4 ± 2.3 (27) | 313.0 ± 2.2 (30) | 299.5 ± 2.5** (27)
21 | 299.0 ± 2.9* (28) | 301.9 ± 2.9 (25) | 301.5 ± 2.6 (27) | 290.7 ± 4.3 (30) | 290.8 ± 3.1 (27)
Lactation Weight Change
Lactation Day Interval
1–4 | 15.1 ± 1.3 (35) | 14.1 ± 1.4 (27) | 20.1 ± 1.4* (33) | 19.3 ± 1.1 (35) | 12.2 ± 1.2 (32)
4–7 | 11.0 ± 1.3** (28) | 7.4 ± 1.1* (25) | 3.4 ± 1.3** (27) | 2.2 ± 1.1** (30) | 3.0 ± 1.2** (27)
7–10 | 7.4 ± 1.3 (28) | 12.0 ± 1.0 (25) | 8.7 ± 1.3 (27) | 10.7 ± 1.4 (30) | 5.4 ± 1.4 (27)
10–14 | 14.0 ± 1.9** (28) | 10.5 ± 1.4 (25) | 10.0 ± 1.5 (27) | 7.4 ± 1.3** (30) | 7.7 ± 1.7** (27)
14–21 | −19.4 ± 1.9** (28) | −20.2 ± 1.9 (25) | −15.9 ± 2.0 (27) | −22.3 ± 3.8 (30) | −8.7 ± 1.5** (27)
1–21 | 26.8 ± 2.2 (28) | 23.2 ± 1.8 (25) | 26.7 ± 2.1 (27) | 17.0 ± 4.5 (30) | 19.6 ± 2.4 (27)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data are presented as mean ± standard error (number of dams). Body weight data are presented in grams.

^b^ Each exposure group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^c^ Decreased number of dams at gestation day 21 reflects animals removed at gestation day 18 for internal dose assessment.

^d^ Decreased number of dams at lactation day 7 reflects animal removal at postnatal day 4 for sample collection to determine gestational and lactational transfer.

Feed consumption during gestation was significantly higher (5%–6%) only in the 10,000 ppm group compared to the control group during gestation day (GD) 12–15 and GD 15–18 intervals (Table 4). Feed consumption in all exposed groups, except the 10,000 ppm group, was significantly increased (1%–9%) compared to the control group from lactation day (LD) 1 to 4 (Table 4). Feed consumption for LD 10–14 and LD 17–21 intervals, and overall during lactation in the 10,000 ppm group, was 4%–9% less than in control animals. Chemical intake throughout gestation and lactation was generally proportional to the exposure concentration and was higher during lactation than gestation. Chemical intake from LD 14 to 21 was not calculated because the entire litter ate feed; therefore, an accurate assessment could not be made for F_0_ or F_1_ consumption.

Table 4 Summary of Feed and Di-n-butyl Phthalate Consumption by F_0_ Female Rats during Gestation and Lactation in the Perinatal and Two-year Feed Study

Parameter^a^ | 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Gestation Day Interval^b,c^
6–9 | 16.1 ± 0.6 (40) | 17.6 ± 0.3 (34) | 17.6 ± 0.3 (39) | 17.2 ± 0.3 (38) | 18.0 ± 0.7 (36)
9–12 | 18.9 ± 0.3 (40) | 19.7 ± 0.3 (34) | 19.7 ± 0.3 (39) | 19.5 ± 0.3 (37) | 19.1 ± 0.3 (34)
12–15 | 18.6 ± 0.2** (40) | 18.5 ± 0.4 (34) | 19.1 ± 0.2 (39) | 18.7 ± 0.3 (38) | 19.6 ± 0.3** (37)
15–18 | 20.8 ± 0.2* (40) | 21.7 ± 0.3 (34) | 21.0 ± 0.3 (39) | 21.4 ± 0.3 (38) | 22.1 ± 0.4* (37)
18–21 | 22.1 ± 0.5 (35) | 22.9 ± 0.4 (29) | 22.6 ± 0.3 (34) | 22.5 ± 0.3 (34) | 23.0 ± 0.5 (30)
6–21 | 19.3 ± 0.2 (35) | 20.1 ± 0.3 (29) | 20.0 ± 0.2 (34) | 19.9 ± 0.2 (33) | 20.0 ± 0.3 (28)
Lactation Day Interval^b,c^
1–4 | 33.24 ± 0.56 (35) | 36.30 ± 0.96* (27) | 36.20 ± 0.76** (33) | 36.39 ± 0.59** (35) | 33.50 ± 0.66 (32)
4–7 | 39.89 ± 0.50* (28) | 40.36 ± 0.69 (25) | 40.41 ± 0.44 (27) | 40.12 ± 0.52 (30) | 38.06 ± 0.45 (27)
7–10 | 47.45 ± 0.92 (28) | 49.54 ± 0.78 (25) | 49.55 ± 0.55 (27) | 49.89 ± 0.56 (30) | 46.44 ± 0.59 (27)
10–14 | 56.81 ± 0.77** (27) | 58.55 ± 0.87 (25) | 57.12 ± 0.61 (27) | 56.10 ± 0.71 (30) | 53.12 ± 0.58** (27)
14–17 | 58.00 ± 0.88 (28) | 58.14 ± 0.83 (25) | 57.53 ± 0.79 (27) | 58.64 ± 0.91 (30) | 57.83 ± 0.73 (27)
17–21 | 72.03 ± 1.29** (28) | 72.80 ± 1.14 (25) | 72.31 ± 1.27 (27) | 66.38 ± 1.74* (30) | 65.58 ± 1.08** (27)
1–14 | 45.45 ± 0.64** (27) | 47.21 ± 0.61 (25) | 46.87 ± 0.49 (27) | 46.38 ± 0.51 (30) | 43.63 ± 0.43* (27)
Chemical Intake (mg/kg/day)^d,e^
GD 6–21 | 0.00 ± 0.00 (35) | 21.62 ± 0.18 (29) | 71.60 ± 0.64 (34) | 213.5 ± 2.14 (33) | 739.9 ± 12.57 (28)
LD 1–14 | 0.00 ± 0.00 (27) | 46.61 ± 0.45 (25) | 155.4 ± 1.36 (27) | 465.6 ± 4.84 (30) | 1,514 ± 15.81 (27)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Data are presented as mean ± standard error (number of dams).

^b^ Feed consumption data are presented as grams/animal/day.

^c^ Each exposure group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^d^ Chemical intake calculated as: ([exposure concentration × feed consumption]/[average body weight of day range]).

^e^ No statistical analysis performed on the chemical intake data.

In the lowest exposure group (300 ppm), total and live litter size were significantly increased (12%) relative to the control group on postnatal day (PND) 1 and PND 4 prestandardization (Table 5). On PND 21, all groups had similar live litter sizes. No significant effects on live litter size occurred in other exposed groups at any time point. No differences in sex ratio or survival during lactation were found.

Table 5 Summary of Mean Litter Size and Survival Ratio of F_1_ Male and Female Rats during Lactation in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

Parameter^a^ | 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
PND 1^b,c^
Total | 11.49 ± 0.35 (35) | 12.85 ± 0.39* (26) | 12.21 ± 0.34 (33) | 12.30 ± 0.25 (33) | 12.09 ± 0.44 (32)
Live | 11.37 ± 0.34 (35) | 12.77 ± 0.39* (26) | 12.18 ± 0.34 (33) | 12.12 ± 0.26 (33) | 11.91 ± 0.46 (32)
% Male per Litter | 50.4 ± 3.1 (31) | 47.7 ± 3.2 (23) | 46.0 ± 3.1 (32) | 48.1 ± 1.7 (32) | 46.1 ± 2.5 (20)
% Male^d,e^ | 50.7 (355) | 47.4 (293) | 46.5 (389) | 48.2 (388) | 46.1 (243)
Male^b,c^
PND 1 | 5.81 ± 0.40 (31) | 6.04 ± 0.46 (23) | 5.66 ± 0.42 (32) | 5.84 ± 0.26 (32) | 5.60 ± 0.48 (20)
PND 4 Prestandardization | 5.77 ± 0.40 (31) | 6.04 ± 0.46 (23) | 5.66 ± 0.42 (32) | 5.84 ± 0.26 (32) | 5.60 ± 0.48 (20)
PND 4 Poststandardization | 4.00 ± 0.10 (28) | 3.88 ± 0.09 (25) | 3.89 ± 0.15 (27) | 4.00 ± 0.00 (30) | 3.85 ± 0.12 (27)
PND 21 | 4.00 ± 0.10 (28) | 3.88 ± 0.09 (25) | 3.85 ± 0.16 (27) | 4.00 ± 0.00 (30) | 3.85 ± 0.12 (27)
Female^b,c^
PND 1 | 5.65 ± 0.37 (31) | 6.70 ± 0.46 (23) | 6.50 ± 0.38 (32) | 6.28 ± 0.25 (32) | 6.55 ± 0.51 (20)
PND 4 Prestandardization | 5.65 ± 0.37 (31) | 6.70 ± 0.46 (23) | 6.47 ± 0.38 (32) | 6.28 ± 0.25 (32) | 6.55 ± 0.51 (20)
PND 4 Poststandardization | 4.00 ± 0.10 (28) | 4.12 ± 0.09 (25) | 4.11 ± 0.15 (27) | 4.00 ± 0.00 (30) | 4.15 ± 0.12 (27)
PND 21 | 4.00 ± 0.10 (28) | 4.08 ± 0.10 (25) | 4.11 ± 0.15 (27) | 4.00 ± 0.00 (30) | 4.11 ± 0.10 (27)
Male and Female^b,c^
PND 4 Prestandardization | 11.34 ± 0.34 (35) | 12.77 ± 0.39* (26) | 12.15 ± 0.35 (33) | 12.12 ± 0.26 (33) | 11.88 ± 0.46 (32)
PND 4 Poststandardization | 8.00 ± 0.00 (28) | 8.00 ± 0.00 (25) | 8.00 ± 0.00 (27) | 8.00 ± 0.00 (30) | 8.00 ± 0.00 (27)
PND 21 | 8.00 ± 0.00 (28) | 7.96 ± 0.04 (25) | 7.96 ± 0.04 (27) | 8.00 ± 0.00 (30) | 7.96 ± 0.04 (27)
Survival per Litter
Total Dead: PND 1–4^e,f^ | 5 (35) | 2 (26) | 2 (33) | 6 (33) | 7 (32)
Total Dead: PND 4–21^e,f^ | 0 (28) | 1 (25) | 1 (27) | 0 (30) | 1 (27)
Dead: PND 1–4^b,c,g^ | 0.14 ± 0.07 (35) | 0.08 ± 0.05 (26) | 0.06 ± 0.04 (33) | 0.18 ± 0.11 (33) | 0.22 ± 0.10 (32)
Dead: PND 4–21^b,c,g^ | 0.00 ± 0.00 (28) | 0.04 ± 0.04 (25) | 0.04 ± 0.04 (27) | 0.00 ± 0.00 (30) | 0.04 ± 0.04 (27)
Survival Ratio: PND 1–4^b,c,h^ | 0.998 ± 0.002 (35) | 1.000 ± 0.000 (26) | 0.997 ± 0.003 (33) | 1.000 ± 0.000 (33) | 0.997 ± 0.003 (32)
Survival Ratio: PND 4–21^b,c,i^ | 1.000 ± 0.000 (28) | 0.995 ± 0.005 (25) | 0.995 ± 0.005 (27) | 1.000 ± 0.000 (30) | 0.995 ± 0.005 (27)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05.

PND = postnatal day.

^a^ Litters in which the male/female pup counts were inconsistent between PND 1 and PND 4 were excluded from the male- or female-specific endpoints.

^b^ Each exposure group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^c^ Data are presented as mean ± standard error (number of litters).

^d^ [100 × (number of live males in dietary exposure group)/(number of live males and females in dietary exposure group)] (number of pups).

^e^ No statistics performed on this endpoint.

^f^ Total number of dead pups in exposure group (number of litters).

^g^ Number dead per litter.

^h^ Survival per litter: Number of pups prestandardization on PND 4/number of live pups on PND 1.

^i^ Survival per litter: Number of live pups on PND 21/number of live pups poststandardization on PND 4.

Male and female pup mean body weight on PND 1 was ≤4% less in the 10,000 ppm group compared to the control group (Table 6). By the end of the lactation period (PND 21), significant decreases in male and female pup weight occurred only in the 10,000 ppm groups, approximately 12% and 13% less than their respective control groups (Table 6).

Table 6 Summary of Preweaning F_1_ Male and Female Rat Pup Mean Body Weights Following Perinatal Exposure to Di-n-butyl Phthalate

Parameter^a^ | 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male (g)
PND 1^b,c,d^ | 7.28 ± 0.12 (31) | 7.38 ± 0.11 (23) | 7.33 ± 0.09 (32) | 7.48 ± 0.08 (32) | 7.00 ± 0.13 (20)
PND 4^e,f,g,h^ | 10.57 ± 0.17** (202/35) | 10.90 ± 0.14 (159/26) | 10.86 ± 0.14 (185/33) | 10.89 ± 0.12 (193/33) | 10.16 ± 0.13 (178/32)
PND 7^e,i^ | 16.32 ± 0.29 (112/28) | 16.29 ± 0.27 (97/25) | 16.61 ± 0.29 (105/27) | 17.04 ± 0.22 (120/30) | 16.76 ± 1.07 (104/27)
PND 14^e,i^ | 33.35 ± 0.50** (112/28) | 34.50 ± 0.36 (97/25) | 34.28 ± 0.48 (105/27) | 34.39 ± 0.38 (119/30) | 31.56 ± 0.39* (104/27)
PND 21^e,i^ | 54.15 ± 0.86** (112/28) | 55.77 ± 0.67 (97/25) | 55.34 ± 0.87 (104/27) | 53.27 ± 0.72 (120/30) | 47.85 ± 0.61** (104/27)
Female (g)
PND 1^b,c,d^ | 6.96 ± 0.13 (31) | 7.09 ± 0.15 (23) | 6.96 ± 0.10 (32) | 7.17 ± 0.08 (32) | 6.77 ± 0.14 (20)
PND 4^e,f,g,h^ | 10.19 ± 0.16** (195/35) | 10.39 ± 0.14 (173/26) | 10.39 ± 0.15 (216/33) | 10.40 ± 0.12 (207/33) | 9.76 ± 0.11 (202/32)
PND 7^e,i^ | 15.93 ± 0.28* (112/28) | 15.56 ± 0.27 (103/25) | 15.82 ± 0.32 (111/27) | 16.30 ± 0.24 (120/30) | 15.05 ± 0.25 (111/27)
PND 14^e,i^ | 32.79 ± 0.54** (112/28) | 33.39 ± 0.33 (102/25) | 33.02 ± 0.49 (111/27) | 33.10 ± 0.37 (120/30) | 30.54 ± 0.35** (110/27)
PND 21^e,i^ | 52.65 ± 0.90** (112/28) | 52.72 ± 0.54 (102/25) | 52.16 ± 0.88 (111/27) | 50.25 ± 0.79 (120/30) | 45.88 ± 0.58** (111/27)
Male and Female (g)
PND 1^b,c,d^ | 7.12 ± 0.10 (35) | 7.15 ± 0.10 (26) | 7.16 ± 0.08 (33) | 7.34 ± 0.08 (33) | 6.77 ± 0.09* (32)
PND 4^e,f,g,h^ | 10.40 ± 0.16** (397/35) | 10.60 ± 0.12 (332/26) | 10.64 ± 0.13 (401/33) | 10.64 ± 0.11 (400/33) | 9.96 ± 0.11 (380/32)
PND 7^e,i^ | 16.12 ± 0.28 (224/28) | 15.91 ± 0.25 (200/25) | 16.23 ± 0.28 (216/27) | 16.67 ± 0.22 (240/30) | 15.89 ± 0.55 (215/27)
PND 14^e,i^ | 33.05 ± 0.50** (224/28) | 33.94 ± 0.32 (199/25) | 33.68 ± 0.41 (216/27) | 33.74 ± 0.35 (239/30) | 31.03 ± 0.33** (214/27)
PND 21^e,i^ | 53.34 ± 0.82** (224/28) | 54.22 ± 0.54 (199/25) | 53.78 ± 0.72 (215/27) | 51.76 ± 0.72 (240/30) | 46.86 ± 0.55** (215/27)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

PND = postnatal day.

^a^ Statistical analysis performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^b^ Data are presented as mean ± standard error (number of litters).

^c^ Each exposure group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^d^ Total pup weight at PND 1 divided by number of live pups at PND 1.

^e^ Data are presented as mean of litter means ± standard error (number of pups/number of litters).

^f^ PND 4 prestandardization.

^g^ Individual pup weights first adjusted for live litter size on PND 1.

^h^ Litters in which the male/female pup counts were inconsistent between PND 1 and PND 4 were excluded from the male- or female-specific endpoints.

^i^ Individual pup weights first adjusted for live litter size on PND 4 poststandardization.

Mono-n-butyl phthalate (MBP) concentrations were measured using validated analytical methods in samples taken on GD 18 and PND 4 (Table 7).^115^ Low concentrations were detected in some matrices in control groups, likely due to a combination of background levels from sample collection and from the analytical assay. At GD 18, MBP concentrations increased more than proportionally to the exposure concentration, despite a linear increase in chemical consumption. There was an approximately 137-fold and 83-fold increase in dam plasma and fetus MBP concentrations, respectively, in the 10,000 ppm group compared to the 300 ppm group, but exposure concentration increased only approximately 33-fold. Concentrations in fetuses were approximately 17%–29% that of dam plasma, demonstrating moderate gestational transfer of MBP (Table 7). MBP was also measured in amniotic fluid at concentrations lower than those found in fetuses (Table 7).

Table 7 Summary of Internal Dose Data for Rats in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Mono-n-butyl Phthalate Concentration^a,b^
n | 5 | 5 | 5 | 3^c^ | 5
Gestation Day 18
Dam plasma (ng/mL)^d^ | 9.2 ± 4.0** | 1,148.0 ± 48.3** | 4,372.0 ± 567.1** | 19,633.3 ± 3,077.5** | 156,800.0 ± 3,878.1**
Amniotic fluid (ng/mL) | BD^e^ | 84.5 ± 13.7 | 403.8 ± 34.5 | 1,693.3 ± 153.4 | 22,760.0 ± 2,183.3
Fetuses (ng/g)^f^ | BD | 323.6 ± 17.8 | 1,270.6 ± 127.7 | 3,930.0 ± 705.0 | 26,840.0 ± 2,763.6
n | 5 | 2^g^ | 5 | 5 | 5
Postnatal Day 4
Dam plasma (ng/mL) | BD | 1,625.0 ± 75.0 | 6,234.0 ± 897.2 | 25,580.0 ± 2,272.1 | 161,200.0 ± 17,690.1
Pups (ng/g)^h,i^ | 8.6 ± 1.3** | 146.6 ± 103.7 | 350.8 ± 70.8** | 2,743.2 ± 725.5** | 4,721.5 ± 1,044.6**

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BD = below detection; group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Data are presented as mean ± standard error except for pup concentrations, which are displayed as mean ± standard error of the litter means.

^b^ Values below the LOD (6.9 ng/mL in plasma, 21.8 ng/mL in amniotic fluid, 9.4 ng/g in fetuses) were substituted with one-half the LOD value.

^c^ Three of the five dams designated for biological sampling were determined not to be pregnant. Although the replacement dams for this group were pregnant, only three complete sample sets (dam plasma, amniotic fluid, fetuses) were able to be collected.

^d^ Statistical analysis performed by the Jonckheere (trend) and the Shirley or Dunn (pairwise) tests.

^e^ If 80% or more of the values in the vehicle control group were below the LOD, no mean or standard error were calculated and no statistical analysis was performed.

^f^ All fetuses from the dam were used and weights recorded.

^g^ Only one extra litter (beyond the 25 minimum used for the 2-year study) met the collection criteria for this exposure group. An additional litter consisting of two male pups and one female pup (that would have been standardized due to unacceptable sex split) was used for biological sample collection.

^h^ Statistical analysis for pup concentrations was performed using a bootstrapped Jonckheere trend test, and pairwise comparisons used the Datta-Satten modified Wilcoxon test with a Hommel adjustment for multiple comparisons.

^i^ The number of pups evaluated was 20 in all groups (2 male pups and 2 female pups per dam) except for the 300 ppm group in which only 7 pups were able to be evaluated. Data reported are for male and female pup data combined.

MBP concentrations in exposed dams on PND 4 were slightly higher than concentrations detected at GD 18 in respective exposure groups likely due to higher feed and, subsequently, chemical consumption (Table 7). Similar to what was found in dams on GD 18, MBP concentrations in dam plasma on PND 4 increased more than proportionally to the exposure concentration, despite a linear increase in chemical consumption, with an approximately 99-fold increase in concentration when exposure concentration increased approximately 33-fold. MBP concentrations in whole pups increased proportionally to the exposure concentration. Concentrations in whole pups were approximately 3%–11% that of dams, demonstrating low lactational transfer of MBP in rats.

### Two-year Study (Postweaning Phase)

Survival of all male and female exposure groups was similar to that of the control groups (Table 8; Figure 2). There were no exposure-related clinical observations (Appendix E).

Table 8 Summary of Survival of Male and Female Rats in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Animals Initially in Study | 49^a^ | 50 | 50 | 50 | 50
Moribund | 9 | 4 | 10 | 9 | 10
Natural Deaths | 13 | 8 | 9 | 7 | 7
Animals Surviving to Study Termination | 27^b^ | 38 | 31 | 34 | 33^b^
Percent Probability of Survival at End of Study^c^ | 55.1 | 76.0 | 62.0 | 68.0 | 66.0
Mean Survival (Days)^d^ | 674 | 691 | 694 | 685 | 655
Survival Analysis^e^ | p = 0.948 | p = 0.029N | p = 0.354N | p = 0.168N | p = 0.359N
Female
Animals Initially in Study | 50 | 50 | 50 | 50 | 50
Moribund | 9 | 8 | 14 | 11 | 13
Natural Deaths | 12 | 5 | 9 | 7 | 8
Animals Surviving to Study Termination | 29^f^ | 37 | 27^b^ | 32 | 29
Percent Probability of Survival at End of Study | 58.0 | 74.0 | 54.0 | 64.0 | 58.0
Mean Survival (Days) | 669 | 679 | 645 | 671 | 648
Survival Analysis | p = 0.490 | p = 0.137N | p = 0.540 | p = 0.590N | p = 0.803

^a^ One pup was missexed at the beginning of the study and was removed.

^b^ Includes one animal that died naturally during the last week of the study.

^c^ Kaplan-Meier determinations.

^d^ Mean of litter means of all deaths (uncensored, censored, and study termination).

^e^ The result of the Cox proportional hazards trend test is in the vehicle control group column, and the results of the Cox proportional hazards pairwise comparisons with the vehicle control group are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^f^ Includes one animal that was euthanized moribund during the last week of the study.

Figure 2

Kaplan-Meier Survival Curves for Rats Exposed to Di-n-butyl Phthalate in Feed for Two Years

Exposure-related significant decreases in group mean body weight were observed throughout the study in both males and females in the 10,000 ppm groups (Table 9, Table 10; Figure 3). At study termination, group mean body weights of the 10,000 ppm group were lower than those of the control groups by 3.5% in males and by 10.6% in females. Group mean feed consumption over the course of the study was similar across exposed and control groups, except that males in the 10,000 ppm group tended to consume less than control males (1%–25% less) (Table 11, Table 12; Appendix E). Group mean chemical consumption increased proportionally to exposure concentration and was similar across male and female animals. Average daily chemical consumption (mg/kg/day) by the 300, 1,000, 3,000, and 10,000 ppm groups was 16.4, 53.6, 152.3, and 510.4 mg/kg/day, respectively, for males and 17.2, 57.4, 168.8, and 599.9 mg/kg/day, respectively, for females.

Table 9 Summary of Survival and Mean Body Weights of Male Rats in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

Study Day^a^ | 0 ppm | | 300 ppm | | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Study Day^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 55.1 | 25 | 57.3 | 104.0 | 25 | 56.7 | 103.0 | 25 | 53.7 | 97.4 | 25 | 50.0 | 90.7 | 25
8 | 87.0 | 25 | 89.5 | 102.9 | 25 | 90.1 | 103.6 | 25 | 86.6 | 99.6 | 25 | 80.0 | 91.9 | 25
15 | 130.4 | 25 | 135.5 | 103.9 | 25 | 135.5 | 103.9 | 25 | 131.2 | 100.6 | 25 | 120.9 | 92.7 | 25
22 | 179.0 | 25 | 184.1 | 102.6 | 25 | 184.3 | 102.8 | 25 | 179.9 | 100.3 | 25 | 166.9 | 93.1 | 25
29 | 226.3 | 25 | 231.3 | 102.2 | 25 | 233.5 | 103.2 | 25 | 225.5 | 99.6 | 25 | 212.0 | 93.7 | 25
36 | 269.4 | 25 | 276.2 | 102.5 | 25 | 276.8 | 102.7 | 25 | 271.7 | 100.8 | 25 | 252.0 | 93.6 | 25
43 | 304.5 | 25 | 310.3 | 101.9 | 25 | 309.0 | 101.5 | 25 | 302.5 | 99.3 | 25 | 285.8 | 93.9 | 25
50 | 328.9 | 25 | 335.6 | 102.0 | 25 | 331.3 | 100.7 | 25 | 331.5 | 100.8 | 25 | 308.0 | 93.7 | 25
57 | 352.6 | 25 | 354.7 | 100.6 | 25 | 353.2 | 100.2 | 25 | 352.5 | 100.0 | 25 | 320.3 | 90.8 | 25
64 | 370.4 | 25 | 373.1 | 100.7 | 25 | 371.2 | 100.2 | 25 | 369.4 | 99.7 | 25 | 332.2 | 89.7 | 25
71 | 385.0 | 25 | 382.5 | 99.3 | 25 | 381.4 | 99.1 | 25 | 378.0 | 98.2 | 25 | 342.1 | 88.9 | 25
78 | 396.8 | 25 | 388.9 | 98.0 | 25 | 390.8 | 98.5 | 25 | 385.8 | 97.2 | 25 | 348.5 | 87.8 | 25
85 | 404.0 | 25 | 394.1 | 97.5 | 25 | 397.3 | 98.3 | 25 | 389.8 | 96.5 | 25 | 353.0 | 87.4 | 25
92 | 411.1 | 25 | 402.1 | 97.8 | 25 | 407.0 | 99.0 | 25 | 396.2 | 96.4 | 25 | 358.7 | 87.3 | 25
120 | 438.9 | 25 | 435.8 | 99.3 | 25 | 442.5 | 100.8 | 25 | 428.5 | 97.6 | 25 | 389.2 | 88.7 | 25
148 | 454.8 | 25 | 462.8 | 101.8 | 25 | 461.7 | 101.5 | 25 | 458.1 | 100.7 | 25 | 411.1 | 90.4 | 25
176 | 482.5 | 25 | 474.2 | 98.3 | 25 | 485.2 | 100.6 | 25 | 479.4 | 99.4 | 25 | 428.6 | 88.8 | 25
204 | 504.4 | 25 | 490.0 | 97.1 | 25 | 505.2 | 100.2 | 25 | 492.4 | 97.6 | 25 | 442.4 | 87.7 | 25
232 | 509.7 | 25 | 507.2 | 99.5 | 25 | 521.0 | 102.2 | 25 | 505.0 | 99.1 | 25 | 456.2 | 89.5 | 25
260 | 515.6 | 25 | 520.5 | 100.9 | 25 | 531.5 | 103.1 | 25 | 521.6 | 101.2 | 25 | 471.2 | 91.4 | 25
288 | 541.9 | 25 | 534.0 | 98.5 | 25 | 546.1 | 100.8 | 25 | 536.3 | 99.0 | 25 | 477.9 | 88.2 | 25
316 | 552.7 | 25 | 537.6 | 97.3 | 25 | 559.0 | 101.1 | 25 | 539.5 | 97.6 | 25 | 485.0 | 87.7 | 25
344 | 561.4 | 25 | 545.8 | 97.2 | 25 | 571.0 | 101.7 | 25 | 548.8 | 97.8 | 25 | 493.1 | 87.8 | 25
372 | 574.7 | 25 | 556.6 | 96.9 | 25 | 583.8 | 101.6 | 25 | 565.5 | 98.4 | 25 | 505.1 | 87.9 | 25
400 | 580.8 | 25 | 565.4 | 97.4 | 25 | 587.4 | 101.1 | 25 | 572.6 | 98.6 | 25 | 512.3 | 88.2 | 25
428 | 601.1 | 25 | 576.2 | 95.9 | 25 | 606.0 | 100.8 | 25 | 583.2 | 97.0 | 25 | 529.4 | 88.1 | 25
456 | 604.9 | 25 | 585.4 | 96.8 | 25 | 614.5 | 101.6 | 25 | 587.3 | 97.1 | 25 | 536.2 | 88.7 | 25
484 | 609.6 | 25 | 600.7 | 98.5 | 25 | 621.1 | 101.9 | 25 | 598.5 | 98.2 | 25 | 546.9 | 89.7 | 25
512 | 619.7 | 25 | 606.9 | 97.9 | 25 | 625.3 | 100.9 | 25 | 607.9 | 98.1 | 25 | 552.9 | 89.2 | 25
540 | 624.8 | 25 | 605.9 | 97.0 | 25 | 625.6 | 100.1 | 25 | 608.7 | 97.4 | 25 | 554.7 | 88.8 | 25
568 | 623.1 | 25 | 614.3 | 98.6 | 24 | 631.1 | 101.3 | 25 | 623.0 | 100.0 | 25 | 560.2 | 89.9 | 25
596 | 626.2 | 25 | 607.2 | 97.0 | 24 | 624.5 | 99.7 | 25 | 630.1 | 100.6 | 25 | 556.1 | 88.8 | 25
624 | 624.6 | 25 | 624.2 | 99.9 | 24 | 624.4 | 100.0 | 25 | 632.3 | 101.2 | 25 | 571.3 | 91.5 | 24
652 | 617.4 | 25 | 612.8 | 99.3 | 24 | 624.8 | 101.2 | 25 | 631.4 | 102.3 | 25 | 565.1 | 91.5 | 24
680 | 605.4 | 24 | 595.3 | 98.3 | 24 | 624.5 | 103.2 | 25 | 626.5 | 103.5 | 25 | 558.5 | 92.3 | 24
708 | 583.3 | 22 | 591.9 | 101.5 | 23 | 606.5 | 104.0 | 25 | 610.0 | 104.6 | 24 | 565.0 | 96.9 | 23
EOS | 589.1 | 20 | 592.0 | 100.5 | 23 | 611.6 | 103.8 | 23 | 608.9 | 103.4 | 23 | 568.5 | 96.5 | 23

EOS = end of study; No. of litters = number of litters represented in weight average.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are means of litter means.

Table 10 Summary of Survival and Mean Body Weights of Female Rats in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

Study Day^a^ | 0 ppm | | 300 ppm | | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Study Day^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 56.5 | 25 | 56.8 | 100.5 | 25 | 54.8 | 96.9 | 25 | 54.2 | 95.9 | 25 | 48.7 | 86.2 | 25
8 | 86.0 | 25 | 85.5 | 99.4 | 25 | 84.2 | 97.9 | 25 | 83.6 | 97.2 | 25 | 77.3 | 89.9 | 25
15 | 120.4 | 25 | 120.7 | 100.3 | 25 | 119.6 | 99.4 | 25 | 118.3 | 98.2 | 25 | 111.0 | 92.1 | 25
22 | 151.2 | 25 | 149.7 | 99.0 | 25 | 148.6 | 98.3 | 25 | 149.0 | 98.5 | 25 | 141.1 | 93.3 | 25
29 | 170.2 | 25 | 165.6 | 97.3 | 25 | 168.5 | 99.0 | 25 | 169.7 | 99.7 | 25 | 162.5 | 95.5 | 25
36 | 190.3 | 25 | 190.7 | 100.2 | 25 | 187.9 | 98.7 | 25 | 188.3 | 98.9 | 25 | 179.6 | 94.4 | 25
43 | 203.9 | 25 | 204.5 | 100.3 | 25 | 197.3 | 96.8 | 25 | 203.3 | 99.7 | 25 | 194.8 | 95.5 | 25
50 | 217.0 | 25 | 218.1 | 100.5 | 25 | 212.8 | 98.1 | 25 | 215.1 | 99.1 | 25 | 204.2 | 94.1 | 25
57 | 224.4 | 25 | 227.3 | 101.3 | 25 | 221.7 | 98.8 | 25 | 223.6 | 99.6 | 25 | 215.3 | 96.0 | 25
64 | 233.3 | 25 | 235.8 | 101.1 | 25 | 231.1 | 99.0 | 25 | 233.6 | 100.1 | 25 | 223.9 | 96.0 | 25
71 | 238.8 | 25 | 239.7 | 100.4 | 25 | 237.2 | 99.3 | 25 | 240.2 | 100.6 | 25 | 228.4 | 95.6 | 25
78 | 243.8 | 25 | 244.0 | 100.1 | 25 | 241.4 | 99.0 | 25 | 241.5 | 99.1 | 25 | 233.3 | 95.7 | 25
85 | 249.6 | 25 | 249.0 | 99.8 | 25 | 247.0 | 99.0 | 25 | 248.3 | 99.5 | 25 | 237.9 | 95.3 | 25
92 | 255.0 | 25 | 253.6 | 99.4 | 25 | 249.6 | 97.9 | 25 | 251.9 | 98.8 | 25 | 242.9 | 95.3 | 25
120 | 268.6 | 25 | 267.4 | 99.6 | 25 | 264.6 | 98.5 | 25 | 266.2 | 99.1 | 25 | 256.4 | 95.5 | 25
148 | 276.7 | 25 | 275.5 | 99.6 | 25 | 273.7 | 98.9 | 25 | 272.9 | 98.6 | 25 | 262.9 | 95.0 | 25
176 | 288.4 | 25 | 287.1 | 99.6 | 25 | 284.8 | 98.8 | 25 | 286.7 | 99.4 | 25 | 269.6 | 93.5 | 25
204 | 297.3 | 25 | 292.7 | 98.4 | 25 | 290.1 | 97.6 | 25 | 292.2 | 98.3 | 25 | 276.7 | 93.1 | 25
232 | 303.8 | 25 | 301.5 | 99.2 | 25 | 296.6 | 97.6 | 25 | 298.8 | 98.4 | 25 | 278.9 | 91.8 | 25
260 | 311.0 | 25 | 307.4 | 98.9 | 25 | 306.7 | 98.6 | 25 | 306.3 | 98.5 | 25 | 284.3 | 91.4 | 25
288 | 313.8 | 25 | 311.5 | 99.3 | 25 | 311.9 | 99.4 | 25 | 312.6 | 99.6 | 25 | 292.0 | 93.1 | 25
316 | 322.9 | 25 | 316.7 | 98.1 | 25 | 320.9 | 99.4 | 25 | 319.6 | 99.0 | 25 | 294.8 | 91.3 | 25
344 | 329.5 | 25 | 322.6 | 97.9 | 25 | 325.5 | 98.8 | 25 | 324.3 | 98.4 | 25 | 295.9 | 89.8 | 25
372 | 327.4 | 25 | 328.0 | 100.2 | 25 | 335.0 | 102.3 | 25 | 329.8 | 100.7 | 25 | 298.9 | 91.3 | 25
400 | 329.5 | 25 | 336.1 | 102.0 | 25 | 338.0 | 102.6 | 25 | 328.6 | 99.7 | 25 | 299.0 | 90.7 | 25
428 | 341.4 | 25 | 338.0 | 99.0 | 25 | 347.7 | 101.9 | 25 | 339.4 | 99.4 | 25 | 307.2 | 90.0 | 25
456 | 343.8 | 25 | 342.5 | 99.6 | 25 | 345.9 | 100.6 | 25 | 347.1 | 101.0 | 25 | 304.2 | 88.5 | 25
484 | 354.5 | 25 | 350.3 | 98.8 | 25 | 352.7 | 99.5 | 25 | 353.0 | 99.6 | 25 | 309.0 | 87.2 | 25
512 | 360.5 | 25 | 350.8 | 97.3 | 25 | 360.8 | 100.1 | 25 | 356.6 | 98.9 | 25 | 312.1 | 86.6 | 25
540 | 363.9 | 25 | 356.8 | 98.1 | 25 | 370.0 | 101.7 | 25 | 366.1 | 100.6 | 24 | 320.0 | 88.0 | 25
568 | 372.7 | 25 | 359.0 | 96.3 | 25 | 369.0 | 99.0 | 24 | 367.5 | 98.6 | 24 | 326.5 | 87.6 | 24
596 | 378.9 | 25 | 366.0 | 96.6 | 24 | 371.0 | 97.9 | 24 | 374.4 | 98.8 | 24 | 321.3 | 84.8 | 23
624 | 393.7 | 24 | 368.9 | 93.7 | 24 | 376.5 | 95.6 | 23 | 381.0 | 96.8 | 23 | 328.5 | 83.4 | 22
652 | 397.4 | 24 | 371.9 | 93.6 | 24 | 380.1 | 95.6 | 22 | 375.6 | 94.5 | 22 | 330.3 | 83.1 | 21
680 | 390.4 | 23 | 363.5 | 93.1 | 24 | 379.2 | 97.1 | 21 | 388.4 | 99.5 | 21 | 331.5 | 84.9 | 20
708 | 391.3 | 23 | 366.0 | 93.5 | 23 | 375.0 | 95.8 | 19 | 386.8 | 98.9 | 21 | 339.0 | 86.6 | 19
EOS | 390.3 | 22 | 374.7 | 96.0 | 23 | 375.5 | 96.2 | 18 | 393.4 | 100.8 | 20 | 348.8 | 89.4 | 19

EOS = end of study; No. of litters = number of litters represented in weight average.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are means of litter means.

Figure 3

Growth Curves for Rats Exposed to Di-n-butyl Phthalate in Feed for Two Years

Table 11 Summary of Feed and Di-n-butyl Phthalate Consumption of Male Rats in the Perinatal and Two-year Feed Study

Week | 0 ppm | 300 ppm | | 1,000 ppm | | 3,000 ppm | | 10,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 9.0 | 9.1 | 47.7 | 9.2 | 162.2 | 8.8 | 492.0 | 7.8 | 1,560.5
13 | 24.3 | 23.9 | 18.2 | 24.0 | 60.4 | 21.5 | 165.5 | 19.9 | 562.7
54 | 27.2 | 27.6 | 14.8 | 27.6 | 47.3 | 26.4 | 140.0 | 22.7 | 450.4
102 | 21.4 | 24.6 | 12.4 | 22.7 | 37.3 | 23.0 | 112.9 | 22.1 | 391.4

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of di-n-butyl phthalate consumed per kilogram body weight per day.

Table 12 Summary of Feed and Di-n-butyl Phthalate Consumption of Female Rats in the Perinatal and Two-year Feed Study

Week | 0 ppm | 300 ppm | | 1,000 ppm | | 3,000 ppm | | 10,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 9.6 | 9.2 | 48.6 | 9.7 | 177.0 | 9.6 | 531.2 | 8.6 | 1,764.6
13 | 15.6 | 15.3 | 18.4 | 15.2 | 61.5 | 15.5 | 187.3 | 15.0 | 630.5
54 | 16.8 | 16.4 | 15.0 | 17.1 | 51.7 | 16.7 | 152.1 | 16.3 | 544.7
102 | 19.9 | 19.4 | 15.8 | 19.2 | 51.6 | 19.4 | 149.8 | 20.2 | 600.3

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of di-n-butyl phthalate consumed per kilogram body weight per day.

#### Pathology

This section describes statistically significant or biologically noteworthy changes in the incidences of neoplasms and/or nonneoplastic lesions of the pancreas, testis, epididymis, prostate gland, seminal vesicle, preputial gland, pituitary gland, liver, and uterus. Summaries of the incidences of neoplasms and nonneoplastic lesions, individual animal tumor diagnoses, statistical analysis of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the biologically significant neoplasms mentioned in this section are presented as supplemental data in Appendix E.

Exocrine Pancreas: The incidence of exocrine pancreatic acinus adenomas in the male rats was slightly higher in the 10,000 ppm group compared to the control group, but only the positive trend was statistically significant (Table 13). Two pancreatic acinus carcinomas occurred in the control group and none in the exposed groups (Table 13). The incidence of pancreatic acinus adenomas in the 10,000 ppm group was within the historical control range (0% to 28%) for studies in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats on the NTP-2000 diet, all exposure routes, and all vehicles. The incidence of pancreatic acinus carcinomas in the control group exceeded the previous historical control range (0% to 4%). The incidence of pancreatic acinus hyperplasia was not significantly increased in any of the exposure groups (Table 13).

Table 13 Incidences of Neoplastic and Nonneoplastic Lesions of the Pancreas in Male Rats in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
n^a^ | 49 | 50 | 50 | 50 | 49
Acinus, Hyperplasia^b^ | 19 (2.3)^c^ | 21 (2.1) | 18 (2.1) | 23 (2.0) | 18 (2.1)
Acinus, Adenoma, Multiple | 2 | 1 | 0 | 0 | 2
Acinus, Adenoma (Includes Multiple)^d^
Overall rate^e^ | 4/49 (8%) | 4/50 (8%) | 3/50 (6%) | 1/50 (2%) | 10/49 (20%)
Rate per litters^f^ | 4/25 (16%) | 4/25 (16%) | 3/25 (12%) | 1/25 (4%) | 9/25 (36%)
Adjusted rate^g^ | 9.7% | 8.9% | 6.8% | 2.3% | 24.1%
Terminal rate^h^ | 2/27 (7%) | 3/38 (8%) | 3/31 (10%) | 1/34 (3%) | 8/33 (24%)
First incidence (days) | 676 | 565 | 729 (T) | 729 (T) | 684
Rao-Scott-adjusted Poly-3 test^i^ | p = 0.010 | p = 0.595N | p = 0.472N | p = 0.192N | p = 0.094
Acinus, Carcinoma^j^ | 2 | 0 | 0 | 0 | 0
Acinus, Adenoma or Carcinoma (Combined)^l^
Overall rate | 6/49 (12%) | 4/50 (8%) | 3/50 (6%) | 1/50 (2%) | 10/49 (20%)
Rate per litters | 6/25 (24%) | 4/25 (16%) | 3/25 (12%) | 1/25 (4%) | 9/25 (36%)
Adjusted rate | 14.3% | 8.9% | 6.8% | 2.3% | 24.1%
Terminal rate | 2/27 (7%) | 3/38 (8%) | 3/31 (10%) | 1/34 (3%) | 8/33 (24%)
First incidence (days) | 611 | 565 | 729 (T) | 729 (T) | 684
Rao-Scott-adjusted Poly-3 test | p = 0.024 | p = 0.349N | p = 0.243N | p = 0.072N | p = 0.217

(T) = terminal euthanasia.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 60/488 (11.58% ± 9.25%); range: 0%–28%.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Number of litters with tumor-bearing animals per number of litters examined at anatomical site.

^g^ Poly-3-estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at study termination.

^i^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidences are the p values corresponding to pairwise comparisons between the control group and that exposed group. The Rao-Scott test adjusts the Poly-3 test, which accounts for differential mortality in animals that do not reach study termination, for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^j^ Historical control incidence: 4/488 (0.8% ± 1.42%); range: 0%–4%.

^k^ Not applicable; no neoplasms in animal group.

^l^ Historical control incidence: 62/488 (12.03% ± 9.16%); range: 0%–28%.

The adenomas of the exocrine pancreas were discrete masses of neoplastic acinar cells that often compressed the adjacent tissue. The masses were >3 mm in diameter and largely devoid of islets of Langerhans, with the exception of the occasional entrapped islet at the edge of the mass. As opposed to the carcinomas, the adenomas lacked a fibrous capsule, were not invasive, and the neoplastic cells did not exhibit atypia. Mitotic figures were rare. Acinus hyperplasia was similar to adenoma but was smaller (<3 mm in diameter) and generally lacked compression of adjacent tissue.

Male Reproductive Tract: Several exposure-related gross lesions occurred in the reproductive tract of male rats (Table 14). These lesions included undescended testes; fluid- or blood-filled testes; missing or small testes, epididymides, prostate glands, seminal vesicles, or vas deferens; and missing gubernaculum or gubernaculum with a length >20 mm. These lesions occurred with the greatest frequency in the 10,000 ppm group. Of a total of 46 animals examined in this group, 36 had small testes, 27 had small epididymides, 4 had small prostate glands, 7 had small seminal vesicles, 19 (of the 40 measured) had an increased gubernacular length (>20 mm), and 36 had undescended testes.

Table 14 Summary of Gross Lesions in the Reproductive Tract of Male Rats in the Perinatal and Two-year Feed study of Di-n-butyl Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
n^a^ | 48 | 49 | 48 | 49 | 46
Testis^b^
Size, small | 1**^c^ (1)^d^ | 0 | 4 (4) | 2 (2) | 36** (23)
Size, enlarged (or swelling) | 0 | 0 | 1 (1) | 1 (1) | 1 (1)
Fluid or blood filled | 1 (1) | 0 | 0 | 1 (1) | 3 (3)
Right, not present | 0 | 0 | 0 | 0 | 2 (2)
Right or left; abdominal; undescended | 1** (1) | 3 (3) | 2 (2) | 2 (2) | 29** (21)
Right or left; inguinal; undescended | 1** (1) | 0 | 0 | 0 | 7 (7)
Right or left; abdominal or inguinal; undescended | 2** (2) | 3 (3) | 2 (2) | 2 (2) | 32** (23)
Epididymis^b^
Size, small | 0** | 0 | 3 (3) | 0 | 27** (19)
Right, agenesis | 0 | 0 | 0 | 0 | 2 (2)
Prostate Glands^b^
Size, small | 0* | 0 | 1 (1) | 2 (2) | 4 (4)
Right or left, ventral, dorsal, or lateral, agenesis | 0 | 0 | 0 | 1 (1) | 2 (2)
Seminal Vesicles^b^
Size, small | 1* (1) | 2 (2) | 2 (2) | 1 (1) | 7 (6)
Vas Deferens^b^
Right, not present | 0 | 0 | 0 | 0 | 2 (2)
Gubernaculum^e,f^
Right, not present | 0 | 0 | 0 | 0 | 1 (1)
Left, length (mm) | 14.24 ± 0.83 33 (23)^g^ | 14.73 ± 0.71 41 (24) | 13.18 ± 0.78 39 (25) | 14.78 ± 0.89 38 (23) | 30.92 ± 4.09 35 (24)
Right, length (mm) | 14.04 ± 0.71 33 (23) | 14.52 ± 0.70 41 (24) | 13.84 ± 0.85 39 (25) | 14.80 ± 0.75 38 (23) | 33.86 ± 4.80 33 (22)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Number of animals examined for each tissue.

^b^ Statistical analysis performed by the Cochran-Armitage test with a Rao-Scott modification for the random effect due to litter.

All trend and pairwise p values are reported as one-sided.

^c^ Number of animals affected given each observation.

^d^ Number of litters with observations for F_1_ animals. F_1_ litter incidence based on the number of F_0_ dams.

^e^ Statistical analysis performed using a bootstrapped Jonckheere test for trend and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons.

^f^ Data are presented as mean ± standard error.

^g^ Number of animals examined (number of litters represented).

In general, the diagnosis of small testis correlated microscopically to germinal epithelial atrophy, enlarged testis correlated to interstitial cell adenoma and/or interstitial edema, and fluid-filled testis correlated to interstitial edema. Small testes tended to also be undescended (either abdominal or inguinal locations). In the two male rats exposed to 10,000 ppm DBP with right testis not present (synonymous with agenesis), both also had the right vas deferens not present, and agenesis of the right epididymis (caput, corpus, and cauda) and ventral prostate gland (right and left). In addition, the left testis in both animals was undescended (abdominal location) and small. A single animal was exposed to 3,000 ppm DBP with agenesis of the right side of the prostate (ventral, dorsal, or lateral lobes). There did not appear to be differences in laterality of other male reproductive tract lesions; therefore, combined incidences are shown.

In general, small epididymis correlated to hypospermia, and small seminal vesicle and small prostate gland both correlated to decreased secretory fluid. There were low occurrences of other gross lesions in the male and female reproductive tracts, but they were considered sporadic and unrelated to DBP exposure (Appendix E).

Testis: Several lesions were observed in the testis involving the seminiferous tubules, the interstitium, or the rete testis (Table 15). There were significant increases in the incidences of the combination of unilateral and bilateral edema, bilateral germinal epithelial atrophy, the combination of unilateral and bilateral germinal epithelial atrophy, diffuse interstitial cell hyperplasia (always bilateral when it was diagnosed), the combination of unilateral and bilateral focal interstitial cell hyperplasia, the combination of unilateral and bilateral rete testis fibrosis, and the combination of unilateral and bilateral seminiferous tubule dysgenesis (Table 15, Appendix E). The incidences of these lesions were all significantly increased in the 10,000 ppm group compared to the control group, and the positive trends also were statistically significant. The incidences of germinal epithelial atrophy and focal interstitial cell hyperplasia also were significantly increased in the 300 ppm group. The average severities of germinal epithelium atrophy were higher in the 1,000, 3,000, and 10,000 ppm groups than in the control group. The incidence of sperm granuloma in the rete testis also was higher in the 10,000 ppm group; although not statistically significant, it was considered related to DBP exposure as sperm granuloma is thought to be the precursor lesion to rete testis fibrosis. The incidences of the combination of unilateral and bilateral germinal epithelium degeneration were not higher compared to the control group (Table 15). The average severity of this lesion was higher in the exposed groups. This is a common background change in laboratory rodents, but the lower incidence of degeneration in the 10,000 ppm group is likely due to exacerbation by DBP exposure, resulting in progression to atrophy, which was clearly exposure-related (degeneration is considered to be on a continuum with atrophy, with atrophy the end stage of ongoing degeneration).

Table 15 Incidences of Nonneoplastic Lesions of the Testis, Epididymis, Prostate Gland, and Seminal Vesicle in Male Rats in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Testis^a^ | 49 | 50 | 50 | 47 | 50
Edema (includes bilateral)^b^ | 2** (3.0)^c^ | 3 (2.0) | 2 (2.5) | 2 (3.0) | 18** (3.5)
Germinal epithelium, atrophy (includes bilateral) | 8** (2.3) | 21** (1.8) | 11 (2.5) | 10 (2.9) | 42** (3.9)
Germinal epithelium, degeneration (includes bilateral) | 8 (1.1) | 7 (2.6) | 12 (2.2) | 7 (2.0) | 3 (2.0)
Interstitial cell, hyperplasia, diffuse, bilateral^d^ | 0** | 0 | 1 (2.0) | 0 | 9** (2.2)
Interstitial cell, hyperplasia, focal (includes bilateral) | 1* (3.0) | 7* (1.6) | 5 (1.2) | 3 (1.7) | 11** (1.5)
Rete testis, fibrosis (includes bilateral) | 0** | 0 | 0 | 0 | 11** (2.5)
Rete testis, sperm granuloma (includes bilateral) | 0 | 0 | 0 | 0 | 2
Seminiferous tubule, dysgenesis (includes bilateral) | 0** | 0 | 0 | 1 (2.0) | 9* (1.9)
Epididymis | 49 | 50 | 50 | 50 | 50
Hypospermia (includes bilateral) | 4** (3.5) | 7 (3.1) | 10 (3.0) | 9 (3.2) | 40** (3.9)
Prostate Gland | 49 | 50 | 50 | 50 | 50
Decreased secretory fluid^e^ | 5** | 8 | 5 | 5 | 18**
Seminal Vesicle | 49 | 50 | 50 | 50 | 49
Decreased secretory fluid^e^ | 6** | 7 | 9 | 6 | 15*

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant (p ≤ 0.05) from the vehicle control group by the Rao-Scott adjusted Poly-3 test; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Incidence reported is the combination of unilateral and bilateral lesions. Severity grade for these types of lesions = sum of unilateral and bilateral severity scores/number of unilateral and bilateral incidences.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ This lesion was observed only as a bilateral lesion.

^e^ This lesion was not graded.

Microscopically, germinal epithelium atrophy was seen as seminiferous tubules devoid of germ cells and lined only by Sertoli cells. Germinal epithelium degeneration was observed as several degenerative features, frequently co-occurring, including tubular vacuolation, focal to segmental germ cell dropout, general depletion of germ cells, degeneration of germ cells not restricted to stage or cell type, and disorganization of the germinal epithelium.

Seminiferous tubule dysgenesis (Figure 4) was observed microscopically as malformed, anastomosing seminiferous tubules. Generally, lesions of dysgenesis consisted of a single focus per testis, but, occasionally, up to three foci were observed. Tubules in dysgenetic lesions were not active in spermatogenesis and contained immature-appearing Sertoli cells with small, elongated nuclei and a less prominent nucleolus than observed in mature Sertoli cells. The basement membranes were thickened and convoluted and appeared discontinuous in some areas. Small “islands” of entrapped Leydig cells were occasionally present within the malformed tubules. Dysgenetic lesions often were surrounded by angular aggregates of Leydig cells, which were smaller, spindle-shaped, and contained less cytoplasm than typically observed in focal Leydig cell hyperplasia or adenomas. Dysgenesis was usually observed in only one of the three sections of a single testis and was generally located in a section of testis that also contained the rete testis.

Figure 4

Representative Images Depicting Seminiferous Tubule Dysgenesis in a Male Rat in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

A) Seminiferous tubule dysgenesis (arrow) in a 10,000 ppm male rat. There is also germinal epithelial atrophy in all seminiferous tubules, as well as interstitial edema. B) Higher magnifications of the dysgenesis lesion in panel A showing the convoluted, malformed seminiferous tubules (asterisk) with immature-appearing Sertoli cells and thickened basement membranes, surrounded by aggregated Leydig cells (arrow). Original magnification: A = 4×, B = 20×.

Edema and interstitial cell hyperplasia were lesions present in the testicular interstitium in DBP-exposed male rats. Microscopically, testicular edema (Figure 4) appeared as increased amounts of eosinophilic fluid within the interstitium. Another lesion of the interstitium was hyperplasia of Leydig cells, both diffuse and focal. Diffuse interstitial cell hyperplasia (Figure 5) was observed as increased numbers of Leydig cells with bridging strands several layers thick between seminiferous tubules, generally involving a large portion of the testis. Focal interstitial cell hyperplasia was seen as a single angular or rounded Leydig cell aggregate between seminiferous tubules with a diameter less than or equal to three seminiferous tubules.

Figure 5

Representative Images of the Testis from Male Rats in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

A) Normal testis and Leydig cell population from a control male rat. B) Diffuse interstitial (Leydig) cell hyperplasia (asterisk) from a 10,000 ppm male rat with seminiferous tubule atrophy. Original magnification: A = 20×, B = 20×.

In the rete testis region, two lesions were observed microscopically. Rete testis granuloma (Figure 6) was seen as expansion of a profile in the rete testis region, subjacent to the capsule at the cranial pole of the testis, by an accumulation of abundant spermatozoa and occasional cholesterol clefts. These spermatozoa and cholesterol clefts were surrounded by a granulomatous inflammatory response, including numerous multinucleated giant cells, which was in turn surrounded by fibrous connective tissue with interspersed macrophages and fibroblasts. Rete testis fibrosis (Figure 7) was observed as a lesion similar in magnitude and location as the rete testis granulomas but consisted of disorganized fibrous connective tissue containing occasional macrophages and fibroblasts and numerous, apparently anastomosing channels, which were lined by cuboidal epithelium. Three sections of a single testis were examined histologically; of the 11 males diagnosed with rete testis fibrosis, 2 also had a rete testis sperm granuloma present in a different section of testis.

Figure 6

Representative Images Depicting Sperm Granuloma in the Rete Testis of a Male Rat in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

A) Sperm granuloma in the rete testis (arrow) in a 10,000 ppm male rat. There is also germinal epithelial atrophy and interstitial edema. B) Higher magnification of the lesion in panel A showing the macrophages at the periphery of the lesion (asterisk) and surrounding the cholesterol clefts (arrow). There are degenerating spermatozoa in the center of the lesion and fibrosis surrounding the lesion. Original magnification: A = 1.4×, B = 20×.

Figure 7

Representative Images Depicting Fibrosis in the Rete Testis of a Male Rat in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

A) Fibrosis in the rete testis in a 10,000 ppm male rat (arrow). There is an increased number of tubular profiles within the lesion. There is also germinal epithelial atrophy and interstitial edema. B) Higher magnification of the lesion in panel A showing the fibrosis separating the tubular profiles. There are several macrophages within the lesion (arrow) suggesting progression of a sperm granuloma. Original magnification: A = 2.5×, B = 10×.

Epididymis: In the epididymis, the incidence of the combination of unilateral and bilateral hypospermia was significantly increased in the 10,000 ppm group compared to the control group (Table 15). The incidence of bilateral hypospermia alone was also significantly increased in the high exposure group compared to the control group (Appendix E). The incidence of unilateral hypospermia alone also was significantly increased in the 10,000 ppm group compared to the control group (Appendix E).

Hypospermia was observed microscopically as reduced density or absence of sperm in the epididymal duct lumen throughout the epididymis. This reduction in sperm and fluid volume was typically accompanied by ductal atrophy, the generalized narrowing of the duct lumen with occasional intraductal epithelial folding, which was considered to be a component of the hypospermia.

Accessory Sex Organs: The incidences of decreased secretory fluid in the prostate gland and seminal vesicle were significantly increased in the 10,000 ppm group compared to the control group (Table 15). These lesions were not graded.

Microscopically, decreased secretory fluid in the prostate gland and seminal vesicle was seen as reduced acinar or vesicular luminal size with reduced luminal secretion. In the seminal vesicle, decreased secretory fluid also was seen as crowding of the intravesicle epithelial folds.

Preputial Gland: The incidences of chronic inflammation (7/49, 10/49, 2/50, 0/49, 0/50), chronic active inflammation (27/49, 8/49, 1/50, 1/49, 2/50), and duct dilation (35/49, 16/49, 3/50, 2/49, 3/50) in the preputial gland were decreased compared to the control group (Appendix E). Duct dilation is a common age-related change. The pathogenesis of the decreased incidences of these lesions in exposed male rats is unclear, but it could be related to hormonal disturbance as preputial gland secretion is influenced by testosterone and pituitary hormones.^146^

Pituitary Gland: In the males, the incidence of hypertrophy of endocrine cells in the pars distalis was significantly increased in only the 10,000 ppm group compared to the control group. The incidence of this lesion in the high exposure group was significant as was the positive trend (Table 16).

Table 16 Incidences of Nonneoplastic Lesions of the Pituitary Gland and Liver in Male and Female Rats in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

| 0 ppm | 300 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Pituitary Gland^a^ | 48 | 50 | 50 | 50 | 50
Pars distalis, hypertrophy^b^ | 0** | 0 | 0 | 0 | 29** (1.0)^c^
Liver | 49 | 50 | 50 | 50 | 50
Hepatocyte, cytoplasmic alteration | 0** | 0 | 0 | 0 | 39** (1.0)
Bile duct, hyperplasia | 15 (1.1) | 14 (1.1) | 14 (1.0) | 9 (1.0) | 9 (1.0)
Female
Pituitary Gland | 50 | 50 | 50 | 50 | 50
Pars distalis, hypertrophy | 1 (1.0) | 0 | 0 | 1 (1.0) | 1 (1.0)
Liver | 50 | 50 | 50 | 50 | 50
Hepatocyte, cytoplasmic alteration | 0** | 0 | 0 | 1 (1.0) | 40** (1.0)
Bile duct, hyperplasia | 5 (1.0) | 11 (1.1) | 6 (1.2) | 6 (1.2) | 12* (1.3)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant (p ≤ 0.05) from the vehicle control group by the Rao-Scott adjusted Poly-3 test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

The hypertrophy (Figure 8) was characterized by increased amounts of pale-staining, eosinophilic cytoplasm and, in many of the cells, by the presence of multiple small vacuoles or a single large vacuole that displaced the nucleus peripherally. The lesion affected individual cells often clustered in the pars distalis.

Figure 8

Representative Images of the Pituitary Gland from Male Rats in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

A) Pituitary gland from a control male. B) Pituitary gland with hypertrophy of the pars distalis endocrine cells in a male exposed to 10,000 ppm DBP. C) Higher magnification of the pars distalis in panel A. D) Higher magnification of the pars distalis in exposed male seen in panel B. Some of the endocrine cells of the pars distalis are enlarged and have a few to one large vacuole with pale eosinophilic cytoplasm. Original magnification: A = 4×, B = 4×, C = 40×, D = 40×.

There was a positive trend in the incidence of hyperplasia (generally focal increases in numbers) of cells of the pars distalis (15/48, 13/50, 13/50, 18/50, 22/50) in males, but there were no statistically significant pairwise increases, nor was there evidence of progression to pars distalis adenomas in either males or females (Appendix E). The lesion of hyperplasia of the pars distalis was not considered related to DBP exposure.

Liver: Significantly increased incidences of cytoplasmic alteration of hepatocytes occurred in the 10,000 ppm groups of both males and females. This lesion was not observed in any other groups (except in one 3,000 ppm female), including the control groups (Table 16). In addition, a slight increase in the incidence of bile duct hyperplasia occurred in the 300 and 10,000 ppm groups of female rats but was significant only in the 10,000 ppm group.

The cytoplasmic alteration (Figure 9) was characterized by increased amounts of cytoplasm with fine eosinophilic granules, mainly in the centrilobular regions in the liver. The bile duct hyperplasia was characterized by increased numbers of bile duct profiles in some of the portal tracts accompanied by increased numbers of inflammatory cells (mainly lymphocytes).

Figure 9

Representative Images of the Liver from Female Rats in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

A) Normal liver from a control female rat. B) Cytoplasmic alteration in a 10,000 ppm female rat liver. The hepatocytes are enlarged by increased amounts of cytoplasm with fine eosinophilic granules, mainly in the centrilobular regions of the liver. Original magnification: A = 40×, B = 40×.

Uterus: The incidence of stromal polyps in the uterus was higher in the 10,000 ppm group compared to the control group (5/50, 6/50, 5/50, 5/50, 10/50) (Appendix E). The positive trend was significant, but the incidences of these lesions were not significantly increased compared to the control group. Moreover, the incidence of uterine stromal polyps was similar to controls (16/90; 18%) in a previous NTP study (cell-phone radiofrequency radiation) using the same rat stock and expanded microscopic evaluation for the uterus.^147^ Because there is no supportive evidence from the companion mouse study that this is an exposure-related response and because this lesion and exposure to DBP have no known association (as opposed to the pancreatic adenomas), the positive trend was not considered related to DBP exposure.

Other Lesions: Several lesions were observed in the male rats with lower incidences in exposed groups compared to the control group (Appendix E). These included keratoacanthomas of the skin, the combined incidences of epithelial neoplasms in the skin (basal or squamous cell carcinoma, carcinoma, basosquamous tumor [malignant or benign], basal cell adenoma, adenoma, papilloma, squamous papilloma, keratoacanthoma, and trichoepithelioma), adenomas of the pars distalis of the pituitary gland, focal hyperplasia of the adrenal cortex, and hyperplasia of the adrenal medulla. The toxicological relevance of the lower incidences of these nonneoplastic lesions is not clear.

## Mice

### Two-year Study

Survival of all exposed groups was similar to that of the control group for both males and females (Table 17; Figure 10). There were no exposure-related clinical observations (Appendix E).

Table 17 Summary of Survival of Male and Female Mice in the Two-year Feed Study of Di-n-butyl Phthalate

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 2 | 2 | 3 | 2
Natural Deaths | 4 | 8 | 11 | 5
Animals Surviving to Study Termination | 44 | 40^a^ | 36 | 43
Percent Probability of Survival at End of Study^b^ | 88.0 | 80.0 | 72.0 | 86.0
Mean Survival (Days)^c^ | 722 | 713 | 698 | 701
Survival Analysis^d^ | p = 0.927N | p = 0.386 | p = 0.070 | p = 0.921
Female
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 1 | 1 | 0 | 0
Natural Deaths | 7 | 7 | 6 | 3
Animals Surviving to Study Termination | 42 | 42 | 44 | 47
Percent Probability of Survival at End of Study | 84.0 | 84.0 | 88.0 | 94.0
Mean Survival (Days) | 713 | 709 | 714 | 722
Survival Analysis | p = 0.126N | p = 1.000 | p = 0.775N | p = 0.198N

^a^ Includes one animal that died naturally during the last week of the study.

^b^ Kaplan-Meier determinations.

^c^ Mean of litter means of all deaths (uncensored, censored, and study termination).

^d^ The result of the Tarone trend test is in the vehicle control group column, and the results of the Cox proportional hazards pairwise comparisons with the vehicle control group are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

Figure 10

Kaplan-Meier Survival Curves for Mice Exposed to Di-n-butyl Phthalate in Feed for Two Years

Exposure-related significant decreases of group mean body weights were observed in the highest exposure group (10,000 ppm) throughout the study in both males and females (Table 18, Table 19; Figure 11). At study termination, group mean body weights for the 10,000 ppm groups were lower than those of the control group by 23.1% for males and by 34.5% for females. Group mean feed consumption over the course of the study was similar across exposed and control groups (Table 20, Table 21). Group mean chemical consumption increased proportionally with exposure concentration and was similar among males and females. Daily chemical consumption by the 1,000, 3,000, and 10,000 ppm groups averaged 111.6, 346.5, and 1,306.0 mg/kg/day, respectively, for males and 105.2, 329.4, and 1,393.3 mg/kg/day, respectively, for females.

Table 18 Summary of Survival and Mean Body Weights of Male Mice in the Two-year Feed Study of Di-n-butyl Phthalate

Study Day^a^ | 0 ppm | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Study Day^a^ | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 20.5 | 50 | 20.5 | 100.4 | 50 | 20.4 | 99.9 | 50 | | 20.6 | 100.6 | 50
8 | 21.7 | 50 | 21.8 | 100.4 | 50 | 21.4 | 98.6 | 50 | | 20.9 | 96.2 | 50
15 | 22.3 | 50 | 22.5 | 100.7 | 50 | 22.1 | 98.7 | 50 | | 21.2 | 94.7 | 50
22 | 22.9 | 50 | 23.2 | 101.3 | 50 | 23.0 | 100.2 | 50 | | 22.0 | 95.7 | 50
29 | 23.8 | 50 | 24.1 | 101.5 | 50 | 23.9 | 100.5 | 50 | | 22.6 | 95.0 | 50
36 | 24.8 | 50 | 24.9 | 100.4 | 50 | 24.5 | 98.6 | 50 | | 23.0 | 92.7 | 50
43 | 25.7 | 50 | 25.9 | 100.8 | 50 | 25.4 | 98.7 | 50 | | 23.7 | 92.5 | 50
50 | 26.3 | 50 | 26.6 | 101.2 | 50 | 26.0 | 98.9 | 50 | | 24.0 | 91.2 | 50
57 | 26.7 | 50 | 27.3 | 102.3 | 50 | 26.4 | 99.0 | 50 | | 24.4 | 91.3 | 49
64 | 27.0 | 50 | 28.0 | 103.7 | 50 | 27.0 | 100.0 | 50 | | 25.0 | 92.7 | 49
71 | 27.3 | 50 | 28.4 | 104.0 | 50 | 26.9 | 98.6 | 50 | | 25.0 | 91.6 | 49
78 | 28.5 | 50 | 29.0 | 101.7 | 50 | 28.3 | 99.2 | 50 | | 25.7 | 90.3 | 49
85 | 29.7 | 50 | 30.4 | 102.4 | 50 | 29.3 | 98.8 | 50 | | 26.4 | 89.0 | 49
92 | 30.4 | 50 | 30.9 | 101.7 | 50 | 29.9 | 98.2 | 50 | | 26.0 | 85.5 | 49
120 | 32.3 | 50 | 33.8 | 104.5 | 50 | 31.9 | 98.6 | 50 | | 27.9 | 86.4 | 49
148 | 35.2 | 50 | 37.1 | 105.5 | 50 | 34.7 | 98.6 | 50 | | 29.1 | 82.8 | 49
176 | 38.5 | 50 | 40.1 | 104.3 | 50 | 37.5 | 97.5 | 50 | | 30.6 | 79.5 | 49
204 | 39.4 | 50 | 41.7 | 105.8 | 50 | 38.9 | 98.6 | 50 | | 31.9 | 80.8 | 49
232 | 41.8 | 50 | 43.5 | 104.1 | 50 | 40.8 | 97.6 | 50 | | 32.7 | 78.4 | 49
260 | 43.3 | 50 | 44.6 | 102.9 | 50 | 42.6 | 98.3 | 49 | | 33.5 | 77.4 | 49
288 | 44.3 | 50 | 45.2 | 102.0 | 50 | 43.7 | 98.7 | 49 | | 34.5 | 77.9 | 49
316 | 45.2 | 50 | 46.4 | 102.6 | 49 | 44.1 | 97.5 | 49 | | 34.8 | 76.9 | 49
344 | 46.2 | 50 | 47.2 | 102.2 | 49 | 45.1 | 97.7 | 49 | | 35.6 | 77.0 | 49
372 | 46.3 | 50 | 47.3 | 102.1 | 49 | 45.5 | 98.1 | 49 | | 36.2 | 78.0 | 49
400 | 46.1 | 50 | 47.6 | 103.3 | 49 | 45.5 | 98.8 | 49 | | 35.9 | 77.9 | 48
428 | 46.7 | 50 | 47.7 | 102.1 | 49 | 46.4 | 99.4 | 49 | | 36.8 | 78.8 | 48
456 | 47.6 | 50 | 48.6 | 102.1 | 49 | 46.0 | 96.6 | 49 | | 37.5 | 78.7 | 48
484 | 47.9 | 50 | 49.3 | 103.1 | 49 | 47.2 | 98.7 | 49 | | 37.8 | 79.0 | 48
512 | 48.3 | 49 | 49.7 | 102.9 | 49 | 47.1 | 97.6 | 48 | | 37.6 | 77.8 | 48
540 | 48.8 | 49 | 50.5 | 103.5 | 49 | 47.3 | 96.9 | 47 | | 38.2 | 78.4 | 48
568 | 48.7 | 49 | 49.5 | 101.6 | 49 | 46.9 | 96.3 | 46 | | 38.1 | 78.2 | 48
596 | 48.2 | 49 | 48.9 | 101.5 | 49 | 46.3 | 96.1 | 46 | | 37.7 | 78.2 | 48
624 | 48.9 | 49 | 50.0 | 102.2 | 48 | 47.1 | 96.4 | 45 | | 38.1 | 77.9 | 45
652 | 48.7 | 49 | 48.8 | 100.2 | 47 | 45.6 | 93.6 | 44 | | 37.4 | 76.9 | 45
680 | 47.5 | 48 | 47.9 | 100.8 | 45 | 45.9 | 96.7 | 41 | | 37.4 | 78.8 | 44
708 | 47.3 | 47 | 47.9 | 101.1 | 41 | 45.9 | 97.0 | 39 | | 37.0 | 78.1 | 43
EOS | 47.7 | 44 | 47.6 | 99.8 | 39 | 46.9 | 98.4 | 36 | | 36.7 | 76.9 | 43

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Table 19 Summary of Survival and Mean Body Weights of Female Mice in the Two-year Feed Study of Di-n-butyl Phthalate

Study Day^a^ | Control | | 1,000 ppm | | | 3,000 ppm | | | 10,000 ppm
Study Day^a^ | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 16.5 | 50 | 16.7 | 101.1 | 50 | 16.8 | 101.6 | 50 | 16.6 | 100.1 | 50
8 | 17.5 | 50 | 17.5 | 100.4 | 50 | 17.4 | 99.4 | 50 | 16.7 | 95.8 | 50
15 | 18.4 | 50 | 18.5 | 100.4 | 50 | 18.4 | 99.6 | 50 | 17.3 | 94.1 | 50
22 | 19.4 | 50 | 19.3 | 99.4 | 50 | 19.4 | 99.8 | 50 | 17.6 | 90.6 | 50
29 | 20.1 | 50 | 20.3 | 101.1 | 50 | 20.1 | 99.7 | 50 | 18.3 | 90.7 | 50
36 | 21.1 | 50 | 21.1 | 100.1 | 50 | 20.8 | 98.7 | 50 | 18.8 | 89.2 | 50
43 | 21.2 | 50 | 21.2 | 99.7 | 50 | 21.3 | 100.2 | 50 | 19.2 | 90.3 | 50
50 | 22.0 | 50 | 21.8 | 99.5 | 50 | 21.7 | 99.0 | 50 | 19.3 | 87.8 | 50
57 | 22.2 | 50 | 22.3 | 100.6 | 50 | 21.8 | 98.1 | 50 | 19.6 | 88.2 | 50
64 | 23.5 | 50 | 23.1 | 98.5 | 50 | 22.9 | 97.4 | 50 | 20.3 | 86.6 | 50
71 | 23.8 | 50 | 23.8 | 99.8 | 50 | 23.1 | 96.9 | 50 | 20.8 | 87.5 | 50
78 | 24.5 | 50 | 24.4 | 99.4 | 50 | 23.7 | 96.7 | 50 | 21.4 | 87.4 | 50
85 | 24.4 | 50 | 24.7 | 101.3 | 50 | 24.3 | 99.6 | 50 | 21.3 | 87.4 | 50
92 | 25.2 | 50 | 25.0 | 99.5 | 50 | 24.7 | 98.1 | 50 | 21.9 | 86.9 | 50
120 | 27.5 | 50 | 27.2 | 98.7 | 50 | 26.4 | 95.7 | 50 | 22.9 | 83.0 | 50
148 | 29.5 | 50 | 30.0 | 101.4 | 50 | 28.7 | 97.1 | 50 | 23.5 | 79.5 | 50
176 | 32.6 | 50 | 33.4 | 102.5 | 50 | 31.7 | 97.3 | 50 | 24.4 | 74.7 | 50
204 | 34.0 | 50 | 34.7 | 102.0 | 50 | 33.3 | 97.9 | 50 | 25.1 | 73.8 | 50
232 | 36.2 | 50 | 37.2 | 102.9 | 50 | 35.1 | 97.1 | 50 | 26.2 | 72.3 | 50
260 | 38.6 | 50 | 38.7 | 100.5 | 50 | 35.7 | 92.6 | 50 | 26.9 | 69.7 | 50
288 | 39.4 | 50 | 40.3 | 102.2 | 50 | 37.8 | 95.8 | 50 | 27.6 | 70.1 | 50
316 | 41.7 | 50 | 42.2 | 101.1 | 50 | 39.8 | 95.4 | 50 | 28.3 | 67.8 | 50
344 | 42.7 | 50 | 43.3 | 101.5 | 50 | 41.2 | 96.6 | 50 | 28.8 | 67.6 | 50
372 | 44.6 | 50 | 45.6 | 102.4 | 50 | 43.2 | 96.9 | 50 | 30.5 | 68.4 | 50
400 | 45.5 | 50 | 46.3 | 101.7 | 50 | 44.1 | 96.8 | 50 | 30.3 | 66.7 | 50
428 | 46.5 | 50 | 47.5 | 102.3 | 50 | 44.8 | 96.5 | 50 | 31.1 | 67.0 | 50
456 | 48.2 | 50 | 49.5 | 102.7 | 50 | 46.1 | 95.7 | 49 | 31.9 | 66.2 | 50
484 | 48.1 | 50 | 51.0 | 105.9 | 50 | 46.7 | 97.0 | 49 | 32.7 | 67.9 | 50
512 | 50.4 | 50 | 52.1 | 103.4 | 49 | 48.0 | 95.3 | 49 | 32.1 | 63.8 | 50
540 | 50.9 | 49 | 51.6 | 101.4 | 48 | 48.1 | 94.5 | 49 | 31.9 | 62.6 | 50
568 | 49.6 | 48 | 50.9 | 102.6 | 47 | 44.3 | 89.3 | 49 | 31.6 | 63.8 | 49
596 | 49.3 | 48 | 52.0 | 105.5 | 45 | 45.3 | 91.8 | 46 | 32.4 | 65.7 | 49
624 | 51.0 | 46 | 52.8 | 103.6 | 45 | 48.1 | 94.2 | 46 | 32.6 | 63.9 | 48
652 | 51.5 | 45 | 53.4 | 103.6 | 45 | 48.7 | 94.6 | 46 | 33.8 | 65.7 | 48
680 | 51.4 | 44 | 51.1 | 99.5 | 44 | 47.9 | 93.2 | 46 | 33.4 | 64.9 | 48
708 | 51.4 | 43 | 50.9 | 98.9 | 43 | 48.2 | 93.7 | 45 | 33.7 | 65.5 | 47
EOS | 51.7 | 42 | 50.7 | 98.0 | 42 | 48.6 | 94.0 | 44 | 33.9 | 65.5 | 47

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 11

Growth Curves for Mice Exposed to Di-n-butyl Phthalate in Feed for Two Years

Table 20 Summary of Feed and Di-n-butyl Phthalate Consumption of Male Mice in the Two-year Feed Study

Week | 0 ppm | 1,000 ppm | | 3,000 ppm | | 10,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
2 | 3.6 | 3.5 | 160.7 | 3.7 | 518.9 | 3.9 | 1,869.2
13 | 4.3 | 4.4 | 144.8 | 4.3 | 440.0 | 4.3 | 1,629.2
54 | 4.5 | 4.4 | 93.0 | 4.3 | 283.8 | 4.1 | 1,134.1
102 | 4.9 | 5.1 | 106.5 | 4.7 | 307.2 | 4.4 | 1,189.9

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of di-n-butyl phthalate consumed per kilogram body weight per day.

Table 21 Summary of Feed and Di-n-butyl Phthalate Consumption of Female Mice in the Two-year Feed Study

Week | 0 ppm | 1,000 ppm | | 3,000 ppm | | 10,000 ppm
Week | Feed (g/day)^a^ | Feed (g/day) | Dose (mg/kg/day)^b^ | Feed (g/day) | Dose (mg/kg/day) | Feed (g/day) | Dose (mg/kg/day)
1 | 3.1 | 3.2 | 191.3 | 3.4 | 606.6 | 4.4 | 2,656.7
13 | 3.4 | 3.5 | 141.8 | 3.6 | 445.1 | 3.5 | 1,643.8
54 | 4.2 | 4.2 | 92.1 | 3.9 | 271.1 | 3.9 | 1,278.8
102 | 4.7 | 4.7 | 92.4 | 4.8 | 298.9 | 4.6 | 1,366.4

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of di-n-butyl phthalate consumed per kilogram body weight per day.

#### Pathology

This section describes statistically significant or biologically noteworthy changes in the incidences of nonneoplastic lesions in the testis, epididymis, coagulating gland, seminal vesicle, liver, and kidney of mice. Summaries of the incidences of neoplasms and nonneoplastic lesions, individual animal tumor diagnoses, statistical analysis of primary neoplasms that occurred with an incidence of at least 5% in at least one animal group, and historical incidences for the biologically significant neoplasms mentioned in this section are presented as supplemental data in Appendix E. No neoplasms or gross pathology lesions in male or female mice were considered to be related to DBP exposure.

Testis: In the testis, the incidences of the combination of unilateral and bilateral degeneration of the germinal epithelium were higher in all exposed groups compared to the control group, but the increases were significant only in the 1,000 and 10,000 ppm groups (Table 22). The incidence of bilateral (only) germinal epithelial degeneration was also higher in all exposed groups compared to the control group but was statistically significant only in the 10,000 ppm group (Appendix E).

Table 22 Incidences of Nonneoplastic Lesions of the Testis, Epididymis, Coagulating Gland, and Seminal Vesicle in Male Mice in the Two-year Feed Study of Di-n-butyl Phthalate

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Testis^a^ | 50 | 50 | 50 | 50
Germinal epithelium, degeneration (includes bilateral)^b^ | 6 (2.2)^c^ | 15* (1.8) | 9 (2.0) | 15* (2.2)
Epididymis | 50 | 50 | 50 | 50
Duct, exfoliated germ cell (includes bilateral) | 6* (1.3) | 10 (1.3) | 5 (2.0) | 13* (1.6)
Hypospermia (includes bilateral) | 1 (3.0) | 4 (3.5) | 3 (3.3) | 3 (3.0)
Duct, atrophy, bilateral^d^ | 0 | 1 (3.0) | 3 (3.0) | 1 (3.0)
Coagulating Gland^e^ | 0 | 1 | 4 | 1
Atrophy, bilateral^d^ | 0 | 1 (3.0) | 3 (3.0) | 1 (3.0)
Seminal Vesicle | 50 | 50 | 50 | 50
Atrophy, bilateral^d^ | 1 (3.0) | 1 (3.0) | 3 (3.0) | 1 (3.0)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Poly-3 test.

^a^ Number of animals with tissue examined microscopically.

^b^ Incidence reported is the combination of unilateral and bilateral lesions. Severity grade for these types of lesions = sum of unilateral and bilateral severity scores/number of unilateral and bilateral incidences.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

^d^ This lesion was observed only as a bilateral lesion.

^e^ Only tissues from animals with gross lesions of the indicated organ were collected at necropsy for histopathological evaluation.

Microscopically, degeneration of the germinal epithelium (Figure 12) consisted variably of scattered loss of germ cells (round and/or elongating spermatids), seminiferous tubules with vacuoles (variable in size and number), degenerating germ cells with eosinophilic cytoplasm, disorganization of germinal epithelium, occasional sloughing of germ cells, and occasional multinucleated germ cells.

Figure 12

Representative Images Depicting Degeneration of the Germinal Epithelium of the Testis in a Male Mouse in the Two-year Feed Study of Di-n-butyl Phthalate

A) Degeneration of the germinal epithelium of the testis from a 10,000 ppm male mouse. The germinal epithelium is vacuolated (arrow). B) Exfoliated germ cells in the epididymal duct lumen from the same mouse in panel A. Exfoliated germ cells (arrow) and debris are present among the spermatozoa. Original magnification: A = 10×, B = 20×.

Epididymis: In the epididymal duct, the combined incidence of unilateral and bilateral exfoliated germ cells was higher in the 1,000 and 10,000 ppm groups compared to the control group, but the incidence was statistically significant only in the 10,000 ppm group (Table 22). The incidence of bilateral (only) exfoliated germ cells was higher in all exposed groups compared to the control group, but none of the increases were statistically significant (Appendix E). The incidences of hypospermia and duct atrophy in the epididymis were also higher in all exposed groups compared to the control group (Table 22). Although these changes were small and not statistically significant and although severity did not increase with increasing exposure concentration, they were considered to be related to DBP exposure.

The microscopic lesion of exfoliated germ cells in the epididymis (Figure 12) was characterized by the presence of degenerating germ cells and cell debris in the epididymal lumen. Exfoliated germ cells were diagnosed when numbers were increased relative to the low concentration occurring in the control animals. When germinal epithelial damage to the testes occurs, it is often accompanied by the presence of exfoliated germ cells in the epididymides. In most mice diagnosed with testicular germinal epithelium degeneration, corroborating lesions of increased exfoliating germ cells and/or low incidences of hypospermia in the epididymis that reinforced a testicular effect were seen. Hypospermia was characterized microscopically by reduced sperm content throughout the epididymis and often was accompanied by reduced size of the duct lumen and exfoliated germ cells. Hypospermia coincided with diagnoses of germinal epithelium degeneration in the testis in all cases. In fewer cases, hypospermia also was diagnosed with seminal vesicle and/or coagulating gland atrophy or epididymal duct atrophy. Epididymis duct atrophy appeared as a diffuse collapse of the duct lumen, generally empty duct profiles, decreased epithelial height, and increased and prominent mesenchymal stroma. The animals with epididymal atrophy also had concomitant testicular degeneration and interstitial cell atrophy, hypospermia, and seminal vesicle and coagulating gland atrophy.

Accessory Sex Organs: The incidence of bilateral atrophy of the coagulating gland was slightly higher in the exposed groups compared to the control group, and the incidence of bilateral atrophy of the seminal vesicle was slightly higher in the 3,000 ppm group compared to the control group (Table 22). Although these changes were small and not statistically significant and although severity did not increase with increasing exposure concentration, they were considered to be related to DBP exposure.

Microscopically, atrophy of the seminal vesicle or coagulating gland was characterized by reduced lumina and crowding of intravesicular epithelial folds, reduced or absent luminal secretory material, and increased stroma. The atrophy was considered of moderate severity for both tissues and was always bilateral. These lesions are commonly seen with chronic androgen depletion.^148^

Liver: Cytoplasmic alteration of hepatocytes was observed only in the 10,000 ppm males and females, and the incidences of these lesions were significantly increased compared to the control groups (Table 23). In all cases, the severity of this lesion was considered minimal. The cytoplasmic alteration was characterized by increased amounts of cytoplasm with fine eosinophilic granules, mainly in the centrilobular regions of the liver. In the male mice, the incidences of multinucleated hepatocytes (Figure 13) were significantly increased in all exposed groups compared to the control group (Table 23). Only the incidences in the 3,000 and 10,000 ppm groups were statistically significant. Multinucleated hepatocytes with up to three or, rarely, four nuclei can be seen as a background lesion in mice, but the multinucleated hepatocytes considered related to DBP exposure were much larger and contained up to 20 nuclei.

Table 23 Incidences of Nonneoplastic Lesions of the Liver and Kidney in Male and Female Mice in the Two-year Feed Study of Di-n-butyl Phthalate

| 0 ppm | 1,000 ppm | 3,000 ppm | 10,000 ppm
Male
Liver^a^ | 50 | 50 | 50 | 50
Hepatocyte, cytoplasmic alteration^b^ | 0** | 0 | 0 | 36** (1.0)^c^
Hepatocyte, multinucleated | 8** (1.0) | 11 (1.0) | 25** (1.0) | 42** (1.0)
Female
Liver | 50 | 50 | 49 | 49
Hepatocyte, cytoplasmic alteration | 0** | 0 | 0 | 48** (1.0)
Kidney | 50 | 50 | 49 | 49
Renal tubule, hyperplasia | 0** | 0 | 0 | 47** (1.0)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01 by the Poly-3 test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Figure 13

Representative Image Depicting Multinucleated Hepatocytes in the Liver of a Male Mouse in the Two-year Feed Study of Di-n-butyl Phthalate

Multinucleated hepatocytes in the liver from a 10,000 ppm male mouse (arrows). Original magnification: 20×.

Kidney: In the female mice, hyperplasia of the renal tubule epithelium was observed, and the incidences were significantly increased in the 10,000 ppm group; this lesion was not seen in any other group, including the control group (Table 23). In all cases, the severity was considered minimal. This lesion is unique and is distinct from the tubular epithelial hyperplasia found in association with chronic progressive nephropathy. It is characterized by segmental hyperplasia of the epithelium in tubules at the corticomedullary junction (Figure 14). Affected renal tubules often were dilated and lined by tightly crowded epithelial cells. The cells also were slightly enlarged with increased height and cytoplasmic volume. Some cells also had slightly enlarged nuclei, and some were multinucleated.

Figure 14

Representative Image Depicting Renal Tubule Hyperplasia in the Kidney in a Female Mouse in the Two-year Feed Study of Di-n-butyl Phthalate

Renal tubule hyperplasia in the kidney of a 10,000 ppm female mouse. There are crowded, basophilic epithelial cells lining portions of the dilated renal tubules (arrows). Original magnification: 20×.