# Materials and Methods

## Procurement and Characterization of Di-n-butyl Phthalate

Di-n-butyl phthalate (DBP) was obtained from Sigma-Aldrich (St. Louis, MO) in a single lot (lot MKBB8432) and was used in the perinatal and 2-year studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at RTI International (Research Triangle Park, NC) (Appendix A). Reports on analyses performed in support of the DBP studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lot MKBB8432 of the chemical, a clear liquid, was identified as DBP by infrared (IR), ^1^H and ^13^C nuclear magnetic resonance (NMR) spectroscopy, and gas chromatography (GC) with mass spectrometry (MS) detection. The IR spectrum was in good agreement with a reference spectrum, and the structure was consistent with DBP. Both ^1^H and ^13^C NMR spectra were consistent with reference and predicted spectra. The GC/MS spectrum correlated well with the structure of DBP. The boiling point, elemental analysis, and precise mass determination of lot MKBB8432 matched those of DBP.

Karl Fischer titration was used to determine the water content of lot MKBB8432, which was 0.204%. Ultra-performance liquid chromatography (UPLC) with photodiode array detection (PDA) and GC with flame ionization detection (FID) were used to determine a purity of 99.9%. The UPLC/PDA analysis identified one minor impurity peak with <0.1% of the total response. The overall purity of lot MKBB8432 was determined to be >99%.

Accelerated stability studies, performed on an additional lot of DBP (lot 91997PJ) obtained from Sigma-Aldrich (St. Louis, MO), confirmed that it was stable for at least 2 weeks when stored in sealed glass vials at temperatures from 5°C to 60°C. The bulk chemical of lot MKBB8432 was homogenized by mixing for 15 minutes and transferred to 1-gallon amber storage bottles, which were stored at room temperature (approximately 25°C). Periodic reanalysis of the bulk chemical was performed during the perinatal and 2-year studies by the study laboratory using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection, and no degradation was detected.

## Preparation and Analysis of Dose Formulations

Dose formulations were prepared approximately monthly by mixing DBP with NIH-07 or NTP-2000 feed (Table A-2). The rat perinatal and 2-year study used dose formulations of 300, 1,000, 3,000, and 10,000 ppm, whereas the mouse 2-year study used dose formulations of 1,000, 3,000, and 10,000 ppm. Formulations were stored in sealed, plastic bag-lined containers at room temperature (approximately 25°C) for up to 42 days. The plastic bags used by the study laboratory in the preparation and storage of blank and dosed feed were determined to have no DBP above the limit of detection of the assay (1.47 ppm).

Homogeneity studies of the dose formulations in a 72 kg NIH-07 feed batch (300 and 1,000 ppm), a 92 kg NTP-2000 feed batch (300 ppm), and a 60 kg NTP-2000 feed batch (1,000 and 10,000 ppm) were performed prior to animal studies by the study laboratory with HPLC/UV (Table A-1). Additional homogeneity studies of the 300 ppm dose formulation in a 60 kg NTP-2000 batch size and of the 10,000 ppm dose formulation in a 72 kg NTP-2000 batch size were performed during the 2-year studies by the study laboratory. Formulations were determined to be homogenous and stable for 42 days at room temperature.

Periodic analyses of the dose formulations of DBP were conducted by the study laboratory using HPLC/UV to determine purity (Table A-3, Table A-4). All preadministration dose formulations were within 10% of the target concentrations. In the perinatal and 2-year rat studies, two samples collected from the residual food in the feeders and one sample from the storage barrel were below 90% of the target concentrations (% relative error, RE: −10.0% to −13.2%). In the 2-year mouse study, three samples collected from the residual food in the feeders and one sample from the storage barrel were below 90% of the target concentrations (%RE: −11.1% to −13.4%). All other postadministration values were within 10% of the target concentrations.

## Animal Source

Time-mated (F_0_) female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN). Male and female B6C3F1/N mice were obtained from Taconic Biosciences, Inc. (Germantown, NY).

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle (Columbus, OH) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health and National Toxicology Program (NTP) animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-year Studies

### Exposure Concentration Selection Rationale

Studies summarized in NTP Toxicity Report 30^51^ established 10,000 ppm as the highest safe exposure concentration of DBP that could be used in rat and mouse reproductive studies; at 20,000 ppm, pups died and the body weight of postweaning and adult rodents was reduced by more than 10% relative to the control groups. At 10,000 ppm, a significant increase in the incidence of nonneoplastic lesions of the liver and testis and alterations in organ weights were observed.

Additionally, these exposures are consistent with another prenatal exposure study showing adverse effects and limited dose-related mortality of rats 18 months of age in the 500 mg DBP/kg body weight/day (mg/kg/day) dose group but not in rats in the 100 mg/kg/day dose group.^65^ Estimated compound intake documented in NTP Toxicity Report 30 suggests that 100 and 500 mg/kg/day are about equivalent to <2,500 ppm and 5,000–10,000 ppm in feed consumption, respectively, for Fischer 344 rats.^51^ For these reasons, 10,000 ppm was chosen as the highest exposure concentration for both rats and mice for the 2-year bioassay.

### Study Design for Rats

F_0_ female rats were 11 to 14 weeks old upon receipt. Evidence of mating is defined as gestation day (GD) 1; F_0_ females were received on GD 2 and held for 4 days. F_0_ females were randomly assigned to one of five exposure groups on GD 5. Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Cedar Knolls, NJ).

F_0_ females were quarantined for 11 days after receipt. Ten nonmated females received with the time-mated females were designated for disease monitoring 11 days after arrival; samples were collected for serological analyses, and the rats were euthanized, necropsied, and examined for the presence of disease or parasites. The health of the F_1_ rats was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). Pinworms (Syphacia spp.) were diagnosed in sentinel animals during routine health monitoring evaluations. Infected animals did not display clinical signs, and no pathological lesions were noted in relation to the presence of the pinworms. As a follow-up to this finding, NTP, in coordination with the testing laboratory, developed and implemented a successful plan of pinworm containment and eradication. NTP required the testing laboratories to monitor animals actively to ensure the continued exclusion of pinworms from all subsequent studies. All other test results were negative.

Beginning on GD 6, groups of 45 (0, 300, 1,000, and 3,000 ppm) or 47 (10,000 ppm; includes two extra rats received in the animal order) F_0_ time-mated female rats were fed diets containing 0, 300, 1,000, 3,000, or 10,000 ppm DBP, respectively, throughout gestation and lactation. Groups of 50 F_1_ rats per sex per exposure concentration continued in the study after weaning and were fed diets containing the same respective DBP concentrations for 2 years.

F_0_ female rats were housed individually during gestation and with their respective litters during lactation. Dosed feed and water were available ad libitum. F_0_ female body weights were recorded on GDs 5, 6, 9, 12, 15, 18, and 21 and on lactation days (LDs) 1, 4, 7, 10, 14, and 21. During gestation, feed consumption was continuously measured over 3-day intervals from GD 6 through GD 21 (GDs 6–9, 9–12, 12–15, 15–18, and 18–21). The day of parturition was considered LD 0 or postnatal day (PND) 0. On apparent GD 27, all time-mated female rats that failed to deliver were euthanized, and the uteri were examined and stained for evidence of implantation. Total litter weight and litter weights by sex were collected on PND 1. Individual F_1_ pup weights were recorded on PNDs 4, 7, 14, and 21. Clinical observations and survival were evaluated throughout lactation. During lactation, feed consumption was measured over 3-day intervals from PND 1 through PND 21 (PNDs 1–4, 4–7, 7–10, 10–14, 14–17, and 17–21).

Select dams and their litters were removed on GD 18 and PND 4 to quantify mono-n-butyl phthalate (MBP) concentrations. On GD 18, blood was collected from the retroorbital sinus of randomly selected dams (n = 5 per exposure group). Blood samples were collected into tubes containing tripotassium ethylene diamine tetraacetic acid (K_3_ EDTA) and centrifuged, and the plasma was harvested. Amniotic fluid was collected and pooled by dam. Each dam’s fetuses were collected, pooled by litter, and flash frozen in liquid nitrogen. On PND 4, randomly selected dams (n = 5 per exposure group) and their pups not selected to continue in the study were used for biological sampling. Plasma was collected from dams in the same manner as on GD 18. Up to four pups were collected from each dam (two per sex when possible) and flash frozen in liquid nitrogen. All samples were stored frozen at approximately −20°C before shipment to RTI International (Research Triangle Park, NC) for analysis. All samples were analyzed using a previously validated method.^115^

F_1_ litters were standardized on PND 4 to eight pups per litter, with at least two pups of each sex and a preference for four males and four females each. Litters that did not meet the minimum of eight pups (or had fewer than two pups of either sex) were removed from the study. For continuation of exposure after weaning, two males and two females per litter were randomly selected from 28 (0 ppm), 25 (300 ppm), 27 (1,000 and 10,000 ppm), and 30 (3,000 ppm) litters. Before weaning, on the day the last litter reached PND 19, 25 litters per exposure group were randomly selected, and pups (generally two/sex/litter) were randomly assigned to the 2-year study. On the day the last litter reached PND 21, dams were removed from the cages, and the pups were weaned. Weaning marked the beginning of the 2-year study.

After weaning, F_1_ rats were housed up to two (males) or four (females) per cage. Water and dosed feed were available ad libitum. Feed consumption was measured weekly for the first 3 months, then for one 7-day period every 4 weeks thereafter, and at study termination. Cages were changed at least once weekly through PND 4, then changed at least twice weekly. Racks were changed and rotated at least every 2 weeks. Further details of animal maintenance are given in Table 1.

Table 1 Experimental Design and Materials and Methods in the Perinatal and Two-year Feed Studies of Di-n-butyl Phthalate

Rats | Mice
Study Laboratory
Battelle (Columbus, OH) | Same as rat study
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | B6C3F1/N
Animal Source
Envigo (formerly Harlan Laboratories, Inc., Indianapolis, IN) | Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Studies
F_0_ females: 11 days | 11 (females) or 12 (males) days
Average Age When Studies Began
F_0_ females: 12–15 weeks | 5–6 weeks
Date of First Exposure
F_0_ females: July 23, 2010 | August 16 (females) or 17 (males), 2010
F_1_: August 30, 2010 (males and females)
Duration of Exposure
F_0_ females: GD 6 to LD 21 | 2 years
F_1_: Perinatal plus 2 years
Date of Last Exposure
F_0_ females: August 30, 2010 | August 15 (females) or 17 (males), 2012
F_1_: August 29 (males) or 31 (females), 2012
Necropsy Dates
F_1_: August 27–29 (males) or 29–31 (females), 2012 | August 13–15 (females) or 15–17 (males), 2012
Average Age at Necropsy
F_1_: 2 years | 2 years
Size of Study Groups
F_0_ females: 45 (0, 300, 1,000, 3,000 ppm) or 47 (10,000 ppm) | 50/sex
F_1_ (2-year study): 50/sex
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights | Same as rat study
Animals per Cage
F_0_ females: 1 (with litter) | Males: 1
F_1_: 2 (males) or 4 (females) | Females: Up to 4
Method of Animal Identification
F_0_ female: Cage card and tail marking with permanent pen | Cage card and tail tattoo
F_1_ (pups): Limb tattoo
F_1_ (2-year study): Cage card and tail tattoo
Diet
Irradiated NIH-07 meal feed (perinatal phase) or irradiated NTP-2000 meal feed (2-year study) (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed twice weekly | Irradiated NTP-2000 meal feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed twice weekly
Water
Tap water (Columbus, OH municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as rat study
Cages
Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly through PND 4, then twice weekly, rotated every 2 weeks | Solid polycarbonate (Lab Products, Inc., Seaford, DE), changed weekly (males) or twice weekly (females), rotated every 2 weeks
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed with cage changes | Same as rat study
Rack Filters
Spun-bonded polyester (Snow Filtration Company, Cincinnati, OH or National Filter Media Corporation, Olive Branch, MS), changed every 2 weeks | Spun-bonded polyester (Snow Filtration Company, Cincinnati, OH), changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks | Same as rat study
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Same as rat study
Exposure Concentrations
0, 300, 1,000, 3,000, or 10,000 ppm in feed | 0, 1,000, 3,000, or 10,000 ppm in feed
Type and Frequency of Observation
F_0_ females: Observed twice daily. Weighed on GDs 5, 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 10, 14, and 21. Feed consumption was measured continuously over 3-day intervals from GD 6 to LD 21. | Observed twice daily. Weighed initially, weekly for the first 13 weeks, every 4 weeks thereafter, and at study termination. Clinical observations were recorded every 4 weeks beginning at week 6 and at study termination. Feed consumption was measured weekly for the first 3 months and then at 4-week intervals thereafter.
F_1_: Observed twice daily. Litter data (litter count by sex, litter weights by sex, and litter observations) were recorded on PND 1. Pups per litter were recorded on PNDs 2 and 3. Pups were weighed on PNDs 4, 7, 14, and 21, weekly for the first 13 weeks, every 4 weeks thereafter, and at study termination. Clinical observations were recorded every 4 weeks beginning on day 29 and at study termination. Feed consumption was recorded weekly for 3 months, and then at 4-week intervals thereafter.
Method of Euthanasia
Carbon dioxide | Same as rat study
Necropsy
Necropsies were performed on all F_1_ rats. | Necropsies were performed on all mice.
Histopathology
Complete histopathology was performed on all F_1_ rats. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, brain, clitoral gland, esophagus, eyes, femur, Harderian gland, heart and aorta, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), kidneys, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus. | Complete histopathology was performed on all mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, brain, clitoral gland, esophagus, eyes, femur, gallbladder, Harderian gland, heart and aorta, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), kidneys, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, spinal cord, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, uterus.
Internal Dose Assessment
Maternal plasma, amniotic fluid (pooled by litter), and fetuses (pooled by litter) (n = 5) were collected at GD 18, and maternal plasma (n = 5) and whole pup (n = 2/sex) were collected at PND 4 to determine mono-n-butyl phthalate concentration to estimate gestational and lactational transfer, respectively. | None

PND = postnatal day; GD = gestation day. LD = lactation day.

Two diets were used in the rat studies: (1) NIH-07 during the perinatal phase and (2) NTP-2000 during the postnatal phase. NIH-07 is a higher protein diet that supports reproduction and lactation in rodents, whereas NTP-2000 is a lower protein diet that decreases the incidence of chronic nephropathy in adult rats. Information on feed composition and contaminants for both diets is provided in Appendix B.

### Study Design for Mice

Male and female B6C3F1/N mice were approximately 3 to 4 weeks old upon receipt and were quarantined for 11 (females) or 12 (males) days before study start. Mice were randomly assigned to one of four exposure groups (n = 50 mice/sex/group). Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Cedar Knolls, NJ). Mice were fed diets containing 0, 1,000, 3,000, or 10,000 ppm DBP for 2 years.

Five male and five female mice were randomly selected for parasite evaluation and gross observation of disease. The health of the mice was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Mice were housed individually (males) or up to four (females) per cage. Water and dosed feed were available ad libitum. Feed consumption was measured weekly for the first 3 months, then for one 7-day period every 4 weeks thereafter. Cages were changed at least once weekly (males) or twice weekly (females) and rotated every 2 weeks. Racks were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is given in Appendix B.

### Clinical Examinations and Pathology

In the 2-year studies of rats and mice, animals were observed twice daily for signs of morbidity and moribundity and were weighed before dosed feed exposure on day 1, weekly for the next 3 months, every 4 weeks thereafter, and at study termination. Clinical observations were recorded every 4 weeks beginning on day 29 (rats) or day 1 (mice) and at study termination.

For determination of internal dose in rats, plasma, amniotic fluid, and fetal tissue samples were analyzed using a previously validated method.^115^

Complete necropsies and microscopic examinations were performed on all F_1_ rats and all mice at the end of the 2-year study. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin except for eyes, which were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides, which were first fixed in modified Davidson’s solution. Tissues were processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 μm, and stained with hematoxylin and eosin (H&E) for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. Three transverse sections of each testis were taken: approximately one-third of the way down from the cranial pole containing the rete testis, at the midpoint, and approximately one-third of the way up from the caudal pole. Two transverse sections of the uterus, one from approximately the midpoint of each horn, were collected. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by a quality assessment (QA) pathologist at a pathology laboratory independent of the study laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all tumors and all potential target organs, which included the liver of rats and mice; the testis, epididymis, prostate gland, seminal vesicles, and pituitary gland of male rats and male mice; the kidney of male and female mice; the exocrine pancreas of rats; and the Harderian gland of female rats.

The QA report and the reviewed slides were submitted to the NTP Pathology Working Group (PWG) coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the QA pathologist and other pathologists experienced in rodent toxicological pathology. This group examined the tissues without any knowledge of exposure groups. When the PWG consensus differed from that of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^116^ and Boorman et al.^117^ For subsequent analyses of the pathology data, the decision to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of McConnell et al.^118^

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^119^ and is presented graphically. Animals surviving to the end of the observation period are treated as censored observations, as are animals dying from unnatural causes within the observation period. Animals dying from natural causes are included in analyses and are treated as uncensored observations. For the 2-year mouse study, exposure concentration-related trends are identified with Tarone’s life table test,^120^ and pairwise exposure concentration-related effects are assessed using Cox’s method.^121^ For the rat perinatal study, exposure concentration-related trends and pairwise exposure concentration-related effects on survival are assessed using a Cox proportional hazards model^121^ with a random litter effect. All reported p values for the survival analyses are two-sided.

### Calculation of Incidence

The incidence of neoplasms or nonneoplastic lesions is presented as the numbers of animals bearing such lesions at a specific anatomic site. For calculation of incidence rates, the denominator for most neoplasms and all nonneoplastic lesions is the number of animals where the site was examined microscopically. When macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, Zymbal’s gland) before microscopic evaluation, however, the denominator consists of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominator consists of the number of animals on which a necropsy was performed. Additional study data also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidence

Statistical analyses of neoplasm and nonneoplastic lesion incidence considered two features of the data. Some animals did not survive the entire 2 years of the study, so survival differences between groups had to be considered. In addition, up to two animals per sex were randomly selected from each litter to participate in the study. The statistical analysis of lesion incidence used the Poly-3 test to account for survival differences, with a Rao-Scott adjustment for litter effects, as described below.

The Poly-k test^122-124^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to account for survival differences. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is 1 if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died before terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only on the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^122^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^122^ after an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control Fischer 344 rats and B6C3F1 mice.^125^ Bailer and Portier^122^ showed that the Poly-3 test gave valid results if the true value of k was within the range of 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^126^ Poly-3 tests used the continuity correction described by Nam.^127^

Littermates tend to be more like each other than like fetuses or pups in other litters. Failure to account for correlation within litters leads to underestimates of variance in statistical tests, resulting in higher probabilities of Type I errors (“false positives”). Because up to two pups per sex per litter were present in the core rat study, the Poly-3 test was modified to accommodate litter effects using the Rao-Scott approach.^128^ The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Poly-3 test as recommended by the Fung et al.^129^ formula ₸_RS2_.

Tests of significance included pairwise comparisons of each exposed group with control groups and a test for an overall exposure concentration-related trend. Continuity-corrected Rao-Scott-adjusted Poly-3 tests were used in the analysis of lesion incidence and reported p values are one-sided. The significance of a lower incidence or negative trend in lesions is approximated as 1−p with the letter N added (e.g., p = 0.99 is presented as p = 0.01N). For neoplasms and nonneoplastic lesions observed without litter structure (e.g., at the interim evaluation), Poly-3 tests that included the continuity correction, but without adjustment for potential litter effects, were used for trend and pairwise comparisons to the control group.

To evaluate incidence rates by litter, the proportions of litters affected by each lesion type were tested among groups. Cochran-Armitage trend tests and Fisher’s exact tests^130^ were used to test for trends and pairwise differences from the control group, respectively.

### Analysis of Continuous Variables

Before statistical analysis, extreme values identified by the outlier test of Dixon and Massey^131^ for small samples (n < 20) and Tukey’s outer fences method^132^ for large samples (n ≥ 20) were examined by NTP personnel, and implausible values were eliminated from the analysis. Body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^133^ and Williams.^134,135^ Dam gestational and lactational feed consumption, litter sizes, pup survival, implantations, number of resorptions, and proportions of male pups per litter for all studies were analyzed using the nonparametric multiple comparison methods of Shirley,^136^ as modified by Williams,^137^ and Dunn,^138^ given that these endpoints typically have skewed distributions. For all quantitative endpoints unaffected by litter structure, the Jonckheere test^139^ was used to assess the significance of the exposure concentration-related trends and to determine at the 0.01 level of significance whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure concentration-related trend (the Dunnett or Dunn test).

Postweaning body weights were measured on two pups per sex per litter in the 2-year study; more than two pups per sex per litter were possible in preweaning body weight measurements. The analyses of pup mean body weights and mean body weights adjusted for litter size (described below) of these animals took litter effects into account using a mixed model with litter as a random effect. To adjust for multiple comparisons, a Dunnett-Hsu adjustment was used.^140^ Dam mean body weights during gestation and lactation were analyzed with the parametric multiple comparison procedures of Dunnett^133^ and Williams,^134,135^ depending on whether the Jonckheere test indicated the use of a trend-sensitive test. P values for these analyses are two-sided.

### Analysis of Gestational and Fertility Indices

Cochran-Armitage trend tests were used to test the significance of trends in gestational and fertility indices across exposure groups. Fisher’s exact test was used to conduct pairwise comparisons of each exposed group with the control group. P values for these analyses are two-sided.

### Body Weight Adjustments

Preweaning pup body weights were adjusted for live litter size as follows: A linear model was fit to body weights as a function of exposure concentration and litter size. The estimated coefficient of litter size was then used to adjust each pup body weight based on the difference between its litter size and the mean litter size. Prestandardization PND 4 body weights were adjusted for PND 1 litter size, and body weights measured between PND 4 poststandardization and PND 21 were adjusted for PND 4 poststandardization litter size. After adjustment, mean body weights were analyzed with a linear mixed model with a random litter effect.

### Historical Control Data

The concurrent control group is the most valid comparison to the exposed groups and is the only control group analyzed statistically in NTP bioassays. Historical control data are often helpful in interpreting potential exposure-related effects, however, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control data must be generally similar. Significant factors affecting the background incidence of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathological findings in control animals completed within the most recent 5-year period,^141-143^ including the concurrent control for comparison across multiple technical reports. In general, the historical control data for a given study includes studies using the same route of administration, and the overall incidence of neoplasms in control groups for all routes of administration are included for comparison, including the current study.

## Quality Assurance Methods

The 2-year studies were conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations.^144^ In addition, the 2-year study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.