# Introduction

Figure 1

Di-n-butyl Phthalate (CASRN 84-74-2; Chemical Formula C16H22O4; Molecular Weight: 278.34)

Synonyms: dibutyl benzene-1,2-dicarboxylate; 1,2-benzenedicarboxylic acid, dibutyl ester; di-n-butylorthophthalate.

## Chemical and Physical Properties

Di-n-butyl phthalate (DBP) is a colorless, oily liquid at room temperature. It is soluble in most solvents but minimally so in water, having a K_ow_ of 3.70 to 4.72. DBP has a melting point of −35°C and a boiling point of 340°C.^1^ At 25°C, its vapor pressure is approximately 2.67 mPa.^2^

## Production, Use, and Human Exposure

DBP is a phthalate ester and is produced primarily in Europe, the United States, Asia, and Pacific Rim countries.^3^ Between 1980 and 1994, U.S. production of DBP, including di-iso-butyl phthalate, ranged from 6.5 to 11.5 million kg, according to the U.S. International Trade Commission.^1^ The national imported volume of DBP reported in the U.S. Environmental Protection Agency’s (EPA’s) Chemical Data Reporting database was approximately 7 million pounds in 2011.^4^

DBP is primarily used as a plasticizer, which increases the malleability of plastics, particularly in nitrocellulose plastics that can be used as food packaging materials. Lower molecular weight phthalates, like DBP, also are used in solvents, inks, and latex adhesives.^5-7^ DBP is the primary plasticizer in nail polish and has been detected in cosmetics and personal care products such as perfume and hair spray.^7-10^ DBP also is used as an enteric coating for some pharmaceutical products to modulate drug absorption.^11,12^

Due to the widespread use of phthalates, metabolites of phthalates are detectable in humans (reviewed in Wang et al.^13^). The primary metabolite of DBP, mono-n-butyl phthalate (MBP), has been detected in human urine with median concentrations ranging from 0 to 2,540 μg/L.^13^ In biomonitoring data from the National Health and Nutrition Evaluation Survey (NHANES) for 2013–2014, urinary MBP in the U.S. population ranged from 0.3 to 489.6 μg/L.^14^ In workers at plastic manufacturing plants in Slovakia, urinary MBP concentrations ranged from 11.9 to 1,221.8 μg/L.^15^

Concentrations of MBP in serum tend to be lower than those in urine.^13^ In a study of Danish men, serum MBP concentration was two orders of magnitude lower than urinary MBP (0.4 versus 42.5 μg/L).^16^ Additionally, MBP has been detected in cord blood, amniotic fluid, and breast milk, suggesting gestational and lactational transfer. Concentrations of MBP in these matrices are lower than urinary MBP concentrations. Median maternal plasma concentration of MBP was 4.37 μg/L, whereas median cord plasma concentration was 5.15 μg/L.^17^ MBP was detected in approximately 93% of amniotic fluid samples collected in the United States, and concentrations ranged from below the limit of detection to 0.264 μg/L.^18^ Median breast milk concentrations of MBP from various cohorts ranged from 0.5 to 12 μg/L.^19-21^

Human exposure to DBP occurs primarily through consumption of DBP-contaminated food, typically dairy, fish, or seafood products.^1^ Because phthalates do not bind to plastic, they are prone to leaching into foods from the packaging products to which they have been added. Estimated exposure through food, based on surveys of phthalates in various food products, is 0–7 μg DBP/kg body weight/ day (μg/kg/day),^22^ although some estimates suggest a maximum likely food intake of DBP of approximately 31 μg/kg/day.^7^ Actual exposure depends highly on food consumption patterns and usage of food packaging, as some food products tend to have higher DBP concentrations than others.^23^ Exposure to DBP through oral pharmaceuticals in a Danish population was estimated at 0.5–32.8 mg DBP per defined daily dose.^11^ Many pharmaceutical products, assuming an intake of one defined dose per day, exceeded the maximum daily exposure limit of 0.01 mg/kg/day for DBP.^11^

DBP exposure via inhalation and dermal routes is also pertinent, both for the general population and for certain occupations. Estimated inhalation of DBP in indoor air by the general adult population—due to off-gassing of household products and/or inhalation of dust containing DBP—ranged from 0.01 to 6.18 μg/m^3^.^7,23,24^ Inhalation exposures for children tended to be higher.^23^ For workers in various manufacturing industries, phthalate exposure levels were found to exceed that of the general population, and one exposure estimate via inhalation was 143 μg/kg/day.^22,25,26^ Manicurists at nail salons are also exposed via inhalation and dermal absorption; use of exhaust systems and gloves decreased urinary MBP concentrations measured after work.^27^ Dermal exposure to DBP in the general population occurs through use of personal care products containing phthalates. An estimate of the maximal daily DBP dermal dose in Canadian women, based on detected concentrations in 252 products, was 0.36 μg/kg/day.^28^

## Regulatory Status

Six phthalate chemicals, including DBP, were banned from use in the United States in children’s toys at concentrations >0.1% by the Consumer Product Safety Commission, starting in 2008.^29^ The final rule was published in 2017.^30^

The U.S. Food and Drug Administration (FDA) has not published a safety assessment of DBP but did release industry guidance in 2012 that recommended not using it as an excipient.^31^ Additionally, in 2018, FDA proposed an amendment to the Code of Federal Regulations to remove 26 phthalates, including DBP, from food-additive and food-contact use.^32^

DBP is listed as a hazardous air pollutant under the Clean Air Act, it is listed in the Toxic Substances Control Act Chemical Substance Inventory, and it is reportable to the Toxic Release Inventory. As such, EPA has established an oral reference dose (RfD) for DBP: 0.1 mg/kg/day based on increased mortality with a no-observed-adverse-effect level of 125 mg/kg/day.^33,34^ Confidence in this RfD is low, however, due to limitations of the Smith et al. study; animals of only one sex were used, and mortality was observed early in the study with no indication of the cause of death.^34^ The ATSDR minimal risk level (MRL), an estimate of exposure that is likely without appreciable risk of adverse, noncancer health effects, for acute oral exposure is 0.5 mg/kg/day.^35^ This value was based on a no-observed-adverse-effect level of 50 mg/kg/day for developmental effects. In addition, EPA has classified DBP as a group D carcinogen, not classifiable as to human carcinogenicity, due to the lack of adequate studies.^34^ DBP has not been evaluated for human carcinogenicity by the International Agency for Research on Cancer.

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

Following oral administration, DBP is hydrolyzed to MBP by lipases and esterases in the gastrointestinal tract; hence, the available data primarily concerns MBP.^36-39^ MBP is rapidly absorbed and distributed in the body after oral exposure to DBP. In Wistar and Sprague Dawley rats, most of an oral dose (ranging from 0 to 250 mg/kg) is accounted for in urine within 24 hours after dosing.^37,40-42^ MBP is distributed to tissues with minimal bioaccumulation.^37,40,41,43^ In male Sprague Dawley rats given 30 mg/kg intravenously, the half-life of DBP was approximately 3.6 hours.^42^

MBP and its glucuronide are the primary metabolites of DBP, eliminated mostly in urine.^37^ Some fecal elimination does occur,^40-43^ and enterohepatic recirculation has been reported.^40,41^ In plasma, tissues, and urine, most MBP exists as unconjugated MBP.^41,43,44^ MBP can be metabolized further through oxidation to produce 3-hydroxybutyl phthalate (3OH-MBP), 4-hydroxybutyl phthalate (4OH-MBP), 3-ketobutyl phthalate, or 4-carboxypropyl phthalate.^1^

Gestational transfer of DBP has been evaluated in two studies.^41,43^ Pregnant Sprague Dawley rats given a single dose of DBP (50, 100, or 250 mg/kg) on gestational day 20 via oral gavage had a maternal plasma T_max_ of MBP and MBP-glucuronide of 0.5 and 2 hours, respectively.^41^ MBP was detected in fetal plasma; C_max_ was 2.4- to 4-fold higher in maternal plasma, but the area under the curve was only 1.4- to 1.7-fold higher. The ratio of MBP:MBP-glucuronide in maternal plasma was higher than that in the fetal plasma.^41^ At higher doses of DBP (500 and 1,500 mg/kg), the plasma T_max_ of MBP was similar to that observed with lower doses, ranging from 1.4 to 2.6 hours.^43^ Concentrations of MBP in embryos and the placenta were <33% of maternal plasma concentrations; MBP-glucuronide was lower than MBP.^43^ MBP and MBP-glucuronide were detected in the amniotic fluid at concentrations similar to those in embryos. Overall, these studies indicate fetal exposure to MBP and MBP-glucuronide occurs, although the concentrations are lower than those observed in the dam. This exposure could occur through transfer of metabolites across the placenta and/or by fetal metabolism.

### Humans

As in animals, DBP in humans is converted to MBP in the gastrointestinal tract before it is absorbed. Human and rodent lipases show similar rates of conversion of DBP to MBP.^45^ Three studies have evaluated human absorption, distribution, metabolism, and excretion of DBP after oral consumption. In one study, one male volunteer ingested 60 μg/kg body weight of DBP.^46^ In the second study, 17 volunteers consumed one capsule of an herbal drug containing 3,600 μg of DBP.^47^ In the third study, 24 volunteers consumed phthalates, including DBP (255 and 510 μg), spiked into margarine and administered on toast.^48^

As shown for animals, most of the dose administered to humans was excreted as MBP in the urine within the first 24 hours.^46-48^ Hydroxylated monoester DBP metabolites were detected in urine after DBP consumption in Koch et al.^46^ In urine, MBP was the dominant metabolite, comprising 84% of the metabolites, followed by 3OH-MBP (7%); other excreted metabolites included 2-hydroxybutyl phthalate (2OH-MBP), 4OH-MBP, and mono-carboxy-propyl phthalate (MCPP), which contributed <1% each.^46^ In plasma, MBP, 3OH-MBP, and MCPP were detected at 196, 13.5, and 2.8 μg/L, respectively.^46^ Unlike rodent studies, in which most MBP is unconjugated, most MBP in human urine and plasma is conjugated with glucuronide. This pattern has been observed in urine and plasma samples from NHANES studies,^49^ in urine after oral ingestion of DBP,^47^ and in urine after topical exposure to DBP.^50^

The urinary half-life of MBP reported for an individual who ingested DBP was 2.6 hours; 3OH-MBP and 4OH-MBP had half-lives similar to that of MBP, but the other detected metabolites had longer (approximately 6 hours) half-lives.^46^

## Toxicity

### Experimental Animals

Several studies have been conducted to evaluate the toxicity of DBP following oral exposure. NTP has conducted both subchronic and reproductive and developmental studies on DBP; these findings are reported in NTP Toxicity Report 30.^51^ Generally, oral DBP exposure is well tolerated in animal models, as indicated by some studies reporting an acute oral LD_50_ (median lethal dose) in rodents >20,000 mg/kg.^52,53^ NTP Toxicity Report 30 studies in rats and mice show minimal differences in survival after 3 months of exposure of up to approximately 4,278 mg/kg/day.^51^ Toxicity to the male reproductive tract is the primary endpoint studied with DBP exposure; these effects are summarized in the reproductive and developmental toxicity section below. Neurotoxicity, particularly following in utero DBP exposure, has been reported in some rodent studies^54-56^ but not others.^57^ Other target organs include the liver and the hematopoietic system.

Increased liver weight has been observed in rats following exposure to DBP for 7 or more days,^51,58,59^ which might be related to proliferation of peroxisomes. Some phthalates are known peroxisome proliferator-activated receptor (PPAR) agonists^60^; DBP and its metabolites weakly activate the three PPAR receptor subtypes in vitro.^61,62^ In the NTP 13-week study of rats administered DBP in feed, peroxisomal enzyme activity was induced at exposure concentrations of ≥356 mg/kg/day.^51^ Hepatic cytoplasmic alteration was noted in male and female rats exposed to ≥720 mg/kg/day and in male and female mice exposed to ≥1,601 mg/kg/day and ≥4,278 mg/kg/day, respectively. Decreases in serum triglyceride and/or cholesterol were observed in the NTP 3-month studies and in other studies^51,58,63^ and could be due to hepatic toxicity because the liver is the site of cholesterol synthesis. These changes also could be due to PPAR activation, which could lead to impaired lipid and glucose homeostasis.

Decreases in erythrocyte, hemoglobin, and hematocrit levels were observed in male rats given DBP at 752 mg/kg/day.^57^ In the NTP 13-week rodent studies, dietary exposure to DBP resulted in minimally severe anemia characterized by decreases in erythrocyte, hemoglobin, and hematocrit levels in male rats only at exposure concentrations >359 mg/kg/day.^51^ Decreased hematocrit was observed in female mice following exposure to 4,278 mg/kg/day.^51^

### Humans

Studies that followed humans after ingestion of up to 5.4 mg DBP reported no adverse effects after acute exposure.^46-48^ Epidemiological studies have focused on associations of phthalate exposure with asthma, reproductive health, metabolic disease, neurodevelopmental disorders, and cancer (particularly breast cancer due to potential estrogen binding of phthalates) (reviewed in Benjamin et al.^64^). Specifically, MBP exposure was significantly associated with metabolic disease and with spermatotoxicity in some studies.^64^

## Reproductive and Developmental Toxicity

### Experimental Animals

Reproductive and developmental toxicity is the main toxicity associated with phthalate exposure in rodents (reviewed in Kavlock et al.^22^). Developmental abnormalities in the male rodent reproductive tract following in utero DBP exposure include malformations of the male reproductive tract, undescended testes, and decreased anogenital distance.^22,65,66^ In addition to small and atrophic testes, hypoplastic epididymides, and decreased size or absence of prostate, seminal vesicles, and vas deferens, male rats exposed to 100 or 500 mg/kg/day via gavage in utero (gestation day [GD] 12 to 21) were diagnosed with testicular dysgenesis.^65^ These lesions were characterized by areas of malformed seminiferous tubules surrounded by Leydig cell aggregates.^65^ The testicular dysgenesis lesions did not increase over time, suggesting these lesions were of developmental origin. Low testosterone and decreased insulin-like peptide 3 (Insl3) levels have been observed after in utero exposure in some studies,^51,67^ which are proposed mechanisms of phthalate toxicity.^68-72^ Delayed puberty was observed in male rats,^73^ but not in females, following exposure to DBP.^74^

Other developmental effects observed with in utero DBP exposure (generally >600 mg/kg/day) include increased resorptions, decreased pup body weight, delayed ossification, and fetal malformations.^1^ External (e.g., cleft palate) and skeletal (e.g., fused sternebrae, deformed vertebral column) malformations have been reported at doses >500 mg/kg/day and depend on the window of exposure during gestation.^43,75-78^ Administration of MBP has elicited similar developmental impairments, suggesting that the metabolite might be responsible for these effects.^43,79,80^

Exposure to DBP impaired fertility and decreased the number of live pups per litter in multiple rodent studies.^51,73,81^ Acute and subchronic oral exposure (feed and gavage) to DBP causes reproductive toxicity in male rodents, guinea pigs, and rabbits, characterized by malformations of the reproductive tract, reduced sperm count, and testicular damage and atrophy.^51,67,73,81-83^ The effects of DBP on female reproduction are less clear and have been reviewed by Kay et al.^74^ Minimal effects on the ovary or estrous cycling were observed in Sprague Dawley and Long Evans rats^51,81,84^) and in CD-1 mice.^51^ A crossover breeding study in CD-1 mice, however, suggests some effect of DBP on female fertility, as decreases in fertility and in the number of pups per litter occurred in exposed females mated with control males.^51^ Furthermore, treatment of Long Evans rats with 500 mg/kg/day DBP increased midterm abortions, and F_1_ female offspring in the study displayed reduced fecundity.^84,85^ The embryonic loss after DBP exposure could be mediated in part by reduced uterine decidualization and/or by disruptions in hormones during gestation.^84,86^

### Humans

The epidemiological data on phthalate exposure and male and female reproductive health have been reviewed by Radke et al.^87,88^ Some evidence supports the relationship between increasing DBP exposure and adverse male reproductive effects, including decreased semen quality, decreased anogenital distance, and decreased fecundability.^87^ Ten studies evaluated testosterone concentrations and DBP exposure. Of those, five reported decreased testosterone with increasing DBP exposure^87^; the association was statistically significant in only one study.^89^ Concerning female reproductive health, no significant associations of DBP exposure with time to pregnancy, spontaneous abortion, or pubertal development were found.^88^ Six studies evaluated DBP exposure and preterm birth; three showed a positive association (significant in two), and three showed no or a negative association.^88^

## Immunotoxicity

### Experimental Animals

Hansen et al.^90^ have reviewed the immunotoxicity of phthalates. Generally, experimental studies indicate that phthalates can affect immune cells and modify cytokine expression; however, the effect is inconsistent across studies and phthalates. Only a few studies have evaluated DBP specifically. Exposure of murine peritoneal exudate macrophages to DBP (1–100 μM) resulted in a dose-dependent decrease in expression of some cell surface markers, decreased phagocytosis, decreased cytokine production, and impaired antigen-presenting capacity.^91^ Testicular macrophages isolated from Sprague Dawley rats after a 90-day exposure to 250 mg/kg/day DBP had higher interleukin (IL)-1β protein expression.^92^ Another study in female Wistar rats found that DBP exposure exacerbated chronic lymphocytic thyroiditis, increased thyroid auto-antibodies, disrupted T helper Type 1 (Th1) and Th2 balances, and activated proinflammatory cytokines.^93^ DBP did not elicit these effects in animals without chronic lymphocytic thyroiditis.^93^

### Humans

To date, epidemiological studies evaluating phthalate exposure and immune function have focused on asthma. Overall, these studies suggest a possible correlation between phthalate exposure and childhood asthma but are limited by the cross-sectional study design and the use of polyvinyl chloride materials or di(2-ethylhexyl)phthalate dust as surrogates of exposure (summarized in Bornehag and Nanberg^94^). One in vitro study stimulated human whole blood with DBP and found that DBP might exert immunosuppressive effects.^95^

## Carcinogenicity

### Experimental Animals

Two rodent studies have examined the carcinogenic effects of chronic DBP exposure. The first exposed 10 male rats per group to 0%, 0.01%, 0.05%, 0.25%, and 1.25% DBP in feed for 1 year.^33^ High mortality occurred at the highest exposure concentration (approximately 625 mg/kg/day) within the first week of the study; the cause of death or whether the deaths were exposure-related was not reported. No hematological or gross pathological changes were observed.^33^ The second study evaluated male Sprague Dawley rats at 6, 12, and 18 months of age after in utero-only exposure to DBP.^65^ Pregnant Sprague Dawley rats were administered 0, 100, or 500 mg/kg/day DBP via oral gavage from GD 12 to 21. Leydig cell adenomas, categorized according to the morphological criteria of the Society of Toxicologic Pathology, were observed only in the 100 mg/kg/day dose group at 18 months of age.^65^ Areas composed of Leydig cell aggregates surrounding malformed, contorted seminiferous tubules, defined as testicular dysgenesis, however, were observed consistently in the high dose group. Low incidences of other neoplasms (e.g., pituitary adenoma, basal cell adenoma, sarcoma) also were reported. Female animals were not evaluated.

### Humans

Carcinogenicity of DBP in humans has not been evaluated by the International Agency for Research on Cancer, and EPA has been unable to classify it due to a lack of adequate studies, both in animal and in epidemiological or human studies. Phthalates have been implicated in breast cancer due to their reactivity with the estrogen receptor in vitro. However, DBP binds weakly to the estrogen receptor in mammalian in vitro screens.^96^ In six epidemiological studies, MBP was not found to be associated with breast cancer (reviewed in Zuccarello et al.^97^). Other epidemiological studies have examined associations of DBP with uterine tumors and gastrointestinal cancers. Urinary MBP was associated with uterine leiomyomas,^98^ but DBP exposure was not associated with increased gastric cancers,^99^ although sample sizes for both studies were small. Cumulative phthalate exposure from drug excipients had an overall protective effect against colorectal cancer; exclusion of nonsteroidal anti-inflammatory drug users from the analysis reversed the relationship.^100^

## Genetic Toxicity

The genetic toxicity of DBP has been evaluated in a variety of in vitro and in vivo assays, and results are mixed. In bacterial mutation assays that examined reversion to histidine prototrophy, DBP was reported to be negative or weakly positive in a variety of Salmonella typhimurium tester strains, both with and without exogenous metabolic activation (S9).^101-104^ In a bacterial forward mutation assay, DBP (0.18–0.45 mM) induced a weak but dose-related increase in 8-azaguanine resistance in S. typhimurium strain TA100 in the absence of, but not the presence of, S9.^105^ DBP at concentrations of 10 or 20 μL/mL did not increase gene reversion frequencies in the yeast Saccharomyces cerevesiae strain XV185-14c after 48 hours of exposure, with or without S9.^106,107^

In contrast to the mostly negative results in bacteria and yeast, positive results were obtained in most genotoxicity assays in cultured mammalian cells. DBP (46–54 μg/mL) induced mutations in mouse lymphoma L5178Y^tk+/−^ cells treated in the absence of S9 at concentrations that induced high levels of cytotoxicity; it was not tested with S9.^51^ In a second mouse lymphoma cell gene mutation assay that used concentrations of DBP ranging up to 0.15 μL/mL, a significant increase in mutations was reported in the presence of S9 and at concentrations that induced marked cytotoxicity (relative total growth <20%).^108^ DBP (354 mM for 60 minutes) induced DNA damage in cultured human oropharyngeal mucosal cells, human nasal mucosal cells, human mucosal cells of the upper aerodigestive tract, and human lymphocytes, as measured by the alkaline comet assay.^109,110^ Negative results were reported for DBP (1 μM–1 mM) in tests for induction of chromosomal aberrations and sister chromatid exchanges in Chinese hamster DON cells.^111^

Conflicting results were obtained in vivo in genotoxicity tests conducted in mice. No increases in the frequencies of micronucleated normochromatic erythrocytes were observed in peripheral blood samples obtained from male and female B6C3F1/N mice after 3 months of exposure to DBP (1,250–20,000 ppm or 163–4,278 mg/kg/day) in dosed feed.^51^ In contrast, significant increases in the percentages of chromosomally aberrant splenic lymphocytes and micronucleated peripheral blood erythrocytes were observed in male and female B6C3F1 mice following 16 to 52 weeks of exposure to 5,000 ppm DBP in dosed feed.^112^ In addition, increases in hprt transversion mutations in splenic T-cells of these male and female mice exposed to DBP (5,000 ppm) for 32 or 52 weeks were reported.^113^ Recently, DBP was reported to disrupt meiotic prophase, disrupt homologous recombination, and increase the number of γH2AX foci (indicative of DNA double-strand breaks) in oocytes of fetal mice following exposure of the dam via oral administration of 10 or 100 mg/kg/day for 3 days.^114^

## Study Rationale

Available studies to evaluate DBP carcinogenicity are limited to two rodent studies that evaluated a small number of male animals with adult-only exposure. Given widespread exposure to DBP in the general population and that previous literature indicates developmental toxicities, a perinatal exposure was included in the rat study to provide a hazard assessment of lifetime exposure to environmental phthalates. To emulate the primary route of human exposure, the animals in this study were exposed via feed. In addition, this study is part of a larger body of work that aims to inform cumulative and aggregate risk characterization efforts for a range of environmental phthalates.