# Appendix E Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TR-600.^145^

## E.1 Perinatal and Two-year Study in Rats

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E08 – Feed Water and Compound Consumption Table

Gestational Body Weights

Gestational Food Consumption

Gestational and Lactational Chemical Consumption

Lactational Body Weights

Lactational Food Consumption

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P22 – Cause of Death Summary

P40 – Survival Curves

PA46R – Summary of Gross Pathology with Litter Incidence

PA48 – Summary of Tissue Concentration

PND 1 Litter Data

PND 4 and 21 Live Litter Size and Survival

Pup Body Weights

R02 – Reproductive Performance Summary

R23 – Gubernaculum Length Summary

## E.2 Individual Animal Data for Perinatal and Two-year Study in Rats

Female Individual Animal Body Weight Data All Animals

Female Individual Animal Pathology Data Neoplastic

Female Individual Animal Pathology Data Non-Neoplastic

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Female Individual Clinical Observations

Male Individual Animal Body Weight Data All Animals

Male Individual Animal Clinical Observations

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Organ Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Gubernaculum and Urogenital Findings Data

Individual Animal DamID and PupID Data

Individual Animal Reproductive Performance Data

Individual Animal Tissue Concentration Data

## E.3 Two-year Study in Mice

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E08 – Feed Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P22 – Cause of Death Summary

P40 – Survival Curves

## E.4 Individual Data for Two-year Study in Mice

Female Individual Animal Body Weight Data

Female Individual Animal Clinical Observations

Female Individual Animal Organ Weight Data

Female Individual Animal Pathology Data Neoplastic

Female Individual Animal Pathology Data Non-Neoplastic

Female Individual Animal Survival Data

Male Individual Animal Body Weight Data

Male Individual Animal Clinical Observations

Male Individual Animal Organ Weight Data

Male Individual Animal Pathology Data Neoplastic

Male Individual Animal Pathology Data Non-Neoplastic

Male Individual Animal Survival Data