# Appendix C Sentinel Animal Program

## C.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that might affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or exposed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

For these toxicology and carcinogenesis studies, blood samples were collected from each sentinel animal, allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for endoparasites and Helicobacter species. All samples were processed appropriately with serology testing sent to IDEXX BioResearch (formerly Rodent Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO, for determination of the presence of pathogens. Evaluation for endo- and ectoparasites was performed in-house by the testing laboratory.

The laboratory methods and agents for which testing was performed are tabulated in Table C-1 and Table C-2 below; the times at which samples were collected during the studies are also listed.

## C.2 Results

Rats: Positive for endoparasites, pinworms (Syphacia spp.). All other test results were negative.

Mice: All test results were negative.

Table C-1 Methods and Results for Sentinel Animal Testing in Male and Female Rats

Collection Time Points | Quarantine^a^ | Perinatal^b^ | 6 Months | 12 Months | 17 Months | 18 Months | End of Study
Number Examined (Males/Females) | 0/10 | 0/10 | 5/5 | 5/5 | 0/1 | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Kilham rat virus (KRV) | − | − | − | − | NT | − | −
Mycoplasma pulmonis | − | − | − | − | NT | − | −
Pneumonia virus of mice (PVM) | − | − | − | − | NT | − | −
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | − | − | − | − | NT | − | −
Rat minute virus (RMV) | − | − | − | − | NT | − | −
Rat parvo virus (RPV) | − | − | − | − | NT | − | −
Rat theilovirus (RTV) | − | − | − | − | NT | − | −
Sendai | − | − | − | − | NT | − | −
Theiler’s murine encephalomyelitis virus (TMEV) | − | − | − | − | NT | − | −
Toolan’s H-1 | − | − | − | − | NT | − | −
In-house Evaluation
Endoparasites (evaluation of cecal content) | NT | NT | NT | NT | + | + | NT
Ectoparasites (evaluation of perianal surface) | NT | NT | NT | NT | + | + | NT

− = negative; + = positive; NT = not tested.

^a^ Age matched nonpregnant females.

^b^ Time-mated females that did not have a litter; 3.5 weeks after arrival.

Table C-2 Methods and Results for Sentinel Animal Testing in Male and Female Mice

Collection Time Points | 1 Month | 6 Months | 12 Months | 18 Months | End of Study
Number Examined (Males/Females) | 5/5 | 5/5 | 5/5 | 5/5 | 5/5
Method/Test
Multiplex Fluorescent Immunoassay (MFI)
Ectromelia virus | − | − | − | − | −
Epizootic diarrhea of infant mice (EDIM) | − | − | − | − | −
Lymphocytic choriomeningitis virus (LCMV) | − | − | − | − | −
Mycoplasma pulmonis | − | − | − | − | −
Mouse hepatitis virus (MHV) | − | − | − | − | −
Mouse norovirus (MNV) | − | − | − | − | −
Mouse parvovirus (MPV) | − | − | − | − | −
Minute virus of mice (MVM) | − | − | − | − | −
Pneumonia virus of mice (PVM) | − | − | − | − | −
Reovirus (REO3) | − | − | − | − | −
Sendai | − | − | − | − | −
Theiler's murine encephalomyelitis virus (TMEV) GDVII | − | − | − | − | −
Immunofluorescence Assay (IFA)
Epizootic diarrhea of infant mice (EDIM) | NT | NT | − | NT | NT
Ectromelia virus | NT | NT | − | NT | NT
Polymerase Chain Reaction (PCR)
Helicobacter species | NT | NT | NT | − | NT

− = negative; NT = not tested.