# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NIH-07 and NTP-2000 Rat and Mouse Ration

Table B-1 Ingredients of NIH-07 Rat Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 24.25
Wheat Middlings | 10.0
Oat Hulls | 0.0
Alfalfa Meal (Dehydrated, 17% Protein) | 4.0
Purified Cellulose | 0.0
Soybean Meal (47% Protein) | 12.0
Fish Meal (62% Protein) | 10.0
Corn Oil (without Preservatives) | 0.0
Soy Oil (without Preservatives) | 2.5
Dried Brewer’s Yeast | 2.0
Calcium Carbonate (USP) | 0.5
Vitamin Premix^a^ | 0.25
Mineral Premix^b^ | 0.15
Calcium Phosphate, Dibasic (USP) | 1.25
Sodium Chloride | 0.5
Choline Chloride (70% Choline) | 0.10
Dried Skim Milk | 5.00
Dried Molasses | 1.50
Corn Gluten Meal (60% Protein) | 3.00
Methionine | 0.00

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NIH-07 Rat Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 6,062 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 5,070 IU | D-activated animal sterol
Vitamin K | 3.1 mg | Menadione sodium bisulfite complex
Vitamin E | 22 IU | α-Tocopheryl acetate
Niacin | 33 mg
Folic Acid | 2.4 mg
d-Pantothenic Acid | 19.8 mg | d-Calcium pantothenate
Riboflavin | 3.8 mg
Thiamine | 11 mg | Thiamine mononitrate
B_12_ | 50 μg
Pyridoxine | 6.5 mg | Pyridoxine hydrochloride
Biotin | 0.15 mg | d-Biotin
Minerals
Iron | 132 mg | Iron sulfate
Zinc | 18 mg | Zinc oxide
Manganese | 66 mg | Manganese oxide
Copper | 4.4 mg | Copper sulfate
Iodine | 2.0 mg | Calcium iodate
Cobalt | 0.44 mg | Cobalt carbonate

^a^ Per kg of finished diet.

Table B-3 Nutrient Composition of NIH-07 Rat Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 24.25 ± 1.485 | 23.2–25.3 | 2
Crude Fat (% by Weight) | 5.5 ± 0.424 | 5.2–5.8 | 2
Crude Fiber (% by Weight) | 3.515 ± 0.191 | 3.38–3.65 | 2
Ash (% by Weight) | 6.135 ± 0.021 | 6.12–6.15 | 2
Amino Acids (% of Total Diet)
Arginine | 1.380 ± 0.06 | 1.3–1.49 | 10
Cystine | 0.322 ± 0.031 | 0.274–0.372 | 10
Glycine | 1.150 ± 0.070 | 1.06–1.31 | 10
Histidine | 0.518 ± 0.024 | 0.497–0.553 | 10
Isoleucine | 0.984 ± 0.024 | 0.952–1.03 | 10
Leucine | 2.018 ± 0.067 | 1.93–2.13 | 10
Lysine | 1.243 ± 0.051 | 1.13–1.32 | 10
Methionine | 0.488 ± 0.016 | 0.468–0.515 | 10
Phenylalanine | 1.097 ± 0.022 | 1.07–1.12 | 10
Threonine | 0.918 ± 0.031 | 0.883–0.961 | 10
Tryptophan | 0.277 ± 0.020 | 0.265–0.326 | 10
Tyrosine | 0.860 ± 0.037 | 0.785–0.894 | 10
Valine | 1.134 ± 0.025 | 1.11–1.17 | 10
Essential Fatty Acids (% of Total Diet)
Linoleic | 2.30 ± 0.219 | 1.99–2.59 | 10
Linolenic | 0.25 ± 0.275 | 0.217–0.296 | 10
Vitamins
Vitamin A (IU/kg) | 4,085 ± 161.9 | 2,940–5,230 | 2
α-Tocopherol (ppm) | 6,704 ± 21,045 | 40.3–66,600 | 10
Thiamine (ppm)^a^ | 10.6 ± 0.283 | 10.4–10.8 | 2
Riboflavin (ppm) | 14.47 ± 3.352 | 10.0–19.8 | 10
Niacin (ppm) | 99.33 ± 8.235 | 87.0–112.0 | 10
Pantothenic Acid (ppm) | 44.38 ± 3.806 | 38.2–51.1 | 10
Pyridoxine (ppm)^a^ | 12.876 ± 3.171 | 9.63–19.7 | 10
Folic Acid (ppm) | 2.482 ± 0.487 | 1.68–3.09 | 10
Biotin (ppm) | 0.3283 ± 0.172 | 0.0–0.638 | 10
B_12_ (ppb) | 49.4 ± 6.83 | 41.8–61.6 | 10
Choline (as Chloride) (ppm) | 1,821 ± 197.5 | 1,570–2,200 | 10
Minerals
Calcium (%) | 1.140 ± 0.014 | 1.13–1.15 | 2
Phosphorus (%) | 0.955 ± 0.006 | 0.951–0.959 | 2
Potassium (%) | 0.830 ± 0.036 | 0.769–0.88 | 10
Chloride (%) | 0.652 ± 0.106 | 0.441–0.8 | 10
Sodium (%) | 0.378 ± 0.46 | 0.318–0.469 | 10
Magnesium (%) | 0.187 ± 0.014 | 0.17–0.218 | 10
Iron (ppm) | 385.1 ± 54.9 | 276.0–469.0 | 10
Manganese (ppm) | 90.81 ± 7.566 | 80.7–104.0 | 10
Zinc (ppm) | 64.15 ± 10.07 | 52.4–89.2 | 10
Copper (ppm) | 14.13 ± 2.57 | 11.9–21.1 | 10
Iodine (ppm) | 1.811 ± 0.992 | 0.54–3.45 | 10
Chromium (ppm) | 3.946 ± 0.036 | 3.89–4.0 | 8
Cobalt (ppm) | 0.5155 ± 0.267 | 0.01–0.963 | 10

^a^ As hydrochloride.

Table B-4 Contaminant Levels in NIH-07 Rat Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.355 ± 0.010 | 0.348–0.362 | 2
Cadmium (ppm) | 0.0445 ± 0.005 | 0.041–0.048 | 2
Lead (ppm) | 0.0885 ± 0.018 | 0.076–0.101 | 2
Mercury (ppm) | 0.022 ± 0.001 | 0.021–0.023 | 2
Selenium (ppm) | 0.5125 ± 0.046 | 0.48–0.545 | 2
Aflatoxins (ppb)^a^ | 5 | – | 2
Nitrate Nitrogen (ppm)^b^ | 15 ± 3.677 | 12.4–17.6 | 2
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 2
BHA (ppm)^a,c^ | <1.0 | – | 2
BHT (ppm)^a,c^ | <1.0 | – | 2
Aerobic Plate Count (CFU/gm) | <10 | – | 2
Coliform (MPN/gm) | <3 | – | 2
Escherichia coli (MPN/gm) | <10 | – | 2
Salmonella (MPN/gm) | Negative | – | 2
Total Nitrosamines (ppb)^d^ | 1.8 ± 2.546 | 0.0–3.6 | 2
N-Nitrosodimethylamine (ppb)^d^ | 1.8 ± 2.546 | 0.0–3.6 | 2
N-Nitrosopyrrolidine (ppb)^d^ | 0 | – | 2
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 2
β-BHC^a^ | <0.02 | – | 2
γ-BHC^a^ | <0.01 | – | 2
δ-BHC^a^ | <0.01 | – | 2
Heptachlor^a^ | <0.01 | – | 2
Aldrin^a^ | <0.01 | – | 2
Heptachlor Epoxide^a^ | <0.01 | – | 2
DDE^a^ | <0.01 | – | 2
DDD^a^ | <0.01 | – | 2
DDT^a^ | <0.01 | – | 2
HCB^a^ | <0.01 | – | 2
Mirex^a^ | <0.01 | – | 2
Methoxychlor^a^ | <0.05 | – | 2
Dieldrin^a^ | <0.01 | – | 2
Endrin^a^ | <0.01 | – | 2
Telodrin^a^ | <0.01 | – | 2
Chlordane^a^ | <0.05 | – | 2
Toxaphene^a^ | <0.10 | – | 2
Estimated PCBs^a^ | <0.20 | – | 2
Ronnel^a^ | <0.01 | – | 2
Ethion^a^ | <0.02 | – | 2
Trithion^a^ | <0.05 | – | 2
Diazinon^a^ | <0.10 | – | 2
Methyl Chlorpyrifos | 0.067 ± 0.067 | 0.02–0.114 | 2
Methyl Parathion^a^ | <0.02 | – | 2
Ethyl Parathion^a^ | <0.02 | – | 2
Malathion | 0.153 ± 0.002 | 0.151–0.154 | 2
Endosulfan I^a^ | <0.01 | – | 2
Endosulfan II^a^ | <0.01 | – | 2
Endosulfane Sulfate^a^ | <0.03 | – | 2

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.

Table B-5 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 22.26
Ground #2 Yellow Shelled Corn | 22.18
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 5.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-6 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
d-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 μg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table B-7 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.81 ± 0.544 | 14.2–16.8 | 25
Crude Fat (% by Weight) | 8.72 ± 0.367 | 8.0–9.7 | 25
Crude Fiber (% by Weight) | 9.38 ± 0.442 | 8.34–10.1 | 25
Ash (% by Weight) | 5.3 ± 0.187 | 4.6–14.2 | 25
Amino Acids (% of Total Diet)
Arginine | 0.805 ± 0.075 | 0.67–0.97 | 29
Cystine | 0.220 ± 0.021 | 0.15–0.025 | 29
Glycine | 0.702 ± 0.038 | 0.62–0.80 | 29
Histidine | 0.342 ± 0.070 | 0.27–0.68 | 29
Isoleucine | 0.549 ± 0.040 | 0.43–0.66 | 29
Leucine | 1.100 ± 0.063 | 0.96–1.24 | 29
Lysine | 0.700 ± 0.104 | 0.31–0.86 | 29
Methionine | 0.409 ± 0.042 | 0.26–0.49 | 29
Phenylalanine | 0.623 ± 0.047 | 0.471–0.72 | 29
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 29
Tryptophan | 0.155 ± 0.027 | 0.11–0.2 | 29
Tyrosine | 0.422 ± 0.066 | 0.28–0.54 | 29
Valine | 0.666 ± 0.040 | 0.55–0.73 | 29
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.94 ± 0.235 | 3.49–4.55 | 29
Linolenic | 0.30 ± 0.064 | 0.005–0.368 | 29
Vitamins
Vitamin A (IU/kg) | 3,821 ± 80.2 | 2,030–5,290 | 25
α-Tocopherol (ppm) | 2,456 ± 12,817 | 13.6–69,100 | 29
Thiamine (ppm)^a^ | 8.47 ± 1.958 | 3.9–12.5 | 25
Riboflavin (ppm) | 8.17 ± 2.841 | 4.2–17.5 | 29
Niacin (ppm) | 78.66 ± 8.11 | 66.4–98.2 | 29
Pantothenic Acid (ppm) | 26.42 ± 11.05 | 17.4–81.0 | 29
Pyridoxine (ppm)^a^ | 9.75 ± 2.045 | 6.44–14.3 | 29
Folic Acid (ppm) | 1.58 ± 0.43 | 1.15–3.27 | 29
Biotin (ppm) | 0.323 ± 0.093 | 0.2–0.704 | 29
B_12_ (ppb) | 50.41 ± 34.89 | 18.3–174 | 29
Choline (as Chloride) (ppm) | 2,593 ± 633.8 | 1,160–3,790 | 29
Minerals
Calcium (%) | 0.911 ± 0.046 | 0.831–1.03 | 25
Phosphorus (%) | 0.547 ± 0.105 | 0.0531–0.613 | 25
Potassium (%) | 0.668 ± 0.029 | 0.626–0.733 | 29
Chloride (%) | 0.392 ± 0.044 | 0.3–0.517 | 29
Sodium (%) | 0.195 ± 0.027 | 0.16–0.283 | 29
Magnesium (%) | 0.217 ± 0.054 | 0.185–0.49 | 29
Iron (ppm) | 191.6 ± 36.18 | 135–311 | 29
Manganese (ppm) | 50.11 ± 9.42 | 21–73.1 | 29
Zinc (ppm) | 57.3 ± 25.54 | 43.3–184 | 29
Copper (ppm) | 7.57 ± 2.49 | 3.21–16.3 | 29
Iodine (ppm) | 0.513 ± 0.221 | 0–0.972 | 29
Chromium (ppm) | 1.02 ± 1.04 | 0.33–3.97 | 28
Cobalt (ppm) | 0.222 ± 0.152 | 0.0857–0.864 | 27

^a^ As hydrochloride.

Table B-8 Contaminant Levels in NTP-2000 Rat and Mouse Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.22 ± 0.066 | 0.149–0.385 | 25
Cadmium (ppm) | 0.054 ± 0.013 | 0.038–0.094 | 25
Lead (ppm) | 0.132 ± 0.104 | 0.064–0.474 | 25
Mercury (ppm) | 0.014 ± 0.009 | 0.01–0.049 | 25
Selenium (ppm) | 0.16 ± 0.031 | 0.029–0.209 | 25
Aflatoxins (ppb)^a^ | <5.0 | – | 25
Nitrate Nitrogen (ppm)^b^ | 15.04 ± 4.97 | 10.0–28.1 | 25
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 25
BHA (ppm)^a,c^ | <1.00 | – | 25
BHT (ppm)^c^ | 1.09 ± 0.428 | 1.0–3.14 | 25
Aerobic Plate Count (CFU/gm) | <10.0 | – | 25
Coliform (MPN/gm) | <3 | – | 25
Escherichia coli (MPN/gm) | <10.0 | – | 25
Salmonella (MPN/gm) | Negative | – | 25
Total Nitrosamines (ppb)^d^ | 11.7 ± 5.58 | 3.2–24.5 | 25
N-Ndimethylamine (ppb)^d^ | 2.6 ± 1.66 | 1.0–6.8 | 25
N-Npyrrolidine (ppb)^d^ | 9.2 ± 5.16 | 2.1–20.0 | 25
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 25
β-BHC^a^ | <0.02 | – | 25
γ-BHC^a^ | <0.01 | – | 25
δ-BHC^a^ | <0.01 | – | 25
Heptachlor^a^ | <0.01 | – | 25
Aldrin^a^ | <0.01 | – | 25
Heptachlor Epoxide^a^ | <0.01 | – | 25
DDE^a^ | <0.01 | – | 25
DDD^a^ | <0.01 | – | 25
DDT^a^ | <0.01 | – | 25
HCB^a^ | <0.01 | – | 25
Mirex^a^ | <0.01 | – | 25
Methoxychlor^a^ | <0.05 | – | 25
Dieldrin^a^ | <0.01 | – | 25
Endrin^a^ | <0.01 | – | 25
Telodrin^a^ | <0.01 | – | 25
Chlordane^a^ | <0.05 | – | 25
Toxaphene^a^ | <0.10 | – | 25
Estimated PCBs^a^ | <0.20 | – | 25
Ronnel^a^ | <0.01 | – | 25
Ethion^a^ | <0.02 | – | 25
Trithion^a^ | <0.05 | – | 25
Diazinon^a^ | <0.10 | – | 25
Methyl Chlorpyrifos | 0.09 ± 0.073 | 0.02–0.315 | 25
Methyl Parathion^a^ | <0.02 | – | 25
Ethyl Parathion^a^ | <0.02 | – | 25
Malathion | 0.094 ± 0.09 | 0.02–0.355 | 25
Endosulfan I^a^ | <0.01 | – | 25
Endosulfan II^a^ | <0.01 | – | 25
Endosulfane Sulfate^a^ | <0.03 | – | 25

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.