# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization of Di-n-butyl Phthalate

Di-n-butyl phthalate (DBP) was obtained from Sigma-Aldrich (St. Louis, MO) in a single lot (lot MKBB8432). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at RTI International (Research Triangle Park, NC). Reports on analyses performed in support of the DBP studies are on file at the National Institute of Environmental Health Sciences.

The appearance, a clear liquid, and density of lot MKBB8432 (1.05 g/mL at 21.7°C) matched that of DBP (1.043 g/mL at 25°C). The boiling point of lot MKBB8432 (335°C) matched that of DBP (340°C), and elemental analysis confirmed the anticipated relative ratios; both analyses were performed by Galbraith Laboratories (Knoxville, TN). A precise molecular mass was measured using a research-grade high-resolution mass spectrometer (HRMS) at the University of South Carolina Mass Spectrometry Facility (Columbia, SC). The observed mass values (278.1514) were within acceptable limits (≤5 ppm) of the calculated mass (278.1518).

The lot was identified using infrared (IR) spectroscopy. In addition, the lot was analyzed using ^1^H and ^13^C nuclear magnetic resonance (NMR) spectroscopy and gas chromatography (GC) with mass spectrometry (MS) detection. The IR spectrum was in good agreement with the structure of DBP and with the reference spectrum of DBP from Sigma-Aldrich (Product No. 524980, accessed December 22, 2009) (Figure A-1). ^1^H and ^13^C NMR spectra were consistent with the structure of DBP and the prediction from Advanced Chemistry Development’s Spectral Prediction Program (Version 10.02, Toronto, Ontario, Canada) (Figure A-2, Figure A-3). GC/MS identified the major peak of lot MKBB8432 as DBP using fragmentation pattern and comparison with the National Institute of Standards and Technology (Gaithersburg, MD) reference spectrum (No. 312145) for DBP (Table A-1; System A).

The moisture content of lot MKBB8432 was determined by Karl Fischer titration. The purity of lot MKBB8432 was determined using ultra-performance liquid chromatography (UPLC) with photodiode array detection (PDA) and GC with flame ionization detection (FID) (Table A-1; Systems B and C, respectively). The Karl Fischer titration yielded a water content of 0.204%. UPLC analysis demonstrated one major peak accounting for 99.9% and no minor peaks >0.1% of the total integrated area, although one minor impurity (<0.1%) was observed. GC/FID analysis also found one major peak accounting for 99.9% and no minor peaks >0.1%. The overall purity of lot MKBB8432 was determined to be >99%.

Accelerated stability studies were conducted on samples of DBP by the analytical chemistry laboratory using lot 91997PJ from Sigma-Aldrich (St. Louis, MO) stored at ambient temperature (approximately 22°C), refrigerated temperature (approximately 5°C), and elevated temperature (approximately 60°C) in amber vials. After 14 days, samples were analyzed by GC/FID (Table A-1; System C). Stability of DBP was confirmed for at least 2 weeks when stored in sealed glass vials at temperatures from 5°C to 60°C. Upon receipt, the bulk chemical of lot MKBB8432 was homogenized by mixing for 15 minutes and transferred to 1-gallon amber storage bottles stored at room temperature. Periodic analyses of the bulk chemical lot MKBB8432 were performed prior to and during the animal studies by the laboratory using high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection (Table A-1; System D), and no degradation of the test chemical was detected.

## A.2 Preparation and Analysis of Dose Formulations

The base diet was meal feed purchased from Zeigler Brothers, Inc. (Gardners, PA). The 2-year rat and mouse studies used NTP-2000 feed (24 lots milled June 2010 through June 2012), whereas NIH-07 feed (two lots milled May and June 2010) also was used during the perinatal phase of the rat study. No analysis was performed on the feed beyond determining suitability for feeding the animals.

Dose formulations were prepared monthly by mixing DBP with feed (Table A-2). For the perinatal and 2-year rat study, formulations were prepared in NIH-07 feed at concentrations of 0, 300, 1,000, 3,000, and 10,000 ppm (July 8 and July 29, 2010) and in NTP-2000 feed at concentrations of 0, 300, 1,000, 3,000, and 10,000 ppm (27 formulations; August 2010 to August 2012). For the 2-year mouse study, formulations were prepared in NTP-2000 feed at concentrations of 0, 1,000, 3,000, and 10,000 ppm (27 formulations; August 2010 to August 2012).

Homogeneity studies of the 300 and 10,000 ppm dose formulations in 72 kg NIH-07 feed batch sizes, 300 ppm dose formulation in a 92 kg NTP-2000 feed batch size, and 1,000 and 10,000 ppm dose formulations in 60 kg NTP-2000 feed batch sizes were performed before the animal studies by the study laboratory using HPLC/UV (Table A-1; System D). Additional homogeneity studies for different batch sizes were performed during the 2-year studies by the study laboratory with the same HPLC/UV system: batch size of 60 kg for the 300 ppm dose formulation in NTP-2000 feed (December 2010) and batch size of 72 kg for the 10,000 ppm dose formulation in NTP-2000 feed (July 2012). All formulations analyzed were determined homogeneous and of appropriate concentration. Stability was confirmed for 42 days at room temperature (approximately 25°C).

The plastic bags used for preparation and storage of animal feed and dose formulations were analyzed for the presence of 11 different phthalates commonly found in plastics, including DBP, by the analytical chemistry laboratory at RTI International (Research Triangle Park, NC). Analysis of the extracts from plastic bags used by the study laboratory in the preparation and storage of control and dosed feed showed no DBP above the limit of detection (1.47 ppm) (Table A-1; System B). The developed method suggested no significant contribution of DBP from the plastic storage bags.

Control and treated formulations were stored in individual plastic bag-lined containers at room temperature (approximately 25°C). The formulations were used within 42 days of preparation.

Periodic analyses of the preadministration dose formulations of DBP were conducted by the study laboratory every 1 to 3 months to determine purity, whereas postadministration (animal room) samples were analyzed every 1 to 8 months (Table A-3, Table A-4). All preadministration formulations for rats and mice were within 10% of the target concentrations. In the perinatal and 2-year rat study, all postadministration barrel samples were within 10% of target concentration, except for the 10,000 ppm formulation prepared on August 9, 2010, which was 13.2% below the target concentration. Postadministration samples collected from residual feed in the feeders prepared July 8, 2010 (10,000 ppm) and August 9, 2010 (300 ppm) were 11.8% and 10.0% below the target concentrations, respectively. All other postadministration values were within 10% of the target concentration. In the 2-year mouse study, postadministration samples of the 1,000 and 10,000 ppm formulations prepared on August 9, 2010, collected from residual feed in the feeders, were up to 13.4% below the target concentrations. Additionally, the 10,000 ppm barrel sample was 13.2% below the target concentration. The postadministration barrel sample from the 10,000 ppm formulation prepared on February 21, 2011 was 12.1% below the target concentration. All other postadministration values were within 10% of the target concentration.

Table A-1 Chromatography Systems Used in the Perinatal and Two-year Feed Studies of Di-n-butyl Phthalate

Chromatography | Detection System | Column | Mobile Phase
System A
Gas chromatography | Mass selective detector | J&W DB-1 (25 m × 0.32 mm ID, 0.25 μm film thickness) | Helium, 1.65 mL/min flow rate
System B
Ultra-performance liquid chromatography | Photodiode array detector (205 to 400 nm, extracted at 225 nm) | Waters Acquity UPLC BEH Phenyl (2.1 mm ID × 50 mm, 1.7 μm particle size), with Waters Acquity In-Line Filter (0.2 μm) | A: Methanol B: Water Gradient program: A:B 25:75 to 75:25 in 3 min, hold at 78:22 for 1 min, ramp to 100:0 in 1 min, hold at 100:0 for 1 min, reverse to 25:75 in 0.5 min, hold at 25:75 for 1.5 min 0.6 mL/min flow rate
System C
Gas chromatography | Flame ionization detection (325°C) | J&W HP-5 (30 m × 0.32 mm ID, film thickness 0.25 μm) | Helium, 1 mL/min flow rate
System D
High-performance liquid chromatography | Ultraviolet (225 nm) | Thermo Scientific Hypersil Phenyl (250 mm × 4.6 mm ID, 5 μm) with Hypersil Phenyl guard (5 μm), | A: Methanol B: ASTM Type I Water Gradient program: A:B 70:30 to 85:15 in 5 min, ramp to 100:0 in 4 min, hold at 100:0 for 4 min, reverse to 70:30 in 0.1 min, hold at 70:30 for 10.9 min 1.0 mL/min flow rate

UPLC = ultra-performance liquid chromatography; BEH = Ethylene Bridged Hybrid; ID = internal diameter; ATSM = American Society for Testing and Materials.

Table A-2 Preparation and Storage of Dose Formulations in the Perinatal and Two-year Feed Studies of Di-n-butyl Phthalate

Preparation
Stock solutions of di-n-butyl phthalate were created by weighing an appropriate amount of lot MKBB8432 and adding it to a volumetric flask. Acetone was used to bring the solution to volume. Flasks of stock solutions were sealed and shaken until the chemical was dissolved (at least 10 inversions). An initial formulation premix was created by weighing an appropriate amount of feed (NIH-07 or NTP-2000) into a mixing bowl. The stock di-n-butyl phthalate solution was slowly poured onto the feed while the mixture was stirred using a Hobart mixer. The premix formulations were mixed for approximately 1 hour and acetone was used twice to rinse the sides of the bowl and incorporate any residuals. The entire procedure was conducted under a nitrogen stream to encourage cyclonic flow and ensure acetone fully evaporated. In a twin shell blender, half the remaining untreated feed was evenly covered with the premix. The sides were “rinsed” with the remaining untreated feed in two increments. The final formulation was mixed in the blender for 15 minutes. The dose formulations were prepared approximately every 4 weeks.
Chemical Lot Number
MKBB8432
Maximum Storage Time
42 days
Storage Conditions
Stored in sealed plastic bag-lined container at ~25°C
Study Laboratory
Battelle (Columbus, OH)

Table A-3 Results of Analyses of Dose Formulations Administered to Rats in the Perinatal and Two-year Feed Study of Di-n-butyl Phthalate

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
July 8, 2010 | July 9, 2010 | 0 | BLOQ | NA
July 8, 2010 | July 9, 2010 | 300 | 288 ± 10 | −4.0
July 8, 2010 | July 9, 2010 | 1,000 | 970 ± 10 | −3.0
July 8, 2010 | July 9, 2010 | 3,000 | 2,910 ± 80 | −3.0
July 8, 2010 | July 9, 2010 | 10,000 | 9,920 ± 500 | −0.8
August 9, 2010 | August 10–12, 2010 | 0 | BLOQ | NA
August 9, 2010 | August 10–12, 2010 | 300 | 304 ± 2 | 1.2
August 9, 2010 | August 10–12, 2010 | 1,000 | 997.0 | −0.3
August 9, 2010 | August 10–12, 2010 | 3,000 | 2,775.0 | −7.5
August 9, 2010 | August 10–12, 2010 | 10,000 | 9,060.0 | −9.4
October 4, 2010 | October 5, 2010 | 0 | BLOQ | NA
October 4, 2010 | October 5, 2010 | 300 | 299 ± 7 | −0.5
October 4, 2010 | October 5, 2010 | 1,000 | 968.5 | −3.2
October 4, 2010 | October 5, 2010 | 3,000 | 2,875.0 | −4.2
October 4, 2010 | October 5, 2010 | 10,000 | 9,645.0 | −3.6
December 20, 2010 | December 20, 2010 | 0 | BLOQ | NA
December 20, 2010 | December 20, 2010 | 300 | 300.5 | 0.2
December 20, 2010 | December 20, 2010 | 1,000 | 1,025.0 | 2.5
December 20, 2010 | December 20, 2010 | 3,000 | 3,040.0 | 1.3
December 20, 2010 | December 20, 2010 | 10,000 | 10,650.0 | 6.5
February 21, 2011 | February 21, 2011 | 0 | BLOQ | NA
February 21, 2011 | February 21, 2011 | 300 | 304 | 1.3
February 21, 2011 | February 21, 2011 | 1,000 | 1,050.0 | 5.0
February 21, 2011 | February 21, 2011 | 3,000 | 3,045.0 | 1.5
February 21, 2011 | February 21, 2011 | 10,000 | 9,970.0 | −0.3
May 16, 2011 | May 16, 2011 | 0 | BLOQ | NA
May 16, 2011 | May 16, 2011 | 300 | 294.5 | −1.8
May 16, 2011 | May 16, 2011 | 1,000 | 976.5 | −2.4
May 16, 2011 | May 16, 2011 | 3,000 | 2,980.0 | −0.7
May 16, 2011 | May 16, 2011 | 10,000 | 9,045.0 | −9.6
August 8, 2011 | August 9, 2011 | 0 | BLOQ | NA
August 8, 2011 | August 9, 2011 | 300 | 293 | −2.3
August 8, 2011 | August 9, 2011 | 1,000 | 989.5 | −1.1
August 8, 2011 | August 9, 2011 | 3,000 | 3,015.0 | 0.5
August 8, 2011 | August 9, 2011 | 10,000 | 9,210.0 | −7.9
October 3, 2011 | October 3, 2011 | 0 | BLOQ | NA
October 3, 2011 | October 3, 2011 | 300 | 295.5 | −1.5
October 3, 2011 | October 3, 2011 | 1,000 | 990.5 | −1.0
October 3, 2011 | October 3, 2011 | 3,000 | 3,020.0 | 0.7
October 3, 2011 | October 3, 2011 | 10,000 | 9,625.0 | −3.8
November 28, 2011 | November 30, 2011 | 0 | BLOQ | NA
November 28, 2011 | November 30, 2011 | 300 | 291.5 | −2.8
November 28, 2011 | November 30, 2011 | 1,000 | 957.0 | −4.3
November 28, 2011 | November 30, 2011 | 3,000 | 2,975.0 | −0.8
November 28, 2011 | November 30, 2011 | 10,000 | 9,410.0 | −5.9
February 20, 2012 | February 21, 2012 | 0 | BLOQ | NA
February 20, 2012 | February 21, 2012 | 300 | 303.5 | 1.2
February 20, 2012 | February 21, 2012 | 1,000 | 964.5 | −3.6
February 20, 2012 | February 21, 2012 | 3,000 | 2,865.0 | −4.5
February 20, 2012 | February 21, 2012 | 10,000 | 9,500.0 | −5.0
May 14, 2012 | May 14, 2012 | 0 | BLOQ | NA
May 14, 2012 | May 14, 2012 | 300 | 295.5 | −1.5
May 14, 2012 | May 14, 2012 | 1,000 | 991.5 | −0.9
May 14, 2012 | May 14, 2012 | 3,000 | 3,035.0 | 1.2
May 14, 2012 | May 14, 2012 | 10,000 | 9,675.0 | −3.3
July 9, 2012 | July 10, 2012 | 0 | BLOQ | NA
July 9, 2012 | July 10, 2012 | 300 | 301.5 | 0.5
July 9, 2012 | July 10, 2012 | 1,000 | 1,005 | 0.5
July 9, 2012 | July 10, 2012 | 3,000 | 3,005.0 | 0.2
July 9, 2012 | July 10, 2012 | 10,000 | 9,665.0 | −3.4
Animal Room Samples
July 8, 2010 | August 17, 2010 (feeder) | 0 | BLOQ | NA
July 8, 2010 | August 17, 2010 (feeder) | 300 | 284 ± 4 | −5.3
July 8, 2010 | August 17, 2010 (feeder) | 1,000 | 923 ± 15 | −7.7
July 8, 2010 | August 17, 2010 (feeder) | 3,000 | 2,710 ± 40 | −9.8
July 8, 2010 | August 17, 2010 (feeder) | 10,000 | 8,820 ± 190 | −11.8
July 8, 2010 | August 17, 2010 (barrel) | 0 | BLOQ | NA
July 8, 2010 | August 17, 2010 (barrel) | 300 | 282 ± 3 | −6.0
July 8, 2010 | August 17, 2010 (barrel) | 1,000 | 918 ± 14 | −8.2
July 8, 2010 | August 17, 2010 (barrel) | 3,000 | 2,710 ± 30 | −9.8
July 8, 2010 | August 17, 2010 (barrel) | 10,000 | 9,050 ± 110 | −9.5
August 9, 2010 | September 15, 2010 (feeder) | 0 | BLOQ | NA
August 9, 2010 | September 15, 2010 (feeder) | 300 | 268 ± 5 | −10.7
August 9, 2010 | September 15, 2010 (feeder) | 1,000 | 900 ± 50 | −10.0
August 9, 2010 | September 15, 2010 (feeder) | 3,000 | 3,200 ± NA^b^ | 6.7
August 9, 2010 | September 15, 2010 (feeder) | 10,000 | 9,730 ± 698 | −2.7
August 9, 2010 | September 15, 2010 (barrel) | 0 | BLOQ | NA
August 9, 2010 | September 15, 2010 (barrel) | 300 | 288 ± l | −4.1
August 9, 2010 | September 15, 2010 (barrel) | 1,000 | 971 ± 25 | −2.9
August 9, 2010 | September 15, 2010 (barrel) | 3,000 | 2,940 ± 290 | −2.0
August 9, 2010 | September 15, 2010 (barrel) | 10,000 | 8,680 ± 40 | −13.2
October 4, 2010 | November 9, 2010 (feeder) | 0 | BLOQ | NA
October 4, 2010 | November 9, 2010 (feeder) | 300 | 285 ± 6 | −5.0
October 4, 2010 | November 9, 2010 (feeder) | 1,000 | 957 ± 16 | −4.3
October 4, 2010 | November 9, 2010 (feeder) | 3,000 | 2,790 ± 50.3 | −7.1
October 4, 2010 | November 9, 2010 (feeder) | 10,000 | 9,740 ± 66.6 | −2.6
October 4, 2010 | November 9, 2010 (barrel) | 0 | BLOQ | NA
October 4, 2010 | November 9, 2010 (barrel) | 300 | 284 ± 8 | −5.3
October 4, 2010 | November 9, 2010 (barrel) | 1,000 | 1,010 ± 10 | 0.6
October 4, 2010 | November 9, 2010 (barrel) | 3,000 | 2,840 ± 10 | −5.2
October 4, 2010 | November 9, 2010 (barrel) | 10,000 | 9,730 ± 230 | −2.7
February 21, 2011 | March 31, 2011 (feeder) | 0 | BLOQ | NA
February 21, 2011 | March 31, 2011 (feeder) | 300 | 292 ± 6 | −2.7
February 21, 2011 | March 31, 2011 (feeder) | 1,000 | 976 ± 6 | −2.4
February 21, 2011 | March 31, 2011 (feeder) | 3,000 | 2,930 ± 35.1 | −2.4
February 21, 2011 | March 31, 2011 (feeder) | 10,000 | 9,320 ± 337 | −6.8
February 21, 2011 | March 31, 2011 (barrel) | 0 | BLOQ | NA
February 21, 2011 | March 31, 2011 (barrel) | 300 | 298 ± l | −0.8
February 21, 2011 | March 31, 2011 (barrel) | 1,000 | 1,020 ± 10 | 1.7
February 21, 2011 | March 31, 2011 (barrel) | 3,000 | 2,990 ± 80 | −0.4
February 21, 2011 | March 31, 2011 (barrel) | 10,000 | 9,740 ± 200 | −2.6
October 3, 2011 | November 9, 2011 (feeder) | 0 | BLOQ | NA
October 3, 2011 | November 9, 2011 (feeder) | 300 | 289 ± 4 | −3.6
October 3, 2011 | November 9, 2011 (feeder) | 1,000 | 962 ± 4 | −3.8
October 3, 2011 | November 9, 2011 (feeder) | 3,000 | 2,880 ± 51.3 | −4.1
October 3, 2011 | November 9, 2011 (feeder) | 10,000 | 9,210 ± 191 | −7.9
October 3, 2011 | November 9, 2011 (barrel) | 0 | BLOQ | NA
October 3, 2011 | November 9, 2011 (barrel) | 300 | 294 ± 3 | −1.9
October 3, 2011 | November 9, 2011 (barrel) | 1,000 | 989 ± 7 | −1.1
October 3, 2011 | November 9, 2011 (barrel) | 3,000 | 3,010 ± 20 | 0.4
October 3, 2011 | November 9, 2011 (barrel) | 10,000 | 9,470 ± 420 | −5.3
May 14, 2012 | June 20, 2012 (feeder) | 0 | BLOQ | NA
May 14, 2012 | June 20, 2012 (feeder) | 300 | 290 ± 2 | −3.2
May 14, 2012 | June 20, 2012 (feeder) | 1,000 | 973 ± 9 | −2.7
May 14, 2012 | June 20, 2012 (feeder) | 3,000 | 3,010 ± 51.3 | 0.2
May 14, 2012 | June 20, 2012 (feeder) | 10,000 | 9,050 ± 90.7 | −9.5
May 14, 2012 | June 20, 2012 (barrel) | 0 | BLOQ | NA
May 14, 2012 | June 20, 2012 (barrel) | 300 | 298 ± 1 | −0.7
May 14, 2012 | June 20, 2012 (barrel) | 1,000 | 999 ± 11 | −0.1
May 14, 2012 | June 20, 2012 (barrel) | 3,000 | 3,020 ± 50 | 0.8
May 14, 2012 | June 20, 2012 (barrel) | 10,000 | 9,210 ± 70 | −7.9

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Preadministration samples are an average of triplicate analysis on two preparations from the same sample or an average and standard deviation of triplicate analysis of a single sample. Animal room samples are an average and standard deviation of triplicate analysis of a single sample.

^b^ Third replicate value Q-tested out, so standard deviation was not calculated. Precision of duplicates (POD) was 1.00.

Table A-4 Results of Analyses of Dose Formulations Administered to Mice in the Two-year Feed Study of Di-n-butyl Phthalate

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration (ppm)^a^ | Difference from Target (%)
August 9, 2010 | August 10–12, 2010 | 0 | BLOQ | NA
August 9, 2010 | August 10–12, 2010 | 1,000 | 997.0 | −0.3
August 9, 2010 | August 10–12, 2010 | 3,000 | 2,775.0 | −7.5
August 9, 2010 | August 10–12, 2010 | 10,000 | 9,060.0 | −9.4
October 4, 2010 | October 5, 2010 | 0 | BLOQ | NA
October 4, 2010 | October 5, 2010 | 1,000 | 968.5 | −3.2
October 4, 2010 | October 5, 2010 | 3,000 | 2,875.0 | −4.2
October 4, 2010 | October 5, 2010 | 10,000 | 9,645.0 | −3.6
December 20, 2010 | December 20, 2010 | 0 | BLOQ | NA
December 20, 2010 | December 20, 2010 | 1,000 | 1,025.0 | 2.5
December 20, 2010 | December 20, 2010 | 3,000 | 3,040.0 | 1.3
December 20, 2010 | December 20, 2010 | 10,000 | 10,650.0 | 6.5
February 21, 2011 | February 21, 2011 | 0 | BLOQ | NA
February 21, 2011 | February 21, 2011 | 1,000 | 1,050.0 | 5.0
February 21, 2011 | February 21, 2011 | 3,000 | 3,045.0 | 1.5
February 21, 2011 | February 21, 2011 | 10,000 | 9,970.0 | −0.3
May 16, 2011 | May 16, 2011 | 0 | BLOQ | NA
May 16, 2011 | May 16, 2011 | 1,000 | 976.5 | −2.4
May 16, 2011 | May 16, 2011 | 3,000 | 2,980.0 | −0.7
May 16, 2011 | May 16, 2011 | 10,000 | 9,045.0 | −9.6
August 8, 2011 | August 9, 2011 | 0 | BLOQ | NA
August 8, 2011 | August 9, 2011 | 1,000 | 989.5 | −1.1
August 8, 2011 | August 9, 2011 | 3,000 | 3,015.0 | 0.5
August 8, 2011 | August 9, 2011 | 10,000 | 9,210.0 | −7.9
October 3, 2011 | October 3, 2011 | 0 | BLOQ | NA
October 3, 2011 | October 3, 2011 | 1,000 | 990.5 | −1.0
October 3, 2011 | October 3, 2011 | 3,000 | 3,020.0 | 0.7
October 3, 2011 | October 3, 2011 | 10,000 | 9,625.0 | −3.8
November 28, 2011 | November 30, 2011 | 0 | BLOQ | NA
November 28, 2011 | November 30, 2011 | 1,000 | 957.0 | −4.3
November 28, 2011 | November 30, 2011 | 3,000 | 2,975.0 | −0.8
November 28, 2011 | November 30, 2011 | 10,000 | 9,410.0 | −5.9
February 20, 2012 | February 21, 2012 | 0 | BLOQ | NA
February 20, 2012 | February 21, 2012 | 1,000 | 964.5 | −3.6
February 20, 2012 | February 21, 2012 | 3,000 | 2,865.0 | −4.5
February 20, 2012 | February 21, 2012 | 10,000 | 9,500.0 | −5.0
May 14, 2012 | May 14, 2012 | 0 | BLOQ | NA
May 14, 2012 | May 14, 2012 | 1,000 | 991.5 | −0.9
May 14, 2012 | May 14, 2012 | 3,000 | 3,035.0 | 1.2
May 14, 2012 | May 14, 2012 | 10,000 | 9,675.0 | −3.3
July 9, 2012 | July 10, 2012 | 0 | BLOQ | NA
July 9, 2012 | July 10, 2012 | 1,000 | 1,005.0 | 0.5
July 9, 2012 | July 10, 2012 | 3,000 | 3,005.0 | 0.2
July 9, 2012 | July 10, 2012 | 10,000 | 9,665.0 | −3.4
Animal Room Samples
August 9, 2010 | September 15, 2010 (feeder) | 0 | BLOQ | NA
August 9, 2010 | September 15, 2010 (feeder) | 1,000 | 866 ± NA^b^ | −13.4
August 9, 2010 | September 15, 2010 (feeder) | 3,000 | 2,830 ± 230 | −5.7
August 9, 2010 | September 15, 2010 (feeder) | 10,000 | 8,890 ± 310 | −11.1
August 9, 2010 | September 15, 2010 (barrel) | 0 | BLOQ | NA
August 9, 2010 | September 15, 2010 (barrel) | 1,000 | 971 ± 25 | −2.9
August 9, 2010 | September 15, 2010 (barrel) | 3,000 | 2,940 ± 290 | −2.0
August 9, 2010 | September 15, 2010 (barrel) | 10,000 | 8,680 ± 40 | −13.2
October 4, 2010 | November 9, 2010 (feeder) | 0 | BLOQ | NA
October 4, 2010 | November 9, 2010 (feeder) | 1,000 | 953 ± 6 | −4.7
October 4, 2010 | November 9, 2010 (feeder) | 3,000 | 2,730 ± 60 | −8.9
October 4, 2010 | November 9, 2010 (feeder) | 10,000 | 9,100 ± 120 | −9.0
October 4, 2010 | November 9, 2010 (barrel) | 0 | BLOQ | NA
October 4, 2010 | November 9, 2010 (barrel) | 1,000 | 1,010 ± 10 | 0.6
October 4, 2010 | November 9, 2010 (barrel) | 3,000 | 2,840 ± 10 | −5.2
October 4, 2010 | November 9, 2010 (barrel) | 10,000 | 9,730 ± 230 | −2.7
February 21, 2011 | March 31, 2011 (feeder) | 0 | BLOQ | NA
February 21, 2011 | March 31, 2011 (feeder) | 1,000 | 973 ± 5 | −2.7
February 21, 2011 | March 31, 2011 (feeder) | 3,000 | 2,960 ± 30 | −1.2
February 21, 2011 | March 31, 2011 (feeder) | 10,000 | 8,790 ± 50 | −12.1
February 21, 2011 | March 31, 2011 (barrel) | 0 | BLOQ | NA
February 21, 2011 | March 31, 2011 (barrel) | 1,000 | 1,020 ± 10 | 1.7
February 21, 2011 | March 31, 2011 (barrel) | 3,000 | 2,990 ± 80 | −0.4
February 21, 2011 | March 31, 2011 (barrel) | 10,000 | 9,740 ± 200 | −2.6
October 3, 2011 | November 9, 2011 (feeder) | 0 | BLOQ | NA
October 3, 2011 | November 9, 2011 (feeder) | 1,000 | 973 ± 4 | −2.7
October 3, 2011 | November 9, 2011 (feeder) | 3,000 | 2,840 ± 70 | −5.4
October 3, 2011 | November 9, 2011 (feeder) | 10,000 | 9,260 ± 120 | −7.4
October 3, 2011 | November 9, 2011 (barrel) | 0 | BLOQ | NA
October 3, 2011 | November 9, 2011 (barrel) | 1,000 | 989 ± 7 | −1.1
October 3, 2011 | November 9, 2011 (barrel) | 3,000 | 3,010 ± 20 | 0.4
October 3, 2011 | November 9, 2011 (barrel) | 10,000 | 9,470 ± 420 | −5.3
May 14, 2012 | June 20, 2012 (feeder) | 0 | BLOQ | NA
May 14, 2012 | June 20, 2012 (feeder) | 1,000 | 993 ± 8 | −0.7
May 14, 2012 | June 20, 2012 (feeder) | 3,000 | 2,990 ± 20 | −0.2
May 14, 2012 | June 20, 2012 (feeder) | 10,000 | 9,240 ± 100 | −7.6
May 14, 2012 | June 20, 2012 (barrel) | 0 | BLOQ | NA
May 14, 2012 | June 20, 2012 (barrel) | 1,000 | 999 ± 11 | −0.1
May 14, 2012 | June 20, 2012 (barrel) | 3,000 | 3,020 ± 50 | 0.8
May 14, 2012 | June 20, 2012 (barrel) | 10,000 | 9,210 ± 70 | −7.9

BLOQ = below the limit of quantification; NA = not applicable.

^a^ Preadministration samples are an average of triplicate analysis on two preparations from the same sample. Animal room samples are an average and standard deviation of triplicate analysis of a single sample.

^b^ Third replicate value Q-tested out, so standard deviation was not calculated. Precision of duplicates (POD) was 1.01.

Figure A-1

Reference Fourier Transformed Infrared Absorption Spectrum of Di-n-butyl Phthalate

Reference spectra: Sigma-Aldrich Product No. 524980, https://www.sigmaaldrich.com/spectra/ftir/FTIR001338.PDF (accessed Dec 22, 2009).

Figure A-2

^1^H NMR Spectrum of Sample of Di-n-butyl Phthalate (Lot MKBB8432)

Reference spectra: Sigma-Aldrich Product No. 524980, https://www.sigmaaldrich.com/spectra/fnmr/FNMR001553.PDF (accessed Dec 22, 2009).

Figure A-3

^13^C NMR Spectrum of Sample of Di-n-butyl Phthalate (Lot MKBB8432)

Sigma-Aldrich Product No. 524980, https://www.sigmaaldrich.com/spectra/fnmr/FNMR001553.PDF (accessed Dec 22, 2009).