# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-599

Report Series: NTP Technical Report Series

Report Series Number: 599

Official citation: National Toxicology Program (NTP). 2021. NTP technical report on the toxicology and carcinogenesis studies of sodium tungstate dihydrate (CASRN 10213-10-2) in Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats and B6C3F1/N mice (drinking water studies). Research Triangle Park, NC: National Toxicology Program. Technical Report 599.