# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed studies, evaluated and interpreted results, and reported findings
  M. Behl, Ph.D., Study Scientist
  C.R. Blystone, Ph.D.
  M.F. Cesta, D.V.M., Ph.D.
  M.C. Cora, D.V.M.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D. (Retired)
  B.S. McIntyre, Ph.D.
  E. Mutlu, Ph.D.
  G.K. Roberts, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.E. Brix, D.V.M., Ph.D., Study Pathologist
- Coordinated NTP Pathology Working Groups on perinatal and 2-year rats (April 3, 2018) and on 2-year mice (May 3, 2018)
  K.Y. Cimon, D.V.M. (Rats)
  E.M. Quist, D.V.M., Ph.D. (Mice)
- Battelle, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  B.R. Sparrow, Ph.D., Principal Investigator
  C.M. Briscoe, D.V.M.
  M.A. Buccellato, D.V.M., Ph.D.
  D.M. Fallacara, Ph.D.
  L.M. Fomby, D.V.M., Ph.D.
  M.J. Ryan, D.V.M., Ph.D.
  A.W. Singer, D.V.M.
  A.J. Skowronek, D.V.M., Ph.D.
- Conducted prestart chemistry activities, dose formulations, and biological sample chemistry analyses
  B.L. Burback, Ph.D., Principal Investigator
  W.M. Black, B.S.
  K.A. Carrico, B.A.
  D.A. Contos, M.S.
  T.A. Cristy, B.A.
  J.S. Richey, B.S.
  N.L. South, B.S.
- RTI International, Research Triangle Park, North Carolina, USA
  Provided sperm count and vaginal cytology evaluation (SCVCE) analysis
  C.S. Sloan, M.S.
  R.W. Tyl, Ph.D.
- ASRC Federal, Research Triangle Park, North Carolina, USA
  Prepared data for report
  P. Brown, B.S.
  H. Gong, M.S.
  C. Martini, B.S.
  C. Myers, M.S.
  N. Sayers, B.S.
  M. Shaw, B.S.
  R. Whittlesey, M.S.