# References

1 Higgins ES, Richert DA, Westerfield WW. Molybdenum deficiency and tungstate inhibition studies. J Nutr. 1956; 59:539–559. 10.1093/jn/59.4.539 13357986
2 Higgins ES, Richert DA, Westerfield WW. Competitive role of tungsten in molybdenum nutrition. Fed Proc. 1956; 15:274–275.
3 Johnson JL, Cohen HJ, Rajagopalan KV. Molecular basis of the biological function of molybdenum-free sulfite oxidase from livers of tungsten-treated rats. J Biol Chem. 1974; 249:5046–5055. 10.1016/S0021-9258(19)42326-0 4368926
4 Owen EC, Proudfoot R. The effect of tungstate ingestion on xanthine oxidase in milk and liver. Br J Nutr. 1968; 22:331–340. 10.1079/BJN19680043
5 Hazardous Substances Data Bank (HSDB). Sodium tungstate CASRN: 13472-45-2. Bethesda, MD: National Library of Medicine; 2009. https://hero.epa.gov/hero/index.cfm/reference/details/reference_id/2346118
6 Agency for Toxic Substances & Disease Registry (ATSDR). Toxicological profile for tungsten. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service; 2005. https://www.atsdr.cdc.gov/ToxProfiles/tp.asp?id=806&tid=157
7 Agency for Toxic Substances & Disease Registry (ATSDR). Addendum to the toxicological profile for tungsten. Atlanta, GA: U.S. Department of Health and Human Services, Public Health Service; 2015. https://www.atsdr.cdc.gov/toxprofiles/Tungsten_Addendum_508.pdf
8 Dominguez JE, Munoz MC, Zafra D, Sanchez-Perez I, Baque S, Caron M, Mercurio C, Barbera A, Perona R, Gomis R, et al. The antidiabetic agent sodium tungstate activates glycogen synthesis through an insulin receptor-independent pathway. J Biol Chem. 2003; 278(44):42785–42794. 10.1074/jbc.M308334200 12925525
9 Altirriba J, Barbera A, Del Zotto H, Badal B, Piguer S, Sanchez-Pla A, Gagliardino JJ, Gomis R. Molecular mechanisms of tungstate-induced pancreatic plasticity: A transcriptomics approach. BMC Genomics. 2009; 10:406. 10.1186/1471-2164-10-406 19715561
10 Bertinat R, Nualart F, Li X, Yanez AJ, Gomis R. Preclinical and clinical studies for sodium tungstate: Application in humans. J Clin Cell Immunol. 2015; 6(1):285. 25995968
11 National Institute for Occupational Safety and Health (NIOSH). Tungsten. U.S. Department of Health and Human Services, Public Health Service, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2011. https://www.cdc.gov/niosh/pel88/7440-33s.html
12 U.S. Environmental Protection Agency (USEPA). Technical fact sheet-tungsten. 2017. https://www.epa.gov/sites/production/files/2017-10/documents/ffrro_ecfactsheet_tungsten_9-15-17_508.pdf
13 McDonald JD, Weber WM, Marr R, Kracko D, Khain H, Arimoto R. Disposition and clearance of tungsten after single-dose oral and intravenous exposure in rodents. J Toxicol Environ Health A. 2007; 70(10):829–836. 10.1080/15287390701211762 17454559
14 Weber WM, Marr R, Kracko D, Gao Z, McDonald JD, Chearnaigh KU. Disposition of tungsten in rodents after repeat oral and drinking water exposures. Toxicologial & Environmental Chemistry. 2008; 90(3):445-455. 10.1080/02772240701565891 10.1080/02772240701565891
15 Lagarde F, Leroy M. Metabolism and toxicity of tungsten in humans and animals. Met Ions Biol Syst. 2002; 39:741–759. 10.1201/9780203909331.ch22 11913143
16 Bowen HJM. The elemental content of human diets and excreta In: Bowen HJM, Berrow ML, Burton JD, Cawse PA, Patterson DSP, Statham PJ, Ure AM, editors. Environmental Chemistry, Vol 2 A Review of the Literature Published up to mid-1980. London: The Royal Society of Chemistry, Burlington House; 1982. p. 70-93. 10.1039/9781847555991-00070 10.1039/9781847555991-00070
17 Friberg L, Nordberg GR. Handbook on the Toxicology of Metals. New York, NY: Elsevier North Holland; 1979.
18 Nadeenko VG. Maximum permissible concentrations of tungsten in water basins. Hyg Sanit. 1966; 31:197–203.
19 Fernandez-Alvarez J, Zapatero J, Pifiol C. Acute oral and intravenous toxicity of sodium tungstate: A potential agent to treat diabetes mellitus. Abstracts of the Symposium on the Insulinomimetic Effects of Metal Ions: Potential Therapy for Diabetes Mellitus Sitges, Spain. 2000a:24.
20 McCain WC, Crouse LC, Bazar MA, Roszell LE, Leach GJ, Middleton JR, Reddy G. Subchronic oral toxicity of sodium tungstate in Sprague-Dawley rats. Int J Toxicol. 2015; 34(4):336–345. 10.1177/1091581815585568 26023051
21 Hazardous Substances Data Bank (HSDB). Sodium tungstate. HSDB No. 5057. Bethesda, MD: National Library of Medicine (NLM); 2002.
22 Fernandez-Alvarez J, Zapatero J, Pinol C. Subacute and subchronic sodium tungstate toxicity studies. Abstracts of the Symposium on the Insulinomimetic Effects of Metal Ions: Potential Therapy for Diabetes Mellitus Sitges, Spain. 2000b:25.
23 Domingo JL. Vanadium and tungsten derivatives as antidiabetic agents: A review of their toxic effects. Biol Trace Elem Res. 2002; 88(2):97–112. 10.1385/BTER:88:2:097 12296430
24 Registry of Toxic Effects of Chemical Substances (RTECS). Tungstic acid, disodium salt. RTECS No. YO7875000. Last updated in December 2000. Cincinnati, OH: National Institute for Occupational Safety and Health (NIOSH); 2002.
25 Frawley RP, Smith MJ, White KL Jr, Elmore SA, Herbert R, Moore R, Staska LM, Behl M, Hooth MJ, Kissling GE, et al. Immunotoxic effects of sodium tungstate dihydrate on female B_6_C_3_F_1_/N mice when administered in drinking water. J Immunotoxicol. 2016; 13(5):666–675. 10.3109/1547691X.2016.1154118 27223060
26 Schroeder HA, Mitchener M. Life-term studies in rats: Effects of aluminum, barium, beryllium, and tungsten. J Nutr. 1975; 105(4):421–427. 10.1093/jn/105.4.421 1113208
27 Sato K, Ichimasa M, Miyahara K, Shiomi M, Nishimura Y, Ichimasa Y. Radioprotective effects of sodium tungstate on hematopoietic injurt by exposure to 60Co gamma-rays in Wistar rats. J Radiat Res (Tokyo). 1999; 40(2):101–113. 10.1269/jrr.40.101 10494142
28 American Conference of Government Industrial Hygienists (ACGIH). Tungsten. Threshold limit values for chemical substances and physical agents and biological exposure indices. Cincinnati, OH; 1991.
29 Wide M. Effect of short-term exposure to five industrial metals on the embryonic and fetal development of the mouse. Environ Res. 1984; 33(1):47–53. 10.1016/0013-9351(84)90007-0 6692813
30 Nadeenko VG, Lenchenko VG, Oschepkova AN. New data for standardization of tungsten and molybdenum in their separate and sim ultaneous presence in water bodies. Gig Sanit. 1978; 3:7–11.
31 McInturf SM, Bekkedal MY, Wilfong E, Arfsten D, Chapman G, Gunasekar PG. The potential reproductive, neurobehavioral and systemic effects of soluble sodium tungstate exposure in Sprague-Dawley rats. Toxicol Appl Pharmacol. 2011; 254(2):133–137. 10.1016/j.taap.2010.04.021 21296100
32 DiPaolo JA, Casto BC. Quantitative studies of in vitro morphological transformation of Syrian hamster cells by inorganic metal salts. Cancer Res. 1979; 39(3):1008–1013. 427740
33 Larramendy ML, Popescu NC, DiPaolo JA. Induction by inorganic metal salts of siter chromatid exchanges and chromosome aberrations in human and Syrian hamster cell strains. Environ Mol Mutagen. 1981; 3(6):597–606. 10.1002/em.2860030602
34 Lemus R, Venezia CF. An update to the toxicological profile for water-soluble and sparingly soluble tungsten substances. Crit Rev Toxicol. 2015; 45(5):388–411. 10.3109/10408444.2014.1003422 25695728
35 Kelly AD, Lemaire M, Young YK, Eustache JH, Guilbert C, Molina MF, Mann KK. In vivo tungsten exposure alters B-cell development and increases DNA damage in murine bone marrow. Toxicol Sci. 2013; 131(2):434–446. 10.1093/toxsci/kfs324 23152188
36 Barbera A, Gomis RR, Prats N, Rodriguez-Gil JE, Domingo M, Gomis R, Guinovart JJ. Tungstate is an effective antidiabetic agent in streptozotocin-induced diabetic rats: A long-term study. Diabetologia. 2001; 44(4):507–513. 10.1007/s001250100479 11357483
37 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
38 Boorman GA, Montgomery CA Jr, Eustis SL, Wolfe MJ, McConnell EE, Hardisty JF. Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA, Weisburger EK, editors. Handbook of Carcinogen Testing. Park Ridge, NJ: Noyes Publications; 1985. p. 345–357.
39 Boorman GA, Haseman JK, Waters MD, Hardisty JF, Sills RC. Quality review procedures necessary for rodent pathology databases and toxicogenomic studies: The National Toxicology Program experience. Toxicol Pathol. 2002; 30(1):88–92. 10.1080/01926230252824752 11890481
40 Brix AE, Hardisty JF, McConnell EE. Combining neoplasms for evaluation of rodent carcinogenesis studies In: Hsu C-H, Stedeford T, editors. Cancer Risk Assessment. Hoboken, NJ: John Wiley & Sons, Inc.; 2010. p. 10.1002/9780470622728.ch28 10.1002/9780470622728.ch28
41 Kaplan EL, Meier P. Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
42 Tarone RE. Tests for trend in life table analysis. Biometrika. 1975; 62(3):679–690. 10.1093/biomet/62.3.679
43 Cox DR. Regression models and life-tables. J R Stat Soc B. 1972; 34(2):187–202.
44 Bailer AJ, Portier CJ. Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
45 Piegorsch W, Bailer AJ. Statistics for environmental biology and toxicology. Section 6.3.2. London, England: CRC Press; 1997.
46 Portier CJ, Bailer AJ. Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
47 Portier CJ, Hedges JC, Hoel DG. Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiemnts. Cancer Res. 1986; 46(9):4372–4378. 3731095
48 Bieler GS, Williams RL. Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
49 Nam JM. A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987; 43(3):701–705. 10.2307/2532006 3663825
50 Rao JN, Scott AJ. A simple method for the analysis of clustered binary data. Biometrics. 1992; 48(2):577–585. 10.2307/2532311 1637980
51 Fung KY, Krewski D, Rao JN, Scott AJ. Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994; 14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
52 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
53 Dixon WJ, Massey FJ Jr. Introduction to Statistical Analysis. New York, NY: McGraw-Hill Book Company; 1957. 10.2307/2332898
54 Tukey J. Easy summaries-numerical and graphical. Exploratory Data Analysis. Reading, MA: Addison-Wesley; 1977. p. 43–44.
55 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
56 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
57 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
58 Shirley E. A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
59 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
60 Dunn OJ. Multiple comparison using RANK sums. Technometrics. 1964; 6:241–252. 10.1080/00401706.1964.10490181
61 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1-2):133–145. 10.1093/biomet/41.1-2.133
62 Hsu JC. The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168.
63 Davison AC, Hinkley DV. Bootstrap Methods and Their Application. Cambridge Univ. Press; 1997. 10.1017/CBO9780511802843
64 Datta S, Satten GA. Rank-sum tests for clustered data. J Am Stat Assoc. 2005; 100:908–915. 10.1198/016214504000001583
65 Hommel G. A stagewise rejective multiple test procedure based on a modified Bonferroni test. Biometrika. 1988; 75(2):383–386. 10.1093/biomet/75.2.383
66 Haseman JK. Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200. 10.1177/009286159202600210
67 Haseman JK. Data analysis: Statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995; 21(1):52–59, discussion 81–56. 10.1006/rtph.1995.1009 7784636
68 Haseman JK, Rao GN. Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
69 Code of Federal Regulations (CFR). 21(Part 58).
70 Miller JA, Miller EC. Ultimate chemical carcinogens as reactive mutagenic electrophiles. In: Hiatt HH, Watson JD, Winsten JA, editors. Origins of Human Cancer. Spring Harbor, NY: Cold Spring Harbor Laboratory; 1977. p. 605–627.
71 Straus DS. Somatic mutation, cellular differentiation, and cancer causation. J Natl Cancer Inst. 1981; 67:233–241. 7021938
72 Crawford BD. Perspectives on the somatic mutation model of carcinogenesis. In: Mehlman MA, Flamm WG, Lorentzen RJ, editors. Advances in Modern Environmental Toxicology Mechanisms and Toxicity of Chemical Carcinogens and Mutagens. Princeton, NJ: Princeton Scientific Publishing Co. Inc; 1985. p. 13–59.
73 Ashby J, Tennant RW. Definitive relationships among chemical structure, carcinogenicity and mutagenicity for 301 chemicals tested by the US NTP. Mutat Res. 1991; 257(3):229–306. 10.1016/0165-1110(91)90003-E 1707500
74 Tennant RW, Margolin BH, Shelby MD, Zeiger E, Haseman JK, Spalding J, Caspary W, Resnick M, Stasiewicz S, Anderson B. Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. 10.1126/science.3554512 3554512
75 Zeiger E, Haseman JK, Shelby MD, Margolin BH, Tennant RW, Holden H. Evaluation of four in vitro genetic toxicity tests for predicting rodent carcinogenicity: Confirmation of earlier results with 41 additional chemicals. Environ Mol Mutag. 1990; 16(S18):1-14. 10.1002/em.2850160502 10.1002/em.2850160502
76 Schmid W. The micronucleus test. Mutation Research/Environmental Mutagenesis and Related Subjects. 1975; 31(1):9-15. 10.1016/0165-1161(75)90058-8 10.1016/0165-1161(75)90058-8
77 Heddle JA, Hite M, Kirkhart B, Mavournin K, MacGregor JT, Newell GW, Salamone MF. The induction of micronuclei as a measure of genotoxicity: A report of the U.S. environmental protection agency Gene-Tox program. Mutat Res Rev Mutat Res. 1983; 123(1):61–118. 6888413
78 Shelby MD, Erexson GL, Hook GJ, Tice RR. Evaluation of a three-exposure mouse bone marrow micronucleus protocol: Results with 49 chemicals. Environ Mol Mutagen. 1993; 21:160–179. 10.1002/em.2850210210 8444144
79 Shelby MD, Witt KL. Comparison results from mouse bone marrow chromosome aberration and micronucleus tests. Environ Mol Mutagen. 1995; 25:302–313. 10.1002/em.2850250407 7607185
80 Witt KL, Knapton A, Wehr CM, Hook GJ, Mirsalis J, Shelby MD, MacGregor JT. Micronucleated erythrocyte frequency in peripheral blood of B6C3F1 mice from short-term, prechronic, and chronic studies of the NTP Carcinogenesis Bioassay Program. Environ Mol Mutagen. 2000; 36:163-194. 10.1002/1098-2280(2000)36:3<163:AID-EM1>3.0.CO;2-P10.1002/1098-2280(2000)36:3
81 Organisation for Economic Cooperation and Development (OECD). OECD guideline for the testing of chemicals. In vivo mammalian alkaline comet assay. Paris, France: OECD Publishing; 2016. Testing Guideline 489. https://www.oecd.org/env/test-no-489-in-vivo-mammalian-alkaline-comet-assay-9789264264885-en.htm
82 Tice RR, Agurell E, Anderson D, Burlinson B, Hartmann A, Kobayashi H, Miyamae Y, Rojas E, Ryu JC, Sasaki YF. Single cell gel/comet assay: Guidelines for in vitro and in vivo genetic toxicology testing. Environ Mol Mutagen. 2000; 35(3):206-221. 10.1002/(sici)1098-2280(2000)35:3<206:aid-em8>3.0.co;2-j10.1002/(sici)1098-2280(2000)35:3
83 Collins AR. The comet assay for DNA damage and repair: Principles, applications, and limitations. Mol Biotechnol. 2004; 26(3):249–261. 10.1385/MB:26:3:249 15004294
84 Brendler-Schwaab S, Hartmann A, Pfuhler S, Speit G. The in vivo comet assay: Use and status in genotoxicity testing. Mutagenesis. 2005; 20(4):245–254. 10.1093/mutage/gei033 15899933
85 Burlinson B, Tice RR, Speit G, Agurell E, Brendler-Schwaab SY, Collins AR, Escobar P, Honma M, Kumaravel TS, Nakajima M, et al. Fourth International Workgroup on Genotoxicity testing: Results of the in vivo comet assay workgroup. Mutat Res. 2007; 627(1):31–35. 10.1016/j.mrgentox.2006.08.011 17118697
86 Pfuhler S, Wolf HU. Detection of DNA-crosslinking agents with the alkaline comet assay. Environ Mol Mutagen. 1996; 27(3):196-201. 10.1002/(sici)1098-2280(1996)27:3<196:Aid-em4>3.0.Co;2-d10.1002/(sici)1098-2280(1996)27:3
87 Hartmann A, Agurell E, Beevers C, Brendler-Schwaab S, Burlinson B, Clay P, Collins A, Smith A, Speit G, Thybaud V, et al. Recommendations for conducting the in vivo alkaline comet assay. 4th International Comet Assay Workshop. Mutagenesis. 2003; 18(1):45–51. 10.1093/mutage/18.1.45 12473734
88 National Toxicology Program (NTP). TR-599: Pathology tables, survival and growth curves from NTP short-term, long-term, and genetic toxicology studies. Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institute of Environmental Health Sciences, National Toxicology Program; 2020. 10.22427/NTP-DATA-TR-599 10.22427/NTP-DATA-TR-599
89 Everds NE, Snyder PW, Bailey KL, Bolon B, Creasy DM, Foley GL, Rosol TJ, Sellers T. Interpreting stress responses during routine toxicity studies: A review of the biology, impact, and assessment. Toxicol Pathol. 2013; 41(4):560–614. 10.1177/0192623312466452 23475558
90 Seely JC, Brix A. Kidney, renal tubule-regeneration.; 2014. https://ntp.niehs.nih.gov/nnl/urinary/kidney/rtregen/index.htm [accessed 3 April 2021]
91 Dixon D, Alison R, Bach U, Colman K, Foley GL, Harleman JH, Haworth R, Herbert R, Heuser A, Long G, et al. Nonproliferative and proliferative lesions of the rat and mouse female reproductive system. J Toxicol Pathol. 2014; 27(3-4 Suppl):1s-107s. 10.1293/tox.27.1S 10.1293/tox.27.1S
92 Haseman JK, Young E, Eustis SL, Hailey JR. Body weight-tumor incidence correlations in long-term rodent carcinogenicity studies. Toxicol Pathol. 1997; 25(3):256–263. 10.1177/019262339702500302 9210256
93 Centers for Disease Control and Prevention (CDC). Exposure to tungsten in three Nevada communities. Centerse for Disease Control and Prevention study results. 2003. https://www.cdc.gov/nceh/clusters/Fallon/w-summary.pdf
94 Centers for Disease Control and Prevention (CDC). Update: Community meeting on February 6, 2003. Cross-sectional exposure assessment of environmental contaminants in Churchill County, Nevada. Centers for Disease Control and Prevention study results. 2003. https://www.cdc.gov/nceh/clusters/fallon/factsheet.pdf
95 McInturf SM, Bekkedal MY, Wilfong E, Arfsten D, Gunasekar PG, Chapman GD. Neurobehavioral effects of sodium tungstate exposure on rats and their progeny. Neurotoxicol Teratol. 2008; 30(6):455–461. 10.1016/j.ntt.2008.07.003 18675901
96 Cohen HJ, Drew RT, Johnson JL, Rajagopalan KV. Molecular basis of the biological function of molybdenum: The relationship between sulfite oxidase and the acute toxicity of bisulfite and SO2. Proc Natl Acad Sci USA. 1973; 70(12):3655–3659. 10.1073/pnas.70.12.3655 4519654
97 Cohen HJ, Johnson JL, Rajagopalan KV. Molecular basis of the biological function of molybdenum. Developmental patterns of sulfite oxidase and xanthine oxidase in the rat. Arch Biochem Biophys. 1974; 164(2):440–446. 10.1016/0003-9861(74)90053-8 4376662
98 Barberà A, Fernàndez-Alvarez J, Truc A, Gomis R, Guinovart JJ. Effects of tungstate in neonatally streptozotocin-induced diabetic rats: Mechanism leading to normalization of glycaemia. Diabetologia. 1997; 40(2):143–149. 10.1007/s001250050655 9049473
99 Barberà A, Rodríguez-Gil JE, Guinovart JJ. Insulin-like actions of tungstate in diabetic rats. Normalization of hepatic glucose metabolism. J Biol Chem. 1994; 269(31):20047–20053. 10.1016/S0021-9258(17)32125-7 8051090
100 Bocca B, Mattei D, Pino A, Alimonti A. Italian network for human biomonitoring of metals: Preliminary results from two regions. Ann Ist Super Sanita. 2010; 46(3):259–265. 20847458
101 Centers for Disease Control and Prevention (CDC). National report on human exposure to environmental chemicals. 2019. https://www.cdc.gov/exposurereport/
102 Witt KL, Livanos E, Kissling GE, Torous DK, Caspary W, Tice RR, Recio L. Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
103 Dertinger SD, Camphausen K, Macgregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T, et al. Three-color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutagen. 2004; 44(5):427–435. 10.1002/em.20075 15517570
104 Kissling GE, Dertinger SD, Hayashi M, MacGregor JT. Sensitivity of the erythrocyte micronucleus assay: Dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117
105 Recio L, Kissling GE, Hobbs CA, Witt KL. Comparison of Comet assay dose-response for ethyl methanesulfonate using freshly prepared versus cryopreserved tissues. Environ Mol Mutagen. 2012; 53(2):101–113. 10.1002/em.20694 22069077