# Conclusions

Under the conditions of these 2-year drinking water studies, there was no evidence of carcinogenic activity of sodium tungstate dihydrate (ST) in male Hsd:Sprague Dawley^®^ SD^®^ rats at exposure concentrations of 250, 500, or 1,000 mg/L. There was equivocal evidence of carcinogenic activity of ST in female Hsd:Sprague Dawley^®^ SD^®^ rats based on increased incidences of C-cell adenoma or carcinoma (combined) of the thyroid gland.

There was equivocal evidence of carcinogenic activity of ST in male B6C3F1/N mice based on the occurrences of renal tubule adenoma or carcinoma (combined) in exposed animals. There was no evidence of carcinogenic activity of ST in female B6C3F1/N mice at exposure concentrations of 500, 1,000, or 2,000 mg/L.

Exposure to ST in drinking water caused increased incidences of nonneoplastic lesions in the kidney of male and female rats and mice, in the uterus of female rats, in the large intestine of male and female mice, and in the testes of male mice.