# Discussion

Tungsten was nominated to the National Toxicology Program (NTP) by the Centers for Disease Control and Prevention for toxicity and carcinogenicity studies due to inadequate data on effects in humans and concern about potential human exposure via drinking water.^93,94^ Tungstate (WO_4_^2-^) is the most common of the naturally occurring forms of soluble tungsten; sodium tungstate dihydrate (ST) was selected for these studies because it is the most water-soluble form of tungstate.

In the current perinatal and 3-month rat study, no exposure-related effects were noted on pregnancy status, maternal survival, or the number of dams that littered at any of the exposure concentrations tested. There were significant decreases in the mean body weights of dams in the 1,000 and 2,000 mg/L groups (approximately 10% and 18%, respectively) at the end of lactation. The mean body weights of pups (male and female combined) on postnatal day 21 in the 2,000 mg/L group were also significantly decreased by approximately 14%. There were no ST-related findings in the testes or epididymides, or changes in sperm parameters in either rat or mouse after 3 months of exposure. A previous study of Sprague Dawley rats exposed daily to ST at 5 or 125 mg/kg/day by gavage for 70 days (including through mating, gestation, and lactation) similarly found no reproductive effects.^95^

In the 3-month drinking water studies, the kidney was the major target organ of toxicity in both rats and mice. In rats, renal tubule regeneration was increased in the male and female 1,000 and 2,000 mg/L groups; the increases in the 2,000 mg/L groups were significant. Renal tubule regeneration was distinct from chronic progressive nephropathy (CPN), which had similar incidences and severities between exposed and vehicle control groups. Renal tubule regeneration was also significantly increased in 1,000 and 2,000 mg/L male mice. In female mice, although there was a significant positive trend, there were no pairwise significant differences between vehicle control animals and exposed animals, indicating sex-related differences in ST sensitivity in mice.

The urine xanthine/creatinine ratios were significantly increased in all the male and female rat groups at 13 weeks. This finding was not unexpected as ST has been shown to antagonize the normal metabolic action of molybdate in its role as a cofactor for several enzymes, including xanthine oxidase.^1,96,97^ Xanthine oxidase catalyzes the oxidation of xanthine to uric acid; thus, inhibition of this enzyme can lead to increases of xanthine in the urine.^1^

Serum insulin concentrations were also measured in the perinatal and 3-month rat study. Serum insulin concentrations were significantly decreased in the high-exposure male group whereas serum glucose was unchanged. Studies have shown that ST has antidiabetic effects in rats in that when administered to streptozotocin-induced (STZ) diabetic rats, serum glucose normalizes without changes to the serum insulin concentrations.^98,99^ In these same studies, both glucose and insulin concentrations were unchanged when ST was administered to healthy rats. These studies suggest that in STZ diabetic rats, serum glucose is lowered in part due to ST’s ability to restore hepatic glucose metabolism by increasing the capacity of the liver to use glucose through glycolysis and glycogenesis. The effects have previously been shown to occur through an insulin receptor-independent pathway.^8^ Given the known effects of tungstate on glucose metabolism, the finding of decreased insulin was unexpected; the reason for this finding in the current study is not known.

Significant decreases noted in body weight gain in rat dams during the lactation phase, and reductions in final mean body weight in weaned pups, informed the decision to lower the top exposure concentration in rats to 1,000 mg/L in the chronic studies and to expose mice up to 2,000 mg/L.

In the perinatal and 2-year rat study, no exposure-related effects were noted on pregnancy status, maternal survival, or the number of dams that littered at any of the exposure concentrations tested (up to approximately 143 mg/kg/day). These findings are consistent with previous findings in the literature, which showed no reproductive effects in Sprague Dawley rats exposed to ST at 5 or 125 mg/kg/day.^95^

At study termination, an approximately 22% reduction in mean body weight was observed in the 1,000 mg/L female rats compared to the vehicle control group. Mean body weights of all groups of exposed males were within 10% of the vehicle control group. Mean water consumption was reduced by approximately 16% in the 1,000 mg/L males; in all other groups it was within 10% of the vehicle control group.

In the chronic studies, female rats in the 500 mg/L group had a significant increase in the incidence of thyroid C-cell adenomas compared to the vehicle control group, and there was a doubling of the incidence of C-cell adenomas in the 250 and 500 mg/L groups compared to that seen in the vehicle control group. Although there was no significant difference between the combined incidences of C-cell adenoma or carcinoma in the exposed groups when compared to the control group, the incidences in the 250 and 500 mg/L groups were above the historical control range. The highest incidence of C-cell carcinomas was found in the 1,000 mg/L group, and there was an earlier onset of C-cell neoplasms in exposed groups compared to the vehicle control group. However, C-cell neoplasms are a fairly common background tumor in Sprague Dawley rats, with a historical control range of up to 24% for adenomas and 28% for adenomas and carcinomas combined. There were no significant differences of C-cell hyperplasia in female rats between exposed groups and the vehicle control group, nor were there any significant differences between exposed and vehicle control male rats in the incidences of C-cell lesions. Therefore, NTP concluded that there was equivocal evidence of carcinogenic activity based on the incidences of C-cell adenoma or carcinoma (combined) in female rats; this was driven primarily by the adenomas.

Similar to the 3-month studies, the kidney was confirmed as a target organ of toxicity in both male and female rats following chronic exposure to ST. Suppurative inflammation of the renal tubules was significantly increased in the 1,000 mg/L males and females. Renal tubule regeneration was significantly increased in the 1,000 mg/L females but was not observed in male rats. By the end of the chronic study, the CPN of moderate to marked severity present in male rats made it challenging to distinguish changes of renal tubule regeneration from those seen with CPN. Given the findings in the 3-month study and the findings in the female rats, the renal tubular epithelium is likely a target of ST in both male and female rats. Despite the observation of renal tubule regeneration at 3 months, there was no progression to renal tubule neoplasms at 2 years. Consistent with the nephrotoxicity, kidney tungsten concentration increased with the exposure concentration and the kidney/plasma ratios were higher than 1.0 at all exposure concentrations and time points demonstrating retention of tungsten in the kidney.

Exposure to ST for 2 years also resulted in a significantly increased incidence of atypical hyperplasia in the uterus of female rats in the 500 mg/L group. The incidences of atypical hyperplasia were greater than that of the vehicle control group, but not significantly so, in the 250 and 1,000 mg/L groups. Atypical hyperplasia in the uterus is considered a preneoplastic finding, but neither the incidences of adenoma nor adenocarcinoma of the uterus were significantly increased in exposed groups compared to the vehicle control group.

In mice, toxicological effects included moderate reductions in final mean body weight and water consumption for males in the 2,000 mg/L group. There were no exposure-related reductions in mean body weights or water consumption for females in any of the ST-exposed groups. Daily estimated ST consumption indicated that the consumed doses of females were approximately 70% of males at a given exposure concentration. Absolute kidney weights were significantly increased in the 500 and 1,000 mg/L males compared to the vehicle control group at 3 months, however, this effect was not observed at the later interim time points.

Histologically, the kidney was a target of ST administration in mice after chronic exposure. Similar to what was seen at 3 months, renal tubule regeneration was recorded in significantly increased incidences with increasing exposure. Three renal tubule neoplasms were observed in exposed male mice; no renal tubule neoplasms occurred in vehicle control mice, and no renal tubule neoplasms were found in female mice. Although there was no statistical difference between the incidences of renal tubule neoplasms in exposed groups versus the vehicle control group, they are uncommon in mice, with only three males out of a total of 687 control male mice in the historical database having renal tubule neoplasms. Of the 13 studies that are in the current NTP historical control database for mice, all three of the renal tubular neoplasms that occurred in control animals occurred in the same study. There were no renal tubule neoplasms recorded in control animals in the other 12 studies. In this study, the findings of renal tubule neoplasms in the mid (adenoma) and high (carcinoma) exposed groups, the lack of any such neoplasms in the concurrent control group, and the fact that the kidney was a target for nonneoplastic lesions—balanced by the lack of statistical significance or a neoplastic response in the kidneys of rats or female mice—led to the conclusion that the renal tubular neoplasms in male mice were considered equivocal evidence of carcinogenic activity. Consistent with this, the kidney/plasma tungsten ratios of higher than 1 suggest retention of tungsten in the kidney.

Overall, the kidney was considered a major target organ of toxicity in rats and mice in the subchronic and chronic studies. As indicated by the tissue burden data, tungsten accumulated in the kidney in an exposure concentration-dependent manner. Some species differences in tungsten accumulation in the kidney was observed in these studies. In mice, kidney/plasma ratios (1.4–4.4) remained similar regardless of the exposure duration with no observed sex difference; however, in rats, the ratios increased with exposure duration, with male rats showing a higher ratio (1.83–2.51 at 3 months to 12.63–24.26 at 18 months) than female rats (1.17–2.06 at 3 months to 3.99–7.11 at 18 months). The general trend was toward a decreasing kidney/plasma ratio with increasing exposure concentration in both rats and mice.

Other nonneoplastic lesions observed in the chronic mouse study associated with exposure to ST included pigment in the cecum and germinal epithelium degeneration in the testes. Hence, there was evidence of systemic exposure to ST following oral administration in the drinking water based on the tissue distribution data and on toxicity in multiple tissues.

Although human biomonitoring data on tungsten concentrations in serum are relatively limited in the literature, the plasma tungsten concentration in the current studies following exposure of male rats (2.64 μg/mL) and male mice (1.27 μg/mL) to 250 ppm ST are approximately 18,000 and 8,500 times higher, respectively, compared to humans (arithmetic mean 0.15 μg/L or 0.00015 μg/mL, n = 290).^100^ Several studies have evaluated urinary tungsten concentrations in humans (summarized in Lemus et al.^34^). Urinary tungsten concentrations in male rat (104.37 μg/mg creatinine) and male mice (278.92 μg/mg creatinine) exposed to 250 ppm ST in these studies are >1,000,000 times the urinary concentrations reported by a National Health and Nutrition Examination Survey program (2015–2016) (geometric mean 0.076 μg/g creatinine or 0.000076 μg/mg creatinine) based on a representative sample of 3,057 individuals.^101^