# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TR-599.^88^

## Rats

### Three-month Study (Perinatal Phase)

No significant effects related to sodium tungstate dihydrate (ST) exposure were observed on pregnancy status, maternal survival, or the number of dams that littered (Table 2). There were no clinical observations in dams (Appendix G). One dam in the 250 mg/L group was euthanized on gestation day (GD) 25 due to moribundity associated with incomplete labor, and one 2,000 mg/L dam (and her pups) was euthanized moribund on lactation day (LD) 6.

Table 2 Summary of the Disposition of F_0_ Female Rats during Perinatal Exposure in the Perinatal and Three-month Drinking Water Study of Sodium Tungstate Dihydrate

| 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Reproductive Performance
Time-mated Females (GD 6) | 8 | 8 | 8 | 8 | 8 | 8
Females Pregnant (%)^a^ | 7 (87.5) | 8 (100.0) | 8 (100.0) | 6 (75.0) | 6 (75.0) | 6 (75.0)
Females Not Pregnant (%) | 1 (12.5) | 0 | 0 | 2 (25.0) | 2 (25.0) | 2 (25.0)
Dams Not Delivering with Evidence of Pregnancy (%) | 0 | 0 | 1 (12.5)^b^ | 0 | 0 | 0
Dams with Litters on LD 0 (%) | 7 (100) | 8 (100.0) | 7 (100.0) | 6 (100.0) | 6 (100.0) | 6 (100.0)
Litters Poststandardization (LD 4)^c^ | 5 | 7 | 7 | 6 | 5 | 5

GD = gestation day; LD = lactation day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Dam died before littering.

^c^ Standardization to eight pups/litter (four pups/sex). Only litters with at least two pups/sex and at least eight pups total/litter were retained to continue on study.

No significant effects on dam mean body weight during gestation were observed, but mean body weights were significantly decreased in the 1,000 and 2,000 mg/L groups starting at LD 14. By the end of lactation (LD 21), the 1,000 and 2,000 mg/L dam groups showed significant decreases in group mean body weight of approximately 10% and 18%, respectively, when compared to the vehicle control group (Table 3).

Table 3 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Three-month Drinking Water Study of Sodium Tungstate Dihydrate

Parameter^a,b^ | 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Gestation Day
6 | 229.8 ± 3.1 (7) | 220.5 ± 8.8 (8) | 224.5 ± 6.2 (8) | 228.1 ± 5.7 (6) | 225.5 ± 4.6 (6) | 228.9 ± 4.6 (6)
9 | 243.3 ± 2.7 (7) | 241.4 ± 5.3 (8) | 245.6 ± 4.3 (8) | 239.1 ± 5.4 (6) | 237.2 ± 5.1 (6) | 242.1 ± 5.8 (6)
12 | 259.1 ± 3.6 (7) | 257.4 ± 4.9 (8) | 261.4 ± 4.4 (8) | 255.5 ± 5.8 (6) | 254.5 ± 4.8 (6) | 258.3 ± 6.6 (6)
15 | 275.5 ± 6.0 (7) | 279.9 ± 4.9 (8) | 281.5 ± 5.1 (8) | 276.2 ± 5.0 (6) | 269.3 ± 4.3 (6) | 277.9 ± 8.6 (6)
18 | 304.9 ± 10.9 (7) | 317.6 ± 5.6 (8) | 313.4 ± 7.8 (8) | 309.3 ± 5.8 (6) | 301.2 ± 4.5 (6) | 306.1 ± 16.0 (6)
21 | 345.0 ± 19.2 (7) | 367.4 ± 7.2 (8) | 353.9 ± 11.9 (8) | 352.0 ± 6.0 (6) | 338.7 ± 8.4 (6) | 339.3 ± 26.0 (6)
Gestation Weight Change
Gestation Day Interval
6–9 | 13.5 ± 0.9 (7) | 20.8 ± 4.3 (8) | 21.1 ± 5.5 (8) | 11.0 ± 0.7 (6) | 11.7 ± 1.2 (6) | 13.2 ± 1.6 (6)
9–12 | 15.8 ± 1.2 (7) | 16.1 ± 0.9 (8) | 15.8 ± 0.8 (8) | 16.3 ± 1.0 (6) | 17.3 ± 0.9 (6) | 16.1 ± 1.5 (6)
12–15 | 16.4 ± 3.3 (7) | 22.5 ± 1.3 (8) | 20.0 ± 1.7 (8) | 20.8 ± 1.2 (6) | 14.8 ± 1.0 (6) | 19.6 ± 2.9 (6)
15–18 | 29.3 ± 5.6 (7) | 37.6 ± 1.4 (8) | 32.0 ± 3.5 (8) | 33.0 ± 1.5 (6) | 31.8 ± 4.9 (6) | 28.2 ± 8.7 (6)
18–21 | 40.1 ± 8.4 (7) | 49.9 ± 3.0 (8) | 40.5 ± 4.4 (8) | 42.7 ± 1.8 (6) | 37.5 ± 5.1 (6) | 33.1 ± 11.5 (6)
6–21 | 115.2 ± 18.0 (7) | 146.9 ± 6.4 (8) | 129.4 ± 12.7 (8) | 123.9 ± 2.2 (6) | 113.3 ± 10.6 (6) | 110.3 ± 22.9 (6)
Lactation Day
1 | 275.0 ± 4.7 (6) | 270.6 ± 3.7 (8) | 277.2 ± 7.4 (7) | 268.3 ± 4.7(6) | 264.3 ± 5.3 (6) | 257.2 ± 10.9 (6)
4 | 290.1 ± 5.4 (5) | 287.2 ± 5.1 (7) | 285.8 ± 7.2 (7) | 279.9 ± 2.9(6) | 271.1 ± 3.9 (5) | 280.3 ± 8.2 (5)
7 | 300.2 ± 5.3* (5) | 289.4 ± 4.5 (7) | 299.4 ± 6.2 (7) | 289.0 ± 2.7(6) | 279.9 ± 5.1 (5) | 281.9 ± 6.0 (4)^c^
14 | 325.4 ± 5.7** (5) | 331.8 ± 6.7 (7) | 326.1 ± 6.6 (7) | 313.3 ± 6.3(6) | 303.0 ± 3.7* (5) | 288.6 ± 6.0** (4)
21 | 313.4 ± 5.5** (5) | 315.2 ± 8.1 (7) | 308.3 ± 8.3 (7) | 306.4 ± 5.7(6) | 283.4 ± 3.4* (5) | 256.1 ± 8.7** (4)
Lactation Weight Change
Lactation Day Interval
1–4 | 12.7 ± 3.8 (5) | 15.8 ± 3.2 (7) | 8.5 ± 3.2 (7) | 11.7 ± 2.1 (6) | 11.3 ± 1.7 (5) | 13.2 ± 3.4 (5)
4–7 | 10.1 ± 2.6 (5) | 2.3 ± 2.0 (7) | 13.6 ± 2.1 (7) | 9.1 ± 2.4 (6) | 8.8 ± 4.4 (5) | 2.8 ± 6.0 (4)^c^
7–14 | 25.1 ± 2.7** (5) | 42.4 ± 3.3 (7) | 26.7 ± 4.3 (7) | 24.3 ± 4.5 (6) | 23.1 ± 4.8 (5) | 6.7 ± 3.4** (4)
14–21 | −12.0 ± 8.7 (5) | −16.6 ± 3.7 (7) | −17.8 ± 6.4 (7) | −7.0 ± 5.2 (6) | −19.6 ± 2.5 (5) | −32.5 ± 7.3 (4)
1–21 | 36.0 ± 8.6** (5) | 43.8 ± 4.7 (7) | 31.0 ± 9.7 (7) | 38.1 ± 5.6 (6) | 23.6 ± 4.5 (5) | −9.6 ± 6.0** (4)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Each exposure group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^b^ Data presented as mean ± standard error (number of dams). Body weight data are presented in grams.

^c^ One dam and her pups in the 2,000 mg/L group were euthanized on PND 6 due to moribundity.

There were no significant changes in water consumption of exposed dams compared to vehicle control dams during gestation; however, during most of the lactation period, water consumption was significantly decreased for the 2,000 mg/L dams, with the largest difference (approximately 27%) occurring during the end of lactation (LD 17–21) (Table 4). Water consumption by the 500 mg/L group was up to 19% lower (LD 4–7) than that of the vehicle control group; however, consumption by the 1,000 mg/L group was no more than 8% lower (LD 17–21) than that of the vehicle control group (Table 4). Daily ST consumption for the 125, 250, 500, 1,000, and 2,000 mg/L groups averaged approximately 17, 33, 58, 132, and 247 mg ST/kg body weight/day (mg/kg/day), respectively, during GD 6–21 and approximately 25, 56, 96, 220, and 374 mg/kg/day, respectively, during LD 1–14 (Table 4).

Table 4 Summary of Water and Sodium Tungstate Dihydrate Consumption of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Three-month Drinking Water Study

Parameter^a^ | 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Gestation Day Interval^b,c^
6–9 | 28.9 ± 1.7 (7) | 30.5 ± 1.2 (8) | 30.9 ± 1.6 (8) | 26.4 ± 2.0 (6) | 28.1 ± 1.5 (6) | 27.5 ± 1.7 (6)
9–12 | 30.7 ± 1.8 (7) | 30.6 ± 1.7 (8) | 30.7 ± 1.0 (8) | 27.9 ± 1.7 (6) | 36.3 ± 7.1 (6) | 27.7 ± 1.2 (6)
12–15 | 33.1 ± 2.3 (7) | 36.0 ± 1.2 (8) | 36.2 ± 1.3 (8) | 31.4 ± 0.8 (6) | 33.5 ± 2.1 (6) | 33.9 ± 1.6 (6)
15–18 | 40.6 ± 3.4 (7) | 45.8 ± 2.9 (8) | 40.4 ± 1.7 (8) | 37.5 ± 1.2 (6) | 39.7 ± 3.5 (6) | 42.0 ± 1.8 (6)
18–21 | 41.4 ± 3.7* (7) | 44.4 ± 2.9 (8) | 42.1 ± 1.2 (8) | 37.3 ± 1.3 (6) | 39.6 ± 4.1 (6) | 37.8 ± 3.0 (6)
6–21 | 34.9 ± 2.4* (7) | 37.4 ± 1.5 (8) | 36.1 ± 1.2 (8) | 32.1 ± 1.2 (6) | 35.5 ± 3.1 (6) | 33.8 ± 1.0 (6)
Lactation Day Interval^b,c^
1–4 | 49.25 ± 2.66 (6) | 51.10 ± 2.24 (8) | 51.37 ± 2.67 (7) | 44.20 ± 1.07 (6) | 57.63 ± 7.59 (6) | 45.00 ± 1.99 (6)
4–7 | 53.62 ± 2.43 (5) | 45.77 ± 1.25 (7) | 61.27 ± 5.07 (7) | 43.50 ± 1.85* (6) | 50.56 ± 2.06 (5) | 45.08 ± 1.94 (4)^d^
7–10 | 68.78 ± 3.43** (5) | 64.20 ± 1.51 (7) | 71.41 ± 5.17 (7) | 58.77 ± 2.59 (6) | 64.94 ± 1.46 (5) | 50.20 ± 1.25** (4)
10–14 | 85.46 ± 3.83** (5) | 78.13 ± 2.49 (7) | 84.93 ± 2.65 (7) | 74.73 ± 1.33 (6) | 78.56 ± 3.16 (5) | 66.05 ± 2.66** (4)
14–17 | 90.48 ± 4.39* (5) | 85.83 ± 4.03 (7) | 89.60 ± 2.63 (7) | 82.78 ± 2.94 (6) | 87.48 ± 2.65 (5) | 64.08 ± 0.54* (4)
17–21 | 108.6 ± 2.86** (5) | 104.5 ± 2.59 (7) | 107.3 ± 2.20 (6) | 96.67 ± 3.50* (6) | 99.96 ± 0.71* (5) | 79.68 ± 2.02** (4)
1–14 | 66.42 ± 2.70** (5) | 61.25 ± 1.70 (7) | 68.61 ± 2.21 (7) | 56.79 ± 1.14 (6) | 62.48 ± 1.61 (5) | 52.79 ± 1.31** (4)
Chemical Intake (mg/kg/day)^e,f^
GD 6–21 | 0.00 ± 0.00 (7) | 16.80 ± 0.50 (8) | 32.50 ± 1.11 (8) | 58.33 ± 1.35 (6) | 131.9 ± 11.20 (6) | 246.6 ± 8.10 (6)
LD 1–14 | 0.00 ± 0.00 (5) | 25.35 ± 0.69 (7) | 56.46 ± 1.76 (7) | 96.43 ± 1.61 (6) | 219.5 ± 4.80 (5) | 374.3 ± 6.22 (4)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

GD = gestation day; LD = lactation day.

^a^ Data presented as mean ± standard error (number of dams).

^b^ Water consumption data are presented as grams/animal/day.

^c^ Each exposure group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^d^ One dam and her pups in the 2,000 mg/L group were euthanized on PND 6 due to moribundity.

^e^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^f^ No statistical analysis was performed on the chemical intake data.

There were no exposure-related differences between the vehicle control group and the ST-exposed groups in the number of litters, total litter weight, or litter size of males and females on PND 1 or PND 4 (Table 5). The litter size did not change appreciably between PND 1 and litter standardization on PND 4.

Table 5 Summary of Mean Litter Size and Survival Ratio of F_1_ Male and Female Rats during Lactation in the Perinatal and Three-month Drinking Water Study of Sodium Tungstate Dihydrate

Parameter | 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
PND 1^a,b^
Total | 11.0 ± 1.2 (6) | 13.0 ± 0.7 (8) | 12.0 ± 0.7 (7) | 12.0 ± 0.7 (6) | 10.8 ± 2.1 (6) | 12.2 ± 1.7 (6)
Live | 11.0 ± 1.2 (6) | 12.8 ± 0.7 (8) | 12.0 ± 0.7 (7) | 12.0 ± 0.7 (6) | 10.7 ± 2.0 (6) | 12.2 ± 1.7 (6)
% Male per Litter^c^ | 42.3 ± 8.2 (4) | 44.3 ± 6.1 (5) | 48.4 ± 4.9 (5) | 53.7 ± 9.2 (4) | 39.2 ± 10.7 (5) | 54.7 ± 6.1 (5)
% Male^c,d,e^ | 39 (38) | 44 (63) | 49 (61) | 52 (48) | 48 (50) | 54 (56)
Male^a,b^
PND 1^c^ | 3.8 ± 0.3 (4) | 5.6 ± 1.0 (5) | 6.0 ± 0.9 (5) | 6.3 ± 0.8 (4) | 4.8 ± 1.3 (5) | 6.0 ± 1.0 (5)
PND 4 Prestandardization^c^ | 2.8 ± 0.9 (4) | 5.0 ± 1.4 (5) | 6.0 ± 0.9 (5) | 6.3 ± 0.8 (4) | 4.8 ± 1.3 (5) | 5.4 ± 1.5 (5)
PND 4 Poststandardization | 3.8 ± 0.2* (5) | 4.0 ± 0.0 (7) | 4.0 ± 0.0 (7) | 4.7 ± 0.4 (6) | 4.0 ± 0.0 (5) | 4.4 ± 0.4 (5)
Female^a,b^
PND 1^c^ | 5.8 ± 1.3 (4) | 7.0 ± 0.9 (5) | 6.2 ± 0.5 (5) | 5.8 ± 1.3 (4) | 5.2 ± 1.2 (5) | 5.2 ± 1.2 (5)
PND 4 Prestandardization^c^ | 5.3 ± 1.8 (4) | 5.0 ± 1.3 (5) | 6.2 ± 0.5 (5) | 5.8 ± 1.3 (4) | 5.0 ± 1.4 (5) | 4.6 ± 1.5 (5)
PND 4 Poststandardization | 4.2 ± 0.2* (5) | 4.0 ± 0.0 (7) | 4.0 ± 0.0 (7) | 3.3 ± 0.4 (6) | 4.0 ± 0.0 (5) | 3.6 ± 0.4 (5)
Male and Female^a,b^
PND 4 Prestandardization | 11.0 ± 1.2 (6) | 12.8 ± 0.7 (8) | 12.0 ± 0.7 (7) | 12.0 ± 0.7 (6) | 10.5 ± 1.9 (6) | 12.0 ± 1.7 (6)
PND 4 Poststandardization | 8.0 ± 0.0 (5) | 8.0 ± 0.0 (7) | 8.0 ± 0.0 (7) | 8.0 ± 0.0 (6) | 8.0 ± 0.0 (5) | 8.0 ± 0.0 (5)
PND 21 | 8.0 ± 0.0 (5) | 8.0 ± 0.0 (7) | 8.0 ± 0.0 (7) | 8.0 ± 0.0 (6) | 8.0 ± 0.0 (5) | 6.4 ± 1.6 (5)
Survival per Litter
Total Dead: PND 1–4^e,f^ | 0 (6) | 2 (8)^g^ | 0 (7) | 0 (6) | 2 (6)^g^ | 1 (6)
Total Dead: PND 4–21^e,f^ | 0 (5) | 0 (7) | 0 (7) | 0 (6) | 0 (5) | 8 (5)^h^
Dead: PND 1–4^a,b,i^ | 0.0 ± 0.0 (6) | 0.3 ± 0.2 (8) | 0.0 ± 0.0 (7) | 0.0 ± 0.0 (6) | 0.3 ± 0.3 (6) | 0.2 ± 0.2 (6)
Dead: PND 4–21^a,b,i^ | 0.0 ± 0.0 (5) | 0.0 ± 0.0 (7) | 0.0 ± 0.0 (7) | 0.0 ± 0.0 (6) | 0.0 ± 0.0 (5) | 1.6 ± 1.6 (5)
Survival Ratio: PND 1–4^a,b,j^ | 1.00 ± 0.00 (6) | 1.00 ± 0.00 (8) | 1.00 ± 0.00 (7) | 1.00 ± 0.00 (6) | 0.99 ± 0.01 (6) | 0.99 ± 0.01 (6)
Survival Ratio: PND 4–21^a,b,k^ | 1.00 ± 0.00 (5) | 1.00 ± 0.00 (7) | 1.00 ± 0.00 (7) | 1.00 ± 0.00 (6) | 1.00 ± 0.00 (5) | 0.80 ± 0.20 (5)

Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

PND = postnatal day.

^a^ Each exposure group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^b^ Data presented as mean ± standard error (number of litters).

^c^ Litters where the male/female pup counts were inconsistent between PND 1 and PND 4 were excluded from the male/female-specific endpoints.

^d^ 100 × [number of live males in exposure group]/[number of live males and females in dietary exposure group] (number of pups).

^e^ No statistics done on this endpoint.

^f^ Total dead in exposure group (number of litters).

^g^ Two pups in the 125 mg/L group and one pup in the 1,000 mg/L group were found dead on PND 1.

^h^ One dam and her pups in the 2,000 mg/L group were euthanized on PND 6 due to moribundity.

^i^ Number dead/litter.

^j^ Survival per litter: number of pups prestandardization on PND 4/total live pups on PND 1.

^k^ Survival per litter: number of live pups on PND 21/number of live pups poststandardization on PND 4.

Two pups in the 125 mg/L group and one pup in the 1,000 mg/L group were found dead on PND 1; one pup in the 1,000 mg/L group was missing on PND 2; and one pup in the 2,000 mg/L group was found dead on PND 3. There was no pup mortality after PND 6. There were no exposure-related clinical observations in dams or pups (Appendix G).

When adjusted for litter size, the mean body weight of male and female pups in the 2,000 mg/L group on PND 21 was significantly decreased by approximately 16% and 11%, respectively, compared to the corresponding vehicle control groups. For male and female pups in the 2,000 mg/L group combined, the mean body weight on PND 21 was significantly decreased by approximately 14% relative to the vehicle control male and female pups combined (Table 6).

Table 6 Summary of Preweaning F_1_ Male and Female Rat Pup Mean Body Weights Following Perinatal Exposure to Sodium Tungstate Dihydrate

Parameter | 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male (g)
PND 1^a,b,c^ | 7.8 ± 0.4** (4) | 7.8 ± 0.2 (5) | 7.8 ± 0.4 (5) | 7.3 ± 0.3 (4) | 7.2 ± 0.2 (4) | 6.7 ± 0.3* (5)
PND 4^d,e,f^ | 10.84 ± 0.46* (19/5) | 10.49 ± 0.28 (28/7) | 10.88 ± 0.52 (28/7) | 9.90 ± 0.34 (28/6) | 10.49 ± 0.39 (20/5) | 9.34 ± 0.48 (22/5)
PND 7^d,e,g^ | 16.94 ± 0.73* (19/5) | 15.96 ± 0.41 (28/7) | 16.67 ± 0.80 (28/7) | 14.65 ± 0.43 (28/6) | 15.61 ± 0.43 (20/5) | 14.70 ± 0.81 (18/4)
PND 14^d,e,g^ | 32.98 ± 0.87** (19/5) | 32.16 ± 0.56 (28/7) | 33.13 ± 1.15 (28/7) | 30.40 ± 1.04 (28/6) | 31.41 ± 0.73 (20/5) | 29.22 ± 1.09 (18/4)
PND 21^d,e,g^ | 55.56 ± 1.59** (19/5) | 54.74 ± 0.58 (28/7) | 55.05 ± 1.75 (28/7) | 50.77 ± 1.92 (28/6) | 51.89 ± 0.89 (20/5) | 46.53 ± 1.44** (18/4)
Female (g)
PND 1^a,b,c^ | 7.1 ± 0.2 (4) | 7.2 ± 0.1 (5) | 7.6 ± 0.3 (5) | 7.0 ± 0.3 (4) | 7.1 ± 0.3 (5) | 6.6 ± 0.5 (5)
PND 4^d,e,f^ | 10.16 ± 0.49 (21/5) | 9.69 ± 0.22 (28/7) | 10.43 ± 0.47 (28/7) | 9.19 ± 0.50 (20/6) | 9.95 ± 0.25 (20/5) | 9.19 ± 0.60 (18/5)
PND 7^d,e,g^ | 15.91 ± 0.76 (21/5) | 14.95 ± 0.27 (28/7) | 16.29 ± 0.71 (28/7) | 13.64 ± 0.74 (20/6) | 15.00 ± 0.24 (20/5) | 14.45 ± 1.16 (14/4)
PND 14^d,e,g^ | 31.80 ± 0.99 (21/5) | 30.48 ± 0.52 (28/7) | 32.44 ± 1.22 (28/7) | 28.04 ± 1.74 (20/6) | 30.44 ± 0.53 (20/5) | 28.63 ± 1.33 (14/4)
PND 21^d,e,g^ | 51.71 ± 1.31** (21/5) | 51.21 ± 0.39 (28/7) | 53.09 ± 1.58 (28/7) | 46.06 ± 2.53 (20/6) | 49.40 ± 0.88 (20/5) | 45.79 ± 2.04* (14/4)
Male and Female (g)
PND 1^a,b,c^ | 7.4 ± 0.2** (6) | 7.4 ± 0.1 (8) | 7.5 ± 0.2 (7) | 7.2 ± 0.2 (6) | 7.1 ± 0.3 (6) | 6.6 ± 0.3* (6)
PND 4^d,e,f^ | 10.49 ± 0.45* (40/5) | 10.09 ± 0.23 (56/7) | 10.65 ± 0.49 (56/7) | 9.69 ± 0.32 (48/6) | 10.22 ± 0.32 (40/5) | 9.24 ± 0.51 (40/5)
PND 7^d,e,g^ | 16.41 ± 0.72 (40/5) | 15.46 ± 0.31 (56/7) | 16.48 ± 0.75 (56/7) | 14.37 ± 0.36 (48/6) | 15.31 ± 0.32 (40/5) | 14.52 ± 0.93 (32/4)
PND 14^d,e,g^ | 32.37 ± 0.88** (40/5) | 31.32 ± 0.44 (56/7) | 32.79 ± 1.19 (56/7) | 29.76 ± 0.84 (48/6) | 30.92 ± 0.56 (40/5) | 28.91 ± 1.19 (32/4)
PND 21^d,e,g^ | 53.53 ± 1.29** (40/5) | 52.98 ± 0.38 (56/7) | 54.07 ± 1.65 (56/7) | 49.33 ± 1.55 (48/6) | 50.65 ± 0.76 (40/5) | 46.08 ± 1.65** (32/4)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

PND = postnatal day.

^a^ Data presented as mean ± standard error (number of litters).

^b^ Each exposure group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^c^ Litter weights of live pups at PND 1 were divided by live litter size on PND 1 to obtain a pup mean weight/litter. Mean values were then adjusted using live litter size on PND 1 as a covariate.

^d^ Statistical analysis was performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^e^ Data presented as mean of litter means ± standard error (number of pups/number of litters).

^f^ PND 4 post-standardization.

^g^ Individual pup weights first adjusted for live litter size on PND 4 poststandardization.

### Three-month Study (Postweaning Phase)

There were no early deaths during the 3-month study; all F_1_ rats survived until study termination (Table 7, Table 8). There were no clinical observations related to exposure, and all exposed animals were similar in overt behavior and general appearance to the vehicle control animals (Appendix G). Initial mean body weights were 9% and 16% below those of the vehicle control group for the 1,000 and 2,000 mg/L males, respectively; and 14%, 11%, and 13% below those of the vehicle control group for the 500, 1,000, and 2,000 mg/L females, respectively (Table 7, Table 8; Figure 2). Final mean body weights were lower for the 1,000 and 2,000 mg/L males and females, with the 2,000 mg/L males weighing approximately 29% less than the vehicle control group and the 2,000 mg/L females weighing approximately 18% less than the vehicle control group.

Table 7 Summary of Survival and Mean Body Weights of Male Rats in the Perinatal and Three-month Drinking Water Study of Sodium Tungstate Dihydrate

Study Day^a^ | 0 mg/L | | 125 mg/L | | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Study Day^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 57.4 | 5 | 57.8 | 100.7 | 5 | 57.3 | 99.9 | 5 | 55.2 | 96.2 | 5 | 52.2 | 91.1 | 5 | 48.4 | 84.3 | 4
7 | 82.1 | 5 | 81.4 | 99.2 | 5 | 81.5 | 99.2 | 5 | 76.4 | 93.1 | 5 | 71.4 | 87.0 | 5 | 60.0 | 73.2 | 4
14 | 108.1 | 5 | 119.0 | 110.1 | 5 | 112.0 | 103.6 | 5 | 109.1 | 100.9 | 5 | 98.3 | 90.9 | 5 | 74.7 | 69.1 | 4
21 | 171.9 | 5 | 175.5 | 102.1 | 5 | 172.8 | 100.6 | 5 | 159.8 | 93.0 | 5 | 136.4 | 79.3 | 5 | 91.2 | 53.1 | 4
28 | 191.1 | 5 | 193.0 | 101.0 | 5 | 198.1 | 103.6 | 5 | 181.4 | 94.9 | 5 | 168.2 | 88.0 | 5 | 112.4 | 58.8 | 4
35 | 261.7 | 5 | 257.7 | 98.4 | 5 | 249.2 | 95.2 | 5 | 245.1 | 93.6 | 5 | 200.0 | 76.4 | 5 | 132.9 | 50.8 | 4
42 | 300.6 | 5 | 294.1 | 97.9 | 5 | 298.5 | 99.3 | 5 | 284.8 | 94.7 | 5 | 243.0 | 80.9 | 5 | 160.7 | 53.5 | 4
49 | 319.6 | 5 | 322.7 | 101.0 | 5 | 324.6 | 101.6 | 5 | 300.8 | 94.1 | 5 | 267.4 | 83.7 | 5 | 188.6 | 59.0 | 4
56 | 352.5 | 5 | 355.1 | 100.8 | 5 | 352.3 | 99.9 | 5 | 339.4 | 96.3 | 5 | 301.5 | 85.5 | 5 | 212.6 | 60.3 | 4
63 | 345.9 | 5 | 345.4 | 99.9 | 5 | 341.5 | 98.7 | 5 | 335.2 | 96.9 | 5 | 310.5 | 89.8 | 5 | 222.4 | 64.3 | 4
70 | 384.2 | 5 | 383.9 | 99.9 | 5 | 379.5 | 98.8 | 5 | 368.0 | 95.8 | 5 | 339.7 | 88.4 | 5 | 250.1 | 65.1 | 4
77 | 398.1 | 5 | 398.3 | 100.1 | 5 | 389.5 | 97.8 | 5 | 385.5 | 96.8 | 5 | 350.4 | 88.0 | 5 | 270.6 | 68.0 | 4
84 | 414.0 | 5 | 412.3 | 99.6 | 5 | 407.9 | 98.5 | 5 | 400.0 | 96.6 | 5 | 365.2 | 88.2 | 5 | 285.0 | 68.8 | 4
EOS | 422.7 | 5 | 425.7 | 100.7 | 5 | 419.7 | 99.3 | 5 | 412.9 | 97.7 | 5 | 379.3 | 89.7 | 5 | 300.6 | 71.1 | 4

EOS = end of study; No. of litters = number of litters represented in weight average.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are means of litter means.

Table 8 Summary of Survival and Mean Body Weights of Female Rats in the Perinatal and Three-month Drinking Water Study of Sodium Tungstate Dihydrate

Study Day^a^ | 0 mg/L | | 125 mg/L | | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Study Day^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 54.4 | 5 | 57.5 | 105.8 | 5 | 56.1 | 103.1 | 5 | 46.7 | 85.9 | 5 | 48.5 | 89.2 | 5 | 47.5 | 87.4 | 4
7 | 79.7 | 5 | 81.1 | 101.8 | 5 | 80.7 | 101.3 | 5 | 69.2 | 86.8 | 5 | 70.8 | 88.8 | 5 | 60.5 | 76.0 | 4
14 | 104.1 | 5 | 116.0 | 111.4 | 5 | 111.1 | 106.7 | 5 | 100.8 | 96.8 | 5 | 98.4 | 94.5 | 5 | 74.5 | 71.6 | 4
21 | 142.4 | 5 | 147.0 | 103.3 | 5 | 150.5 | 105.7 | 5 | 129.6 | 91.0 | 5 | 121.7 | 85.5 | 5 | 86.9 | 61.1 | 4
28 | 165.1 | 5 | 173.5 | 105.1 | 5 | 167.2 | 101.3 | 5 | 153.6 | 93.1 | 5 | 141.9 | 85.9 | 5 | 102.2 | 61.9 | 4
35 | 179.2 | 5 | 188.9 | 105.4 | 5 | 191.1 | 106.6 | 5 | 175.2 | 97.8 | 5 | 163.7 | 91.3 | 5 | 114.7 | 64.0 | 4
42 | 198.3 | 5 | 207.0 | 104.4 | 5 | 208.9 | 105.4 | 5 | 191.0 | 96.3 | 5 | 179.1 | 90.3 | 5 | 132.7 | 66.9 | 4
49 | 210.8 | 5 | 223.4 | 106.0 | 5 | 216.3 | 102.6 | 5 | 202.4 | 96.0 | 5 | 191.8 | 91.0 | 5 | 150.7 | 71.5 | 4
56 | 215.5 | 5 | 225.4 | 104.6 | 5 | 230.3 | 106.9 | 5 | 217.9 | 101.1 | 5 | 203.8 | 94.6 | 5 | 166.0 | 77.1 | 4
63 | 230.9 | 5 | 239.3 | 103.6 | 5 | 243.6 | 105.5 | 5 | 230.0 | 99.6 | 5 | 214.6 | 92.9 | 5 | 177.3 | 76.8 | 4
70 | 238.6 | 5 | 255.5 | 107.1 | 5 | 252.8 | 105.9 | 5 | 241.1 | 101.0 | 5 | 222.2 | 93.1 | 5 | 190.0 | 79.6 | 4
77 | 243.4 | 5 | 255.8 | 105.1 | 5 | 254.1 | 104.4 | 5 | 244.4 | 100.4 | 5 | 228.6 | 93.9 | 5 | 194.8 | 80.0 | 4
84 | 250.4 | 5 | 260.4 | 104.0 | 5 | 260.8 | 104.2 | 5 | 251.7 | 100.5 | 5 | 236.0 | 94.3 | 5 | 201.3 | 80.4 | 4
EOS | 259.5 | 5 | 268.6 | 103.5 | 5 | 271.2 | 104.5 | 5 | 257.9 | 99.4 | 5 | 242.8 | 93.6 | 5 | 213.1 | 82.1 | 4

EOS = end of study; No. of litters = number of litters represented in weight average.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are means of litter means.

Figure 2

Growth Curves for Rats Exposed to Sodium Tungstate Dihydrate in Drinking Water for Three Months

Water consumption was lower for the 1,000 and 2,000 mg/L males and females, with overall reductions of 27% and 42% for males and females, respectively, in the 2,000 mg/L groups compared to the respective vehicle control groups (Table 9; Appendix G). Drinking water concentrations of 125, 250, 500, 1,000, and 2,000 mg/L resulted in average daily ST doses of approximately 11.8, 24.3, 48.9, 91.8, and 157.2 mg/kg/day for males and 14.0, 26.1, 54.4, 101.4, and 160.5 mg/kg/day for females.

Table 9 Summary of Water and Sodium Tungstate Dihydrate Consumption of Male and Female Rats in the Perinatal and Three-month Drinking Water Study

Week | 0 mg/L | 125 mg/L | | 250 mg/L | | 500 mg/L | | 1,000 mg/L | | 2,000 mg/L
Week | Water (g/day)^a^ | Water (g/day) | Dose (mg/kg/day)^b^ | Water (g/day) | Dose (mg/kg/day) | Water (g/day) | Dose (mg/kg/day) | Water (g/day) | Dose (mg/kg/day) | Water (g/day) | Dose (mg/kg/day)
Male
1 | 11.5 | 10.2 | 18.3 | 11.1 | 40.0 | 9.5 | 72.2 | 8.8 | 142.4 | 6.6 | 241.3
4 | 23.4 | 22.3 | 14.4 | 23.8 | 30.0 | 22.9 | 63.1 | 19.9 | 118.3 | 10.0 | 176.3
12 | 17.2 | 17.0 | 5.2 | 17.3 | 10.6 | 16.6 | 20.8 | 14.2 | 38.9 | 10.8 | 75.3
Female
1 | 11.1 | 11.0 | 19.8 | 10.9 | 39.8 | 10.0 | 86.3 | 9.6 | 160.9 | 6.5 | 241.6
4 | 20.9 | 21.3 | 15.3 | 19.2 | 28.7 | 19.2 | 62.5 | 16.6 | 117.0 | 8.8 | 171.3
12 | 20.8 | 22.2 | 10.7 | 19.9 | 19.1 | 18.4 | 36.5 | 16.9 | 71.6 | 12.5 | 124.1

^a^ Grams of water consumed/animal/day.

^b^ Milligrams of sodium tungstate dihydrate consumed/kilogram body weight/day.

Blood was collected from up to 10 animals per group (originating from 4 or 5 litters) on the morning of day 91. Urine was collected overnight (for approximately 16 hours) during week 12 of the study from up to five animals per group; during collection, animals had access to untreated water. Total blood and urine tungsten concentrations were determined using validated analytical methods (Appendix E) and corresponding data are presented in Table 10. In both males and females, the total tungsten concentration in blood increased proportionally to the exposure concentration with no observed sex difference. The blood tungsten concentration in vehicle control animals was below the limit of detection (LOD; 0.0016 μg/g) of the assay. The urine tungsten concentration is presented as both μg/g of urine and after correcting for urinary creatinine concentrations (μg/mg creatinine) (Table 10). Low concentrations of tungsten were detected in urine from vehicle control male and female groups. The concentrations of creatinine-corrected tungsten in urine increased proportionally to the exposure concentration in both males and females and were significantly increased in all exposed groups compared to the corresponding vehicle control groups. As with blood, there was no observed sex difference in urinary tungsten concentrations.

Table 10 Summary of Blood and Urine Tungsten Concentration Data for Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Sodium Tungstate Dihydrate^a^

| 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
n | 5 | 5 | 5 | 5 | 5 | 4
Male
Blood (μg/g) | BD | 0.49 ± 0.07 | 0.99 ± 0.10 | 1.93 ± 0.21 | 4.67 ± 0.45 | 10.66 ± 0.93
Urine^b,c^
Urine (μg/g urine) | 0.04 ± 0.00** | 9.78 ± 3.02** | 24.21 ± 5.08** | 67.11 ± 22.66** | 61.91 ± 11.79** | 184.98 ± 30.14**
Urine (μg/mg creatinine) | 0.06 ± 0.01** | 11.84 ± 1.43** | 33.68 ± 4.97** | 42.40 ± 4.64** | 86.68 ± 5.67** | 291.52 ± 25.65**
Female
Blood (μg/g) | BD | 0.59 ± 0.06 | 1.19 ± 0.13 | 2.83 ± 0.29 | 5.67 ± 0.35 | 11.54 ± 1.03
Urine^b,c^
Urine (μg/g urine) | 0.03 ± 0.00** | 9.10 ± 1.54** | 26.40 ± 8.95** | 27.65 ± 6.43** | 98.98 ± 14.40** | 182.81 ± 33.44**
Urine (μg/mg creatinine) | 0.07 ± 0.01** | 18.88 ± 1.40** | 33.55 ± 3.82** | 45.59 ± 4.34** | 142.92 ± 21.99** | 280.85 ± 46.16**

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BD = below detection; group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Data presented as mean ± standard error of the litter means, where n = the number of litters.

^b^ Values below the LOD (0.0054 μg/g) were substituted with 1/2 the LOD value. If 80% or more of the values in the vehicle control group were below the LOD, no mean or standard error were calculated, and no statistical analysis was performed.

^c^ Statistical analysis performed using a bootstrapped Jonckheere test for trend and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons.

In female rats, there was a mild (<10%) significant decrease in the erythron characterized by a significant decrease in the hemoglobin concentration in the 2,000 mg/L group and a significant negative trend in the hematocrit concentration, hemoglobin concentration, and erythrocyte count with increasing exposure (Table 11). Although there were no significant pairwise changes observed in the male erythron, there were significant negative trends in hematocrit concentration, hemoglobin concentration, and erythrocyte count with increasing exposure concentration. The reticulocyte count was unchanged in both males and females. These mild erythron changes were most likely due to the stress of exposure,^89^ which is supported by the lower mean body weights observed in the 2,000 mg/L groups.

Table 11 Summary of Select Clinical Pathology Data for Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Sodium Tungstate Dihydrate^a,b^

| 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
n | 5 | 5 | 5 | 5 | 5 | 4
Male
Hematocrit (%) | 50.0 ± 1.2** | 48.2 ± 0.9 | 49.3 ± 0.5 | 48.5 ± 0.6 | 46.8 ± 0.8 | 45.7 ± 1.1
Hemoglobin (g/dL) | 15.2 ± 0.3** | 14.9 ± 0.2 | 15.3 ± 0.1 | 15.2 ± 0.1 | 14.6 ± 0.3 | 14.3 ± 0.3
Erythrocytes (10^6^/μL) | 8.69 ±0.18* | 8.45 ± 0.10 | 8.72 ± 0.10 | 8.54 ± 0.13 | 8.23 ± 0.15 | 8.13 ± 0.22
Urea Nitrogen (mg/dL) | 18.1 ± 0.5** | 14.8 ± 0.5* | 17.3 ± 0.3 | 17.6 ± 0.7 | 19.2 ± 0.4 | 24.4 ± 1.8*
Total Protein (g/dL) | 6.64 ± 0.04 | 6.67 ± 0.06 | 6.76 ± 0.09 | 6.75 ± 0.10 | 6.73 ± 0.07 | 6.04 ± 0.07*
Globulin (g/dL) | 2.46 ± 0.05* | 2.37 ± 0.03 | 2.48 ± 0.07 | 2.48 ± 0.05 | 2.37 ± 0.05 | 1.86 ± 0.04*
Insulin (ng/mL) | 4.36 ± 0.29** | 3.36 ± 0.33 | 3.09 ± 0.40 | 3.36 ± 0.42 | 2.52 ± 0.33 | 1.94 ± 0.34*
Female
Hematocrit (%) | 44.7 ± 0.6* | 45.5 ± 0.9 | 44.4 ± 0.6 | 44.6 ± 0.7 | 44.5 ± 0.8 | 42.3 ± 0.2
Hemoglobin (g/dL) | 14.2 ± 0.1* | 14.3 ± 0.3 | 14.1 ± 0.2 | 14.2 ± 0.1 | 14.0 ± 0.2 | 13.4 ± 0.1*
Erythrocytes (10^6^/uL) | 7.80 ± 0.07* | 7.87 ± 0.14 | 7.78 ± 0.05 | 7.70 ± 0.08 | 7.73 ± 0.07 | 7.38 ± 0.12

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data presented as mean ± standard error of the litter means, where n = the number of litters.

^b^ Statistical analysis performed using a bootstrapped Jonckheere test for trend and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons.

In male rats, blood urea nitrogen (BUN) was significantly increased, and the total protein, globulin concentrations, and insulin concentrations were significantly decreased in the 2,000 mg/L group (Table 11). The BUN was likely increased due to the lower water consumption values in that exposure group. The toxicological relevance of the observed decreases in the total protein and globulins is uncertain; these changes could be a secondary effect of exposure.

The urine xanthine/creatinine ratios were significantly increased in all male and female exposed groups relative to the vehicle control groups (Table 12).

Table 12 Summary of Select Urinalysis Data for Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Sodium Tungstate Dihydrate^a,b^

| 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
n | 5 | 5 | 5 | 5 | 5 | 4
Male
Creatinine (mg/dL) | 77.9 ± 10.2 | 80.5 ± 22.6 | 76.2 ± 11.3 | 154.5 ± 44.5 | 73.9 ± 15.1 | 73.5 ± 11.8
Xanthine (μg/mL) | 1.20 ± 0.16** | 1.51 ± 0.44 | 1.58 ± 0.24 | 4.48 ± 1.75 | 3.20 ± 0.52* | 5.45 ± 0.88*
Xanthine/Creatinine (μg/mg) | 1.55 ± 0.09** | 1.83 ± 0.04* | 2.13 ± 0.08* | 2.79 ± 0.37* | 4.63 ± 0.27* | 7.65 ± 0.26*
Female
Creatinine (mg/dL) | 43.7 ± 6.1* | 47.8 ± 4.6 | 77.1 ± 22.9 | 58.9 ± 10.2 | 66.7 ± 4.1 | 82.3 ± 22.3
Xanthine (μg/mL) | 0.43 ± 0.07** | 0.74 ± 0.12 | 1.77 ± 0.54* | 2.00 ± 0.35* | 3.30 ± 0.21* | 3.72 ± 0.75
Xanthine/Creatinine (μg/mg) | 1.02 ± 0.09** | 1.51 ± 0.14* | 2.27 ± 0.27** | 3.39 ± 0.18** | 5.21 ± 0.38** | 7.28 ± 0.86*

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data presented as mean ± standard error of the litter means, where n = the number of litters.

^b^ Statistical analysis performed using a bootstrapped Jonckheere test for trend and a Datta-Satten modified Wilcoxon test with Hommel adjustment for pairwise comparisons.

Absolute kidney weights were reduced in males in all exposed groups, relative to the vehicle control group, with a significant decrease observed in the 2,000 mg/L group (approximately 21%). Relative kidney weights were higher in 1,000 mg/L females and significantly increased in the 2,000 mg/L males and females, relative to the vehicle control group (Table 13). Although the kidney was a target tissue, it is unlikely that the lesions observed were responsible for the differences in kidney weights; it is more likely that these organ weight differences are an effect of body weight differences.

Table 13 Summary of Renal Findings for Male and Female Rats in the Perinatal and Three-month Drinking Water Study of Sodium Tungstate Dihydrate

| 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
n | 5 | 5 | 5 | 5 | 5 | 4
Male
Necropsy Body Wt. (g)^a^ | 422.7 ± 5.2** | 425.7 ± 3.9 | 419.7 ± 9.0 | 412.9 ± 10.2 | 379.3 ± 6.7** | 300.6 ± 17.9**
R. Kidney Weight^a^
Absolute (g) | 1.35 ± 0.04** | 1.32 ± 0.03 | 1.25 ± 0.05 | 1.26 ± 0.04 | 1.22 ± 0.02 | 1.06 ± 0.06**
Relative (mg/g)^b^ | 3.20 ± 0.08** | 3.11 ± 0.06 | 2.99 ± 0.10 | 3.06 ± 0.03 | 3.21 ± 0.01 | 3.56 ± 0.09**
Histological Findings
Kidney^c^ | 10 | 10 | 10 | 10 | 10 | 10
Renal tubule, regeneration^d^ | 0** | 0 | 0 | 0 | 3 (1.0)^e^ | 10** (2.0)
Female
Necropsy Body Wt. (g) | 259.5 ± 3.8** | 268.6 ± 9.1 | 271.2 ± 7.0 | 257.9 ± 6.3 | 242.8 ± 0.8 | 213.1 ± 4.1**
R. Kidney Weight
Absolute (g) | 0.84 ± 0.02 | 0.87 ± 0.03 | 0.84 ± 0.02 | 0.81 ± 0.02 | 0.84 ± 0.02 | 0.85 ± 0.03
Relative (mg/g) | 3.25 ± 0.04** | 3.25 ± 0.03 | 3.08 ± 0.05 | 3.13 ± 0.05 | 3.47 ± 0.07 | 3.98 ± 0.15**
Histological Findings
Kidney | 10 | 10 | 10 | 10 | 10 | 10
Renal tubule, regeneration | 0** | 0 | 0 | 0 | 3 (1.0) | 10** (2.0)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

Statistical analysis for organ weight data performed using mixed models, with litter as a random effect and a Dunnett-Hsu adjustment for multiple comparisons. Statistical analysis for histological findings performed by the Rao-Scott test.

** Statistically significant at p ≤ 0.01.

^a^ Data presented as mean ± standard error of the litter means.

^b^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

^c^ Number of animals examined microscopically.

^d^ Number of animals with lesion.

^e^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

When compared to vehicle control groups, significant differences were also observed in other organ weights, including decreased absolute heart and lung weights in males and females; decreased absolute liver weights in males and increased relative liver weights in females; decreased absolute thymus weights in males and increased relative testis weights (Appendix G). These changes were considered secondary to body weight reductions. Rats administered 2,000 mg/L ST exhibited significantly decreased left cauda epididymis (14%) and epididymis (13%) weights, and lower testis weights (8%) compared to the vehicle control group (Appendix G). Although these were significant (cauda and epididymis) and/or displayed a significant negative trend with increasing exposure concentration (right testis), rats in the 2,000 mg/L group displayed mean body weights that were 28% lower than the vehicle control group. There were no changes in reproductive parameters or alterations in contralateral testis and epididymis or in histopathology (Appendix G). Given the magnitude of the body weight effect and the absence of changes in other endpoints, the lower reproductive organ weights are likely secondary to effects on body weight.

Although the weights of the left epididymis and the left cauda were significantly decreased in the 2,000 mg/L males, there were no corresponding changes in sperm parameters, including number of sperm/mg cauda epididymis, total number of sperm/cauda, sperm motility, number of homogenization-resistant spermatids/mg testis, or total number of spermatids (Appendix G).

No exposure-related gross lesions were recorded. Exposure-related histological lesions were found in the kidneys (Table 13). Renal tubule regeneration was increased in the male and female 1,000 and 2,000 mg/L groups; the increases in the 2,000 mg/L groups were significant relative to the vehicle control groups (Table 13). The lesion was characterized by hyperplasia of proximal convoluted tubular epithelial cells that manifested as cytoplasmic basophilia, nuclear crowding, and occasional mitotic figures. Renal tubule regeneration occurs as a response to previous degeneration or necrosis and is one of the most common exposure-related lesions in the kidney.^90^ Degeneration and necrosis were not present in this study, perhaps due to the fact that by the time of necropsy, the response of the kidney had progressed from degeneration to regeneration. Renal tubule regeneration differed from chronic progressive nephropathy (CPN) by the lack of thickened basement membranes, associated inflammatory cells, proteinaceous casts, and cytoplasmic pigment—all features typically seen with CPN. The incidences and severities of CPN were not increased in exposed groups of animals (Appendix G).

### Exposure Concentration Selection Rationale for the Perinatal and Two-year Study in Rats

A >10% reduction in final mean body weight in males and females (Table 7, Table 8) and up to a 65% reduction in water consumption for males (at week 3), and a 60% reduction in water consumption for females (at week 3) (Table 9) in the 3-month studies coupled with lesions noted in the kidney (Table 13), led to the assessment that 2,000 mg/L was too high for the 2-year studies. The 1,000 mg/L concentration was considered an adequate top exposure concentration to challenge the animals based on an approximate 10% reduction in final mean body weight in males, an approximate 20% reduction in water consumption in females, and minimal to mild renal tubule regeneration in the 3-month studies. Because there was no overlap in tungstate blood concentrations between the 1,000 mg/L and 2,000 mg/L groups, and no significant effects were noted at 500 mg/L or lower, the exposure concentrations were spaced by half. Hence, exposure concentrations selected for the chronic studies were 0, 250, 500 and 1,000 mg/L. Additionally, tissue tungsten concentrations were evaluated in the kidney, plasma, and urine at 3, 6, 12, and 18 months in an additional group of animals to determine systemic exposure and to help identify species differences given the findings from the 3-month studies showing the kidney as a target organ of toxicity.

### Two-year Study (Perinatal Phase)

No significant clinical observations were noted in dams and no significant effects were noted on reproductive performance, including the percentage of mated females producing pups (Table 14). Gestational mean body weights of dams in the 1,000 mg/L group were less than that of the vehicle control group by up to 5% by GD 21 (Table 15). During lactation, mean body weights of dams in the 1,000 mg/L group were significantly decreased by 3%, 3%, and 4% relative to the vehicle control group at LD 1, LD 17, and LD 21, respectively (Table 15).

Table 14 Summary of the Disposition of F_0_ Female Rats during Perinatal Exposure in the Perinatal and Two-year Drinking Water Study of Sodium Tungstate Dihydrate

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Reproductive Performance
Time-mated Females (GD 6) | 47 | 41 | 41 | 41
Females Pregnant (%)^a^ | 41 (87.2) | 34 (82.9) | 36 (87.8) | 36 (87.8)
Females Not Pregnant (%) | 6 (12.8) | 7 (17.1) | 5 (12.2) | 5 (12.2)
Dams Not Delivering with Evidence of Pregnancy (%) | 0 | 0 | 1 (2.8)^b^ | 2 (5.6)
Dams with Litters on LD 0 (%) | 41 (100.0) | 34 (100.0) | 35 (100.0) | 34 (94.4)
Litters Poststandardization (LD 4)^c^ | 37 | 33 | 33 | 32

GD = gestation day; LD = lactation day.

^a^ Statistical analysis performed by the Cochran-Armitage (trend) and Fisher’s exact (pairwise) tests.

^b^ Dam died before littering.

^c^ Standardization to eight pups/litter (four pups/sex). Only litters with at least two pups/sex and at least eight pups total/litter were retained to continue on study.

Table 15 Summary of Mean Body Weights and Body Weight Gains of F_0_ Female Rats during Gestation and Lactation in the Perinatal and Two-year Drinking Water Study of Sodium Tungstate Dihydrate

Parameter^a,b^ | 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Gestation Day
6 | 233.4 ± 1.87 (41) | 236.6 ± 2.01 (34) | 236.2 ± 1.71 (36) | 233.4 ± 1.82 (36)
9 | 251.4 ± 2.07 (41) | 252.9 ± 2.10 (34) | 250.6 ± 1.93 (36) | 248.2 ± 1.61 (36)
12 | 265.7 ± 1.81 (41) | 267.1 ± 2.36 (34) | 264.5 ± 1.90 (36) | 260.7 ± 1.73 (36)
15 | 288.2 ± 2.21** (41) | 289.0 ± 2.45 (34) | 286.3 ± 2.05 (36) | 279.2 ± 1.90** (36)
18 | 325.7 ± 2.75** (41) | 326.9 ± 2.85 (34) | 323.8 ± 2.56 (36) | 312.6 ± 2.96** (36)
21 | 373.7 ± 4.07** (41) | 377.0 ± 3.44 (34) | 371.0 ± 3.45 (36) | 354.3 ± 4.76** (36)
Gestation Weight Change
Gestation Day Interval
6–9 | 17.9 ± 0.8** (41) | 16.3 ± 0.5 (34) | 14.3 ± 0.6** (36) | 14.8 ± 0.9** (36)
9–12 | 14.3 ± 1.0 (41) | 14.2 ± 0.7 (34) | 14.0 ± 0.5 (36) | 12.5 ± 0.6 (36)
12–15 | 22.5 ± 0.7** (41) | 21.9 ± 0.6 (34) | 21.8 ± 0.6 (36) | 18.5 ± 0.8** (36)
15–18 | 37.5 ± 1.2 (41) | 37.9 ± 0.9 (34) | 37.5 ± 0.9 (36) | 33.4 ± 1.6* (36)
18–21 | 48.0 ± 1.6** (41) | 50.1 ± 1.2 (34) | 47.2 ± 1.3 (36) | 41.7 ± 2.1** (36)
6–21 | 140.3 ± 3.6** (41) | 140.4 ± 2.1 (34) | 134.8 ± 2.6 (36) | 120.9 ± 4.8** (36)
Lactation Day
1 | 282.4 ± 2.04** (41) | 282.7 ± 2.49 (34) | 276.9 ± 2.01 (35) | 273.8 ± 2.16** (34)
4 | 295.1 ± 2.15* (41) | 295.7 ± 2.58 (34) | 291.8 ± 2.42 (35) | 288.7 ± 2.48 (34)
7 | 302.6 ± 2.04 (37) | 303.8 ± 2.65 (33) | 297.0 ± 2.74 (33) | 298.4 ± 2.07 (32)
10 | 312.8 ± 2.4* (37) | 310.4 ± 3.0 (32) | 308.6 ± 2.7 (32) | 305.0 ± 2.4 (32)
14 | 321.2 ± 2.45 (37) | 321.5 ± 2.66 (32) | 320.0 ± 2.66 (32) | 316.6 ± 2.48 (32)
17 | 320.5 ± 2.35* (37) | 321.0 ± 3.12 (32) | 321.9 ± 3.20 (32) | 309.9 ± 2.13* (32)
21 | 301.6 ± 2.70* (37) | 306.4 ± 3.45 (32) | 299.8 ± 3.84 (32) | 289.2 ± 4.05* (32)
Lactation Weight Change
Lactation Day Interval
1–4 | 12.7 ± 1.2 (41) | 12.9 ± 1.5 (34) | 15.0 ± 1.2 (35) | 15.0 ± 2.2 (34)
4–7 | 7.5 ± 1.2 (37) | 8.6 ± 1.1 (33) | 4.8 ± 1.5 (33) | 8.7 ± 1.9 (32)
7–10 | 10.2 ± 1.4 (37) | 6.4 ± 1.4 (32) | 10.9 ± 1.2 (32) | 6.5 ± 1.6 (32)
10–14 | 8.4 ± 1.6 (37) | 11.0 ± 2.0 (32) | 11.4 ± 1.6 (32) | 11.6 ± 2.0 (32)
14–17 | −0.7 ± 2.1 (37) | −0.5 ± 1.8 (32) | 1.8 ± 1.7 (32) | −6.7 ± 2.0 (32)
17–21 | −18.9 ± 2.6 (37) | −14.5 ± 2.8 (32) | −22.1 ± 3.3 (32) | −20.7 ± 3.5 (32)
1–21 | 19.5 ± 2.9 (37) | 24.2 ± 2.5 (32) | 22.5 ± 3.4 (32) | 15.0 ± 4.1 (32)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Each exposure group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^b^ Data presented as mean ± standard error (number of dams). Body weight data are presented in grams.

Summaries of water and ST consumption are presented in Table 16. Water consumption trends were similar during gestation and lactation. During gestation, water consumption of all ST-exposed groups was within 9% of the vehicle control group (ranging from 99% to 109%). During lactation, water consumption of all ST-exposed groups was within 8% of the vehicle control group (ranging from 92% to 100%) (Table 16). Daily ST consumption for the 250, 500, and 1,000 mg/L groups averaged approximately 32, 65, and 143 mg/kg/day, respectively, during GD 6–21, and approximately 48, 98, and 197 mg/kg/day, respectively, during LD 1–14 (Table 16).

Table 16 Summary of Water and Sodium Tungstate Dihydrate Consumption by F_0_ Female Rats during Gestation and Lactation in the Perinatal and Two-year Drinking Water Study

Parameter^a^ | 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Gestation Day Interval^b,c^
6–9 | 29.72 ± 0.83* (39) | 29.89 ± 0.77 (34) | 30.21 ± 0.91 (35) | 33.29 ± 1.03 (36)
9–12 | 31.55 ± 0.96 (41) | 32.01 ± 0.93 (34) | 31.92 ± 0.82 (36) | 34.46 ± 1.04 (36)
12–15 | 36.94 ± 0.79 (41) | 36.47 ± 0.89 (34) | 35.33 ± 0.91 (36) | 38.93 ± 1.06 (36)
15–18 | 43.39 ± 1.00* (41) | 44.50 ± 1.23 (34) | 43.54 ± 1.09 (36) | 47.06 ± 1.38* (36)
18–21 | 45.27 ± 1.16 (41) | 45.61 ± 1.25 (34) | 44.43 ± 1.13 (36) | 46.40 ± 1.54 (36)
6–21 | 37.31 ± 0.83* (39) | 37.70 ± 0.91 (34) | 37.19 ± 0.89 (35) | 40.03 ± 1.08 (36)
Lactation Day Interval^b,c^
1–4 | 47.08 ± 1.08 (41) | 46.17 ± 1.07 (34) | 46.03 ± 0.93 (35) | 46.36 ± 1.22 (34)
4–7 | 50.35 ± 1.05 (37) | 49.85 ± 1.09 (33) | 47.90 ± 0.92 (33) | 48.68 ± 0.81 (32)
7–10 | 63.61 ± 1.51 (37) | 60.39 ± 1.27 (32) | 60.49 ± 1.20 (32) | 60.80 ± 1.36 (32)
10–14 | 74.39 ± 1.27 (35) | 74.75 ± 1.18 (31) | 76.51 ± 1.43 (32) | 74.59 ± 1.49 (32)
14–17 | 86.82 ± 1.69* (37) | 82.54 ± 1.50 (32) | 85.16 ± 1.93 (32) | 80.28 ± 1.85 (32)
17–21 | 96.58 ± 1.57 (37) | 91.38 ± 1.92 (32) | 90.17 ± 2.46 (32) | 90.51 ± 2.68 (31)
1–14 | 59.71 ± 1.04 (35) | 58.86 ± 0.92 (31) | 59.17 ± 0.92 (32) | 59.10 ± 1.04 (32)
Chemical Intake (mg/kg/day)^d,e^
GD 6–21 | 0.00 ± 0.00 (39) | 32.49 ± 0.68 (34) | 64.77 ± 1.52 (35) | 143.2 ± 3.70 (36)
LD 1–14 | 0.00 ± 0.00 (35) | 48.14 ± 0.72 (31) | 97.92 ± 1.53 (32) | 197.3 ± 3.44 (32)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

GD = gestation day; LD = lactation day.

^a^ Data presented as mean ± standard error (number of dams).

^b^ Water consumption data are presented as grams/animal/day.

^c^ Each exposure group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^d^ Chemical intake calculated as: ([exposure concentration × water consumption]/[average body weight of day range]).

^e^ No statistical analysis was performed on the chemical intake data.

No significant clinical observations were noted in pups (Appendix G). No exposure-related differences were noted between the vehicle control groups and the ST-exposed groups in the number of litters, litter size, mean litter weights, sex ratio, or the pup mean weights of males and females on PND 1 or PND 4 (Table 17, Table 18). Litter size did not change appreciably between PND 1 and litter standardization on PND 4. Pups were weaned on PND 21, and this was considered day 1 of the 2-year exposure period.

Table 17 Summary of Mean Litter Size and Survival Ratio of F_1_ Male and Female Rats during Lactation in the Perinatal and Two-year Drinking Water Study of Sodium Tungstate Dihydrate

Parameter | 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
PND 1^a,b^
Total | 12.83 ± 0.45 (41) | 13.15 ± 0.31 (34) | 13.03 ± 0.36 (35) | 11.82 ± 0.49 (34)
Live | 12.51 ± 0.49 (41) | 12.82 ± 0.33 (34) | 12.69 ± 0.37 (35) | 11.68 ± 0.51 (34)
% Male per Litter | 51.83 ± 2.36 (41) | 49.27 ± 3.10 (34) | 47.95 ± 2.53 (35) | 51.42 ± 2.04 (34)
% Male^c,d^ | 52 (513) | 50 (436) | 48 (444) | 52 (397)
Male^a,b^
PND 1 | 6.54 ± 0.42 (41) | 6.35 ± 0.44 (34) | 6.11 ± 0.38 (35) | 6.03 ± 0.37 (34)
PND 4 Prestandardization | 6.51 ± 0.42 (41) | 6.29 ± 0.44 (34) | 6.11 ± 0.38 (35) | 6.03 ± 0.37 (34)
PND 4 Poststandardization | 4.05 ± 0.12 (37) | 4.00 ± 0.13 (33) | 3.97 ± 0.08 (33) | 3.97 ± 0.07 (32)
Female^a,b^
PND 1 | 5.98 ± 0.33 (41) | 6.47 ± 0.37 (34) | 6.57 ± 0.33 (35) | 5.65 ± 0.34 (34)
PND 4 Prestandardization | 5.85 ± 0.34 (41) | 6.38 ± 0.39 (34) | 6.49 ± 0.34 (35) | 5.56 ± 0.33 (34)
PND 4 Poststandardization | 3.95 ± 0.12 (37) | 4.00 ± 0.13 (33) | 4.03 ± 0.08 (33) | 4.03 ± 0.07 (32)
Male and Female^a,b^
PND 4 Prestandardization | 12.37 ± 0.49 (41) | 12.68 ± 0.34 (34) | 12.60 ± 0.39 (35) | 11.59 ± 0.51 (34)
PND 4 Poststandardization | 8.00 ± 0.00 (37) | 8.00 ± 0.00 (33) | 8.00 ± 0.00 (33) | 8.00 ± 0.00 (32)
PND 21 | 7.92 ± 0.05 (37) | 7.94 ± 0.04 (32) | 7.94 ± 0.04 (32) | 7.81 ± 0.13 (32)
Survival per Litter
Total Dead: PND 1–4^d,e^ | 19 (41) | 16 (34) | 15 (35) | 8 (34)
Total Dead: PND 5–21^d,e^ | 3 (37) | 2 (32) | 2 (32) | 6 (32)
Dead: PND 1–4^a,b,f^ | 0.463 ± 0.140 (41) | 0.471 ± 0.185 (34) | 0.429 ± 0.170 (35) | 0.235 ± 0.085 (34)
Dead: PND 4–21^a,b,f^ | 0.081 ± 0.045 (37) | 0.063 ± 0.043 (32) | 0.063 ± 0.043 (32) | 0.188 ± 0.130 (32)
Survival Ratio: PND 1–4^a,b,g^ | 0.988 ± 0.007 (41) | 0.988 ± 0.007 (34) | 0.991 ± 0.005 (35) | 0.993 ± 0.004 (34)
Survival Ratio: PND 4–21^a,b,h^ | 0.990 ± 0.006 (37) | 0.992 ± 0.005 (32) | 0.992 ± 0.005 (32) | 0.977 ± 0.016 (32)

PND = postnatal day.

^a^ Each exposure group was compared to the vehicle control group with the Shirley test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunn test when no trend was present.

^b^ Data presented as mean ± standard error (number of litters).

^c^ 100 × [number of live males in exposure group]/[number of live males and females in exposure group].

^d^ No statistics done on this endpoint.

^e^ Total dead in exposure group (number of litters).

^f^ Number dead/litter.

^g^ Survival per litter: number of pups prestandardization on PND 4/total live pups on PND 1.

^h^ Survival per litter: number of live pups on PND 21/number of live pups poststandardization on PND 4.

Table 18 Summary of Preweaning F_1_ Male and Female Rat Pup Mean Body Weights Following Perinatal Exposure to Sodium Tungstate Dihydrate

Parameter | 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Male (g)
PND 1^a,b,c^ | 6.82 ± 0.07 (41) | 6.80 ± 0.08 (34) | 6.74 ± 0.07 (35) | 6.69 ± 0.11 (34)
PND 4^d,e,f^ | 9.80 ± 0.15 (267/41) | 9.30 ± 0.22 (214/34) | 9.75 ± 0.15 (214/35) | 9.18 ± 0.21* (205/34)
PND 7^d,e,g^ | 14.97 ± 0.35 (150/37) | 14.19 ± 0.37 (131/33) | 14.70 ± 0.35 (131/33) | 14.35 ± 0.34 (125/32)
PND 14^d,e,g^ | 30.97 ± 0.65 (148/37) | 30.12 ± 0.48 (126/32) | 30.26 ± 0.55 (126/32) | 29.84 ± 0.55 (125/32)
PND 21^d,e,g^ | 51.32 ± 1.05 (148/37) | 49.48 ± 0.86 (126/32) | 49.77 ± 0.94 (126/32) | 48.96 ± 1.08 (125/32)
Female (g)
PND 1^a,b,c^ | 6.43 ± 0.08 (41) | 6.50 ± 0.09 (34) | 6.46 ± 0.07 (35) | 6.34 ± 0.09 (34)
PND 4^d,e,f^ | 9.31 ± 0.17 (240/41) | 8.98 ± 0.22 (217/34) | 9.43 ± 0.15 (226/35) | 8.86 ± 0.18 (189/34)
PND 7^d,e,g^ | 14.19 ± 0.35 (146/37) | 13.67 ± 0.41 (130/33) | 14.21 ± 0.36 (131/33) | 13.56 ± 0.34 (128/32)
PND 14^d,e,g^ | 29.71 ± 0.65 (145/37) | 29.17 ± 0.52 (128/32) | 29.55 ± 0.63 (128/32) | 28.39 ± 0.69 (125/32)
PND 21^d,e,g^ | 48.27 ± 1.03 (145/37) | 47.00 ± 0.87 (128/32) | 47.59 ± 0.92 (128/32) | 46.26 ± 1.10 (125/32)
Male and Female (g)
PND 1^a,b,c^ | 6.63 ± 0.07 (41) | 6.65 ± 0.09 (34) | 6.60 ± 0.07 (35) | 6.52 ± 0.10 (34)
PND 4^d,e,f^ | 9.58 ± 0.16 (507/41) | 9.14 ± 0.22 (431/34) | 9.59 ± 0.15 (440/35) | 9.05 ± 0.19 (394/34)
PND 7^d,e,g^ | 14.60 ± 0.34 (296/37) | 13.94 ± 0.37 (261/33) | 14.47 ± 0.36 (262/33) | 13.95 ± 0.34 (253/32)
PND 14^d,e,g^ | 30.37 ± 0.63 (293/37) | 29.64 ± 0.49 (254/32) | 29.91 ± 0.58 (254/32) | 29.18 ± 0.54 (250/32)
PND 21^d,e,g^ | 49.84 ± 1.01 (293/37) | 48.23 ± 0.85 (254/32) | 48.71 ± 0.91 (254/32) | 47.64 ± 1.01 (250/32)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05.

PND = postnatal day.

^a^ Data presented as mean ± standard error (number of litters).

^b^ Each exposure group was compared to the vehicle control group with the Williams test when a trend was present (p ≤ 0.01 from the Jonckheere trend test) or with the Dunnett test when no trend was present.

^c^ Litter weights of live pups at PND 1 were divided by live litter size on PND 1 to obtain a pup mean weight/litter. Mean values were then adjusted using live litter size on PND 1 as a covariate.

^d^ Statistical analysis was performed using mixed models with random litter effect for both trend and pairwise tests, using the Dunnett-Hsu adjustment for multiple comparisons.

^e^ Data presented as the mean of litter means ± standard error (number of pups/number of litters).

^f^ PND 4 prestandardization.

^g^ Individual pup weights first adjusted for live litter size on PND 4 poststandardization.

Plasma from up to five dams per exposure group along with plasma from one pup/sex/dam were collected on PND 21. Total tungsten concentrations were determined using a validated analytical method (Appendix E). In dams, tungsten concentrations increased with the exposure concentration (Table 19). Tungsten was also detected in male and female pups with concentrations slightly lower than in dams, suggesting significant exposure of pups to tungsten via lactation and/or from direct consumption of dosed drinking water. There was no apparent sex difference in tungsten concentrations in the pups.

Table 19 Summary of Internal Dose Data for F_0_ Female Rats and Pups in the Perinatal and Two-year Drinking Water Study of Sodium Tungstate Dihydrate^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n | 5 | 5 | 5 | 5
Tungsten Concentration (μg/mL)
Postnatal Day 21
Dam plasma | BD | 1.54 ± 0.17 | 2.35 ± 0.10 | 3.82 ± 0.84
Male pup plasma | BD | 0.84 ± 0.17 | 1.48 ± 0.30 | 3.68 ± 0.89
Female pup plasma | BD | 0.76 ± 0.26 | 1.35 ± 0.18 | 2.58 ± 0.56^b^

BD = below detection; group did not have over 20% of its values above the limit of detection (LOD; 0.013 μg/mL).

^a^ Data are presented as mean ± standard error.

^b^ n = 4.

### Two-year Study (Interim Evaluations – 3, 6, 12, and 18 Months)

Ten predesignated rats/sex from each exposure group were evaluated at 3, 6, 12, or 18 months for organ weights and tungsten concentrations. Mean body weights of the 500 mg/L males were significantly decreased by approximately 12% relative to the vehicle control group at the 12-month time point (Table 20). Mean body weights of all other groups, both males and females, were within 10% of their respective vehicle control group at all interim evaluations (Table 20, Table 21).

Table 20 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Rats Exposed to Sodium Tungstate Dihydrate in Drinking Water for 3, 6, 12, and 18 Months^a,b^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Three Months^c^ | 10 | 10 | 10 | 10
Necropsy Body Wt. (g) | 420.7 ± 8.3* | 387.7 ± 8.9* | 407.8 ± 11.0* | 384.0 ± 6.3*
Kidneys
Absolute (g) | 2.82 ± 0.07 | 2.72 ± 0.07 | 2.81 ± 0.11 | 2.76 ± 0.08
Relative (mg/g)^d^ | 6.71 ± 0.10* | 7.02 ± 0.12 | 6.87 ± 0.14 | 7.17 ± 0.14*
Liver
Absolute (g) | 16.95 ± 0.55 | 14.84 ± 0.51* | 16.30 ± 0.74 | 15.48 ± 0.55
Relative (mg/g) | 40.23 ± 0.84 | 38.21 ± 0.65 | 39.85 ± 1.09 | 40.24 ± 0.96
Six Months | 10 | 10 | 10 | 10
Necropsy Body Wt. (g) | 481.4 ± 14.1 | 473.9 ± 9.9 | 467.3 ± 5.7 | 452.6 ± 12.0
Kidneys
Absolute (g) | 2.96 ± 0.12 | 2.87 ± 0.08 | 2.84 ± 0.07 | 2.75 ± 0.05
Relative (mg/g) | 6.14 ± 0.11 | 6.05 ± 0.10 | 6.08 ± 0.14 | 6.09 ± 0.11
Liver
Absolute (g) | 15.55 ± 0.75 | 14.96 ± 0.59 | 15.03 ± 0.41 | 14.02 ± 0.50
Relative (mg/g) | 32.16 ± 0.79 | 31.48 ± 0.72 | 32.19 ± 0.85 | 30.95 ± 0.63
Twelve Months | 8 | 10 | 10 | 10
Necropsy Body Wt. (g) | 586.4 ± 18.8* | 571.9 ± 16.3 | 515.3 ± 15.8* | 524.8 ± 18.5
Kidneys
Absolute (g) | 3.57 ± 0.09 | 3.45 ± 0.10 | 3.10 ± 0.11* | 3.31 ± 0.14
Relative (mg/g) | 6.11 ± 0.19 | 6.04 ± 0.15 | 6.03 ± 0.19 | 6.32 ± 0.20
Liver
Absolute (g) | 21.84 ± 0.93** | 19.46 ± 0.44* | 18.26 ± 0.73** | 18.09 ± 0.91**
Relative (mg/g) | 37.25 ± 1.08 | 34.20 ± 0.95 | 35.40 ± 0.81 | 34.38 ± 0.79
Eighteen Months | 8 | 9 | 8 | 9
Necropsy Body Wt. (g) | 604.9 ± 24.1* | 609.5 ± 14.2 | 594.2 ± 15.6 | 500.0 ± 33.6*
Kidneys
Absolute (g) | 4.57 ± 0.36** | 4.04 ± 0.19 | 3.84 ± 0.11* | 3.28 ± 0.18**
Relative (mg/g) | 7.72 ± 0.81 | 6.64 ± 0.34 | 6.48 ± 0.23 | 6.67 ± 0.32
Liver
Absolute (g) | 21.01 ± 0.64** | 21.98 ± 0.78 | 19.91 ± 1.10 | 17.28 ± 1.31*
Relative (mg/g) | 34.90 ± 0.96 | 36.03 ± 0.75 | 33.46 ± 1.46 | 34.47 ± 0.82

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and the Williams or Dunnett (pairwise) tests.

^c^ Number of animals examined at each time point.

^d^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

Table 21 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Female Rats Exposed to Sodium Tungstate Dihydrate in Drinking Water for 3, 6, 12, and 18 Months^a,b^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Three Months^c^ | 10 | 10 | 10 | 10
Necropsy Body Wt. (g) | 251.6 ± 3.9 | 257.2 ± 6.9 | 245.6 ± 5.9 | 236.9 ± 6.5
Kidneys
Absolute (g) | 1.67 ± 0.03 | 1.66 ± 0.05 | 1.66 ± 0.06 | 1.67 ± 0.05
Relative (mg/g)^d^ | 6.64 ± 0.09 | 6.45 ± 0.14 | 6.74 ± 0.20 | 7.05 ± 0.13
Liver
Absolute (g) | 9.01 ± 0.14 | 9.25 ± 0.46 | 9.09 ± 0.31 | 8.59 ± 0.31
Relative (mg/g) | 35.82 ± 0.53 | 35.83 ± 1.04 | 36.94 ± 0.55 | 36.23 ± 0.74
Six Months | 10 | 10 | 10 | 10
Necropsy Body Wt. (g) | 278.8 ± 4.0 | 277.3 ± 6.7 | 287.5 ± 6.4 | 275.6 ± 7.4
Kidneys
Absolute (g) | 1.71 ± 0.03** | 1.67 ± 0.04 | 1.82 ± 0.05* | 1.83 ± 0.03*
Relative (mg/g) | 6.12 ± 0.04** | 6.04 ± 0.08 | 6.32 ± 0.11 | 6.67 ± 0.17**
Liver
Absolute (g) | 8.66 ± 0.37 | 8.69 ± 0.35 | 9.09 ± 0.34 | 8.45 ± 0.27
Relative (mg/g) | 31.01 ± 1.14 | 31.23 ± 0.64 | 31.59 ± 0.91 | 30.73 ± 0.92
Twelve Months | 9 | 10 | 10 | 10
Necropsy Body Wt. (g) | 313.9 ± 16.0 | 336.9 ± 15.7 | 310.0 ± 9.6 | 290.9 ± 10.5
Kidneys
Absolute (g) | 1.87 ± 0.07 | 1.95 ± 0.05 | 2.06 ± 0.06 | 1.93 ± 0.06
Relative (mg/g) | 6.02 ± 0.21** | 5.84 ± 0.16 | 6.68 ± 0.22* | 6.67 ± 0.23*
Liver
Absolute (g) | 9.61 ± 0.44 | 10.81 ± 0.53 | 10.03 ± 0.49 | 8.73 ± 0.36
Relative (mg/g) | 30.74 ± 0.84 | 32.40 ± 1.64 | 32.33 ± 1.12 | 30.06 ± 0.99
Eighteen Months | 10 | 8 | 10 | 8
Necropsy Body Wt. (g) | 359.5 ± 11.5* | 372.9 ± 25.5 | 353.8 ± 11.5 | 313.6 ± 16.4
Kidneys
Absolute (g) | 2.20 ± 0.06 | 2.12 ± 0.05 | 2.12 ± 0.08 | 2.05 ± 0.06
Relative (mg/g) | 6.16 ± 0.16 | 5.91 ± 0.49 | 6.02 ± 0.26 | 6.63 ± 0.28
Liver
Absolute (g) | 10.97 ± 0.52* | 11.58 ± 0.64 | 10.54 ± 0.58 | 9.49 ± 0.50
Relative (mg/g) | 30.67 ± 1.52 | 31.98 ± 2.75 | 29.83 ± 1.47 | 30.29 ± 0.62

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data presented as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and the Williams or Dunnett (pairwise) tests.

^c^ Number of animals examined at each time point.

^d^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

The mean relative kidney weights were significantly increased at 3 months in the 1,000 mg/L males relative to the vehicle control group (Table 20); in females, there were no significant differences in kidney weights between exposed groups and the vehicle control group (Table 21). At 6 months, there were no significant differences in the kidney weights of males (Table 20), but in females, the mean absolute kidney weights were significantly increased in the 500 mg/L and 1,000 mg/L groups by approximately 6% and 7%, respectively, compared to the vehicle control group, and the mean relative kidney weight was significantly increased in the 1,000 mg/L group (Table 21). By 12 months, the mean absolute kidney weight was significantly decreased by approximately 13% in the 500 mg/L males compared to the vehicle control males (Table 20), and in females, the mean relative kidney weights were significantly increased in the 500 and 1,000 mg/L groups, relative to the vehicle control group (Table 21). At 18 months, mean absolute kidney weights were significantly decreased in the 500 and 1,000 mg/L males, by approximately 16% and 28%, respectively, relative to the vehicle control group (Table 20), whereas in females, there were no significant differences in kidney weights (Table 21).

At 3 months, the mean absolute liver weights were significantly decreased relative to the vehicle control group by approximately 12% in the 250 mg/L males. By 12 months, the mean absolute liver weights were significantly decreased relative to the vehicle control group in all male exposed groups by approximately 11%, 16%, and 17% in the 250, 500 and 1,000 mg/L males, respectively (Table 20). At 18 months, the mean absolute liver weight was significantly decreased relative to the vehicle control group by approximately 18% in the 1,000 mg/L males (Table 20). In females, the trend was significant for decreased absolute liver weight with increasing exposure concentration at 18 months (Table 21). The biological importance of these changes in liver weights is unknown; no liver effects were observed histologically in the 2-year study.

Other sporadic differences in organ weights were considered isolated changes of no toxicological significance (Appendix G).

Plasma, kidney, and urine from up to 10 animals per exposure group were collected from interim animals at 3, 6, 12, and 18 months. Total tungsten concentrations in all matrices were determined using validated analytical methods (Appendix E). In male rats, plasma tungsten concentrations increased proportionally with exposure concentration at all time points (except at 18 months for the 500 mg/L group) with no observed differences between time points (Table 22; Figure 3A). In female rats, plasma tungsten concentrations increased proportionally with exposure concentration up to 500 mg/L at all time points (except at 18 months for the 250 mg/L group); however, at 1,000 mg/L, the trend was toward a more-than-proportional increase in tungsten concentrations with increasing exposure concentration (Table 23; Figure 3A). Low tungsten concentrations were observed in some vehicle control groups; however, tungsten concentrations in exposed groups were significantly higher than those in corresponding vehicle control groups. There was no observed sex difference in plasma tungsten concentrations in rats (Table 22, Table 23; Figure 3A).

Table 22 Summary of Plasma, Kidney, and Urine Tungsten Concentration Data for Male Rats Exposed to Sodium Tungstate Dihydrate in Drinking Water for 3, 6, 12, and 18 Months^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Three Months
Kidney (μg/g) | BD | 2.79 ± 0.24 (10) | 5.30 ± 0.50 (10) | 10.50 ± 2.94 (10)
Plasma (μg/mL)^b,c^ | 0.01 ± 0.00** (10) | 1.34 ± 0.20** (10) | 2.91 ± 0.27** (10) | 5.87 ± 0.54** (10)
Kidney/Plasma Ratio^d^ | BD | 2.51 ± 0.42 (10) | 1.87 ± 0.16 (10) | 1.83 ± 0.51 (10)
Urine^b,c^
Urine (μg/mL urine) | 0.04 ± 0.01** (10) | 135.36 ± 16.14** (9) | 321.33 ± 21.53** (9) | 862.80 ± 58.27** (10)
Urine (μg/mg creatinine) | 0.02 ± 0.00** (10) | 101.00 ± 12.63** (9) | 268.52 ± 30.82** (9) | 663.17 ± 41.98** (10)
Six Months
Kidney (μg/g) | BD | 6.77 ± 2.13 (10) | 13.40 ± 1.86 (10) | 14.11 ± 1.05 (10)
Plasma (μg/mL)^b,c^ | 0.02 ± 0.00** (10) | 1.37 ± 0.14** (10) | 4.89 ± 1.02** (10) | 6.48 ± 0.78** (10)
Kidney/Plasma Ratio | BD | 5.55 ± 2.04 (10) | 3.39 ± 0.64 (10) | 2.45 ± 0.33 (10)
Urine^b,c^
Urine (μg/mL urine) | 0.04 ± 0.00** (10) | 143.37 ± 16.83** (10) | 258.30 ± 27.17** (10) | 572.10 ± 59.06** (10)
Urine (μg/mg creatinine) | 0.03 ± 0.00** (10) | 107.36 ± 10.22** (10) | 216.91 ± 30.97** (10) | 338.59 ± 41.61** (10)
Twelve Months
Kidney (μg/g) | BD | 14.84 ± 2.09 (10) | 20.42 ± 3.85 (10) | 27.98 ± 2.71 (10)
Plasma (μg/mL)^b,c^ | 0.01 ± 0.00** (8) | 2.22 ± 0.25** (10) | 3.85 ± 0.62** (10) | 7.05 ± 0.55** (10)
Kidney/Plasma Ratio | BD | 7.50 ± 1.09 (10) | 6.22 ± 1.26 (10) | 4.11 ± 0.45 (10)
Urine^b,c^
Urine (μg/mL urine) | 1.29 ± 0.95** (8) | 161.92 ± 15.97** (10) | 368.70 ± 52.38** (10) | 654.23 ± 125.91** (10)
Urine (μg/mg creatinine) | 2.05 ± 1.76** (8) | 94.50 ± 14.54** (10) | 284.48 ± 66.96** (10) | 435.73 ± 65.39** (10)
Eighteen Months
Kidney (μg/g)^b,c^ | 0.05 ± 0.01** (6) | 25.74 ± 3.34** (9) | 30.27 ± 5.21** (8) | 74.90 ± 20.04** (9)
Plasma (μg/mL) | BD | 2.64 ± 0.35 (9) | 2.34 ± 0.95 (8) | 7.59 ± 2.66 (9)
Kidney/Plasma Ratio | BD | 12.63 ± 3.18 (9) | 24.26 ± 8.14 (8) | 16.69 ± 4.27 (9)
Urine^b,c^
Urine (μg/mL urine) | 0.03 ± 0.01** (9) | 121.77 ± 9.17** (9) | 159.93 ± 28.11** (8) | 390.11 ± 38.03** (9)
Urine (μg/mg creatinine) | 0.03 ± 0.01** (8) | 104.37 ± 7.08** (9) | 156.40 ± 27.17** (7) | 436.76 ± 109.49** (9)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BD = below detection; group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Data presented as mean ± standard error (n).

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^c^ Values below the LOD (0.013 μg/mL) were substituted with 1/2 the LOD value. If 80% or more of the values in the vehicle control group were below the LOD, no mean or standard error were calculated, and no statistical analysis was performed.

^d^ For the kidney/plasma ratio calculation, a plasma density of 1 g/mL was assumed.

Figure 3

Tungsten Concentrations in Plasma, Kidney, and Urine in Rats Exposed to Sodium Tungstate Dihydrate in Drinking Water for 3, 6, 12, and 18 Months

Study day (SD) 93 = 3 months; SD 185 = 9 months; SD 367 = 12 months; SD 549 = 18 months.

Table 23 Summary of Plasma, Kidney, and Urine Tungsten Concentration Data for Female Rats Exposed to Sodium Tungstate Dihydrate in Drinking Water for 3, 6, 12, and 18 Months^a^

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Three Months
Kidney (μg/g) | BD | 3.92 ± 0.24 (10) | 6.39 ± 0.52 (10) | 11.93 ± 0.71 (10)
Plasma (μg/mL) | BD | 1.92 ± 0.13 (10) | 3.67 ± 0.58 (10) | 10.99 ± 1.40 (10)
Kidney/Plasma Ratio^b^ | BD | 2.06 ± 0.08 (10) | 1.92 ± 0.18 (10) | 1.17 ± 0.09 (10)
Urine^c,d^
Urine (μg/mL urine) | 0.04 ± 0.01** (10) | 167.30 ± 9.11** (10) | 355.50 ± 26.36** (8) | 512.20 ± 43.84** (10)
Urine (μg/mg creatinine) | 0.05 ± 0.01** (10) | 247.12 ± 14.01** (10) | 484.15 ± 56.46** (8) | 809.98 ± 103.55** (10)
Six Months
Kidney (μg/g) | BD | 6.65 ± 0.92 (10) | 9.89 ± 0.67 (10) | 17.11 ± 1.81 (10)
Plasma (μg/mL)^c,d^ | 0.05 ± 0.01** (10) | 2.41 ± 0.43** (10) | 4.01 ± 0.39** (10) | 10.44 ± 1.38** (10)
Kidney/Plasma Ratio | BD | 2.96 ± 0.32 (10) | 2.56 ± 0.13 (10) | 1.70 ± 0.11 (10)
Urine^c,d^
Urine (μg/mL urine) | 0.04 ± 0.01** (10) | 174.10 ± 10.74** (10) | 413.30 ± 20.05** (10) | 619.20 ± 50.46** (10)
Urine (μg/mg creatinine) | 0.05 ± 0.00** (10) | 228.49 ± 20.07** (10) | 467.46 ± 40.93** (10) | 856.85 ± 58.29** (10)
Twelve Months
Kidney (μg/g) | BD | 10.62 ± 0.53 (10) | 19.26 ± 1.89 (10) | 31.65 ± 2.20 (10)
Plasma (μg/mL)^c,d^ | 0.03 ± 0.01** (8)^e^ | 2.47 ± 0.29** (10) | 4.55 ± 0.33** (10) | 12.06 ± 1.31** (10)
Kidney/Plasma Ratio | 4.57 ± 0.85** (4) | 4.76 ± 0.50 (10) | 4.36 ± 0.42 (10) | 2.96 ± 0.48 (10)
Urine^c,d^
Urine (μg/mL urine) | 0.07 ± 0.02** (9) | 158.00 ± 8.45** (10) | 291.60 ± 17.88** (10) | 672.30 ± 51.25** (10)
Urine (μg/mg creatinine) | 0.10 ± 0.02** (8) | 298.03 ± 26.20** (10) | 567.24 ± 42.20** (10) | 1,036.16 ± 57.95** (10)
Eighteen Months
Kidney (μg/g)^c,d^ | 0.09 ± 0.01** (3) | 25.89 ± 7.69* (8) | 27.96 ± 2.79** (10) | 43.29 ± 2.90** (8)
Plasma (μg/mL)^c,d^ | 0.02 ± 0.00** (2) | 5.45 ± 3.00* (8) | 5.71 ± 0.59* (10) | 11.78 ± 1.51** (8)
Kidney/Plasma Ratio | NR^f^ | 7.11 ± 1.17 (8) | 5.47 ± 0.79 (10) | 3.99 ± 0.42 (8)
Urine^c,d^
Urine (μg/mL urine) | 0.03 ± 0.00** (8) | 162.00 ± 17.50** (8) | 328.11 ± 37.85** (9) | 612.38 ± 47.87** (8)
Urine (μg/mg creatinine) | 0.05 ± 0.01** (8) | 349.42 ± 34.89** (8) | 628.91 ± 105.62** (9) | 1,089.91 ± 100.25** (8)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BD = below detection; group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Data presented as mean ± standard error (n).

^b^ For the kidney/plasma ratio calculation, a plasma density of 1 g/mL was assumed.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^d^ Values below the LOD (0.013 μg/mL) were substituted with 1/2 the LOD value. If 80% or more of the values in the vehicle control group were below the LOD, no mean or standard error were calculated, and no statistical analysis was performed.

^e^ The plasma concentration value for one female in the 0 mg/L group at 12 months was excluded from the analysis as an implausible value.

^f^ The kidney/plasma ratio could not be calculated for females in the 0 mg/L group at 18 months because no animals in the group had concentration measures for both kidney and plasma.

In male rats, at 3 months, tungsten concentrations in the kidney increased proportionally with exposure concentration (Table 22; Figure 3B); however, the trend was toward a less-than-proportional increase in tungsten concentrations with increasing exposure concentration at 6, 12, and 18 months in males (except at 18 months for the 1,000 mg/L group) and at all time points in females (Table 22, Table 23; Figure 3B). Kidney tungsten concentrations increased with increasing exposure duration and concentration in both males and females, with the kidney/plasma ratio >1 (Table 22, Table 23). Taken collectively, these data demonstrate that tungsten is retained in the kidney, and the retention increases with the exposure duration (Figure 3B). Low tungsten concentrations were observed in some vehicle control groups; however, tungsten concentrations in exposed groups were significantly higher than those in corresponding vehicle control groups. There were no observed sex differences in kidney tungsten concentrations in rats (Table 22, Table 23; Figure 3B).

Tungsten concentrations in urine are presented as both μg/mL of urine and μg/mg creatinine. Creatinine-corrected tungsten concentrations in urine increased with exposure concentration in both males and females (Figure 3C). The trend was toward a less-than-proportional increase in tungsten concentration with increasing exposure concentration and an increase in tungsten concentration with exposure duration, both of which were more evident in females than in males. Depending on the exposure concentration and duration, females excreted 1.2- to 4-fold more tungsten in urine compared to males (Table 22, Table 23). Low tungsten concentrations were observed in some vehicle control groups; however, the tungsten concentrations in exposed groups were significantly higher than those in the corresponding vehicle control groups.

### Two-year Study (Postweaning Phase)

#### Survival

Survival to study termination was significantly increased in the groups of exposed male rats compared to the vehicle control males (Table 24; Figure 4). The survival of the vehicle control males was lower than that typically seen in groups of control male Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats in previous 2-year NTP studies. Early deaths in the vehicle control males were attributed at necropsy primarily to CPN (22 animals). Pituitary gland adenomas were listed as the cause of death at necropsy for six vehicle control males, compared to two, two, and one animal in the 250, 500, and 1,000 mg/L males, respectively. The large number of vehicle control males with CPN as a cause of death at necropsy corresponded to an increased severity of nephropathy observed histologically in that group. There were no exposure-related differences in the survival of female groups.

Table 24 Summary of Survival of Male and Female Rats in the Perinatal and Two-year Drinking Water Study of Sodium Tungstate Dihydrate

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
Male
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 17 | 14 | 10 | 8
Natural Deaths | 21 | 10 | 16 | 13
Animals Surviving to Study Termination | 12 | 26 | 24^a^ | 29
Percent Probability of Survival at End of Study^b^ | 24.0% | 52.0% | 48.0% | 58.0%
Mean Survival (Days)^c^ | 620.7 ± 17.4 | 656.6 ± 20.3 | 670.6 ± 13.7 | 657.4 ± 17.6
Survival Analysis^d^ | p = 0.008N | p = 0.028N | p = 0.018N | p = 0.004N
Female
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 13 | 10 | 13 | 9
Natural Deaths | 7 | 7 | 6 | 10
Animals Surviving to Study Termination | 30 | 33 | 31 | 31^e^
Percent Probability of Survival at End of Study | 60.0% | 66.0% | 62.0% | 62.0%
Mean Survival (Days) | 667.0 ± 15.1 | 686.7 ± 12.3 | 661.8 ± 18.0 | 674.7 ± 14.8
Survival Analysis | p = 0.976N | p = 0.467N | p = 0.964 | p = 0.794

^a^ Includes one animal that died naturally during the last week of the study.

^b^ Kaplan-Meier determinations.

^c^ Mean of litter means of all deaths (uncensored, censored, and study termination) ± standard error.

^d^ The result of the Cox proportional hazards trend test with random litter effects is in the vehicle control group column, and the results of the proportional hazards pairwise comparisons to the vehicle control group with random litter effects are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^e^ Includes one animal that was euthanized moribund during the last week of the study.

Figure 4

Kaplan-Meier Survival Curves for Rats Exposed to Sodium Tungstate Dihydrate in Drinking Water for Two Years

#### Body Weights, Water and Compound Consumption, and Clinical Observations

At study termination, mean body weights of all groups of exposed males were within 10% of the vehicle control group (Table 25; Figure 5). In females, mean body weights of the 500 mg/L and 1,000 mg/L groups at study termination were 88.9% and 78.4% of the vehicle control group, respectively (Table 26; Figure 5).

Table 25 Summary of Survival and Mean Body Weights of Male Rats in the Perinatal and Two-year Drinking Water Study of Sodium Tungstate Dihydrate

Study Day^a^ | 0 mg/L | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L
Study Day^a^ | Av. Wt. (g)^a^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 53.2 | 25 | 52.2 | 98.2 | 25 | 52.6 | 98.9 | 25 | 52.6 | 98.9 | 25
8 | 82.2 | 25 | 81.1 | 98.6 | 25 | 82.3 | 100.1 | 25 | 80.7 | 98.2 | 25
15 | 127.5 | 25 | 125.7 | 98.6 | 25 | 127.4 | 100.0 | 25 | 118.0 | 92.5 | 25
22 | 178.3 | 25 | 174.4 | 97.8 | 25 | 177.1 | 99.3 | 25 | 156.0 | 87.5 | 25
29 | 226.9 | 25 | 222.1 | 97.9 | 25 | 225.2 | 99.2 | 25 | 194.0 | 85.5 | 25
36 | 271.3 | 25 | 267.6 | 98.6 | 25 | 269.1 | 99.2 | 25 | 235.4 | 86.8 | 25
43 | 304.9 | 25 | 302.9 | 99.3 | 25 | 301.3 | 98.8 | 25 | 270.5 | 88.7 | 25
50 | 326.8 | 25 | 324.7 | 99.3 | 25 | 325.7 | 99.7 | 25 | 299.4 | 91.6 | 25
57 | 352.9 | 25 | 349.8 | 99.1 | 25 | 350.5 | 99.3 | 25 | 325.6 | 92.3 | 25
64 | 371.4 | 25 | 363.8 | 97.9 | 25 | 366.8 | 98.8 | 25 | 345.9 | 93.1 | 25
71 | 386.9 | 25 | 380.7 | 98.4 | 25 | 378.1 | 97.7 | 25 | 357.1 | 92.3 | 25
78 | 399.7 | 25 | 394.7 | 98.7 | 25 | 392.3 | 98.1 | 25 | 374.5 | 93.7 | 25
85 | 411.8 | 25 | 405.7 | 98.5 | 25 | 402.3 | 97.7 | 25 | 385.6 | 93.6 | 25
92 | 419.1 | 25 | 415.4 | 99.1 | 25 | 408.9 | 97.6 | 25 | 395.5 | 94.4 | 25
120 | 443.5 | 25 | 431.7 | 97.4 | 25 | 429.7 | 96.9 | 25 | 420.0 | 94.7 | 25
148 | 466.5 | 25 | 459.1 | 98.4 | 25 | 448.9 | 96.2 | 25 | 442.1 | 94.8 | 25
176 | 489.9 | 25 | 478.8 | 97.7 | 25 | 471.6 | 96.3 | 25 | 460.6 | 94.0 | 25
204 | 505.2 | 25 | 494.7 | 97.9 | 25 | 487.0 | 96.4 | 25 | 476.7 | 94.4 | 25
232 | 521.0 | 25 | 508.6 | 97.6 | 25 | 500.1 | 96.0 | 25 | 491.5 | 94.3 | 25
260 | 537.7 | 25 | 523.7 | 97.4 | 25 | 517.0 | 96.1 | 25 | 505.3 | 94.0 | 25
288 | 549.3 | 25 | 533.1 | 97.0 | 25 | 528.4 | 96.2 | 25 | 516.2 | 94.0 | 25
316 | 560.4 | 25 | 547.1 | 97.6 | 25 | 540.4 | 96.4 | 25 | 527.5 | 94.1 | 25
344 | 573.4 | 25 | 555.6 | 96.9 | 25 | 553.2 | 96.5 | 25 | 537.9 | 93.8 | 25
372 | 585.5 | 25 | 570.5 | 97.4 | 25 | 561.7 | 95.9 | 25 | 547.6 | 93.5 | 25
400 | 593.9 | 25 | 580.4 | 97.7 | 25 | 572.1 | 96.3 | 25 | 555.5 | 93.5 | 25
428 | 598.3 | 25 | 589.3 | 98.5 | 25 | 579.9 | 96.9 | 25 | 561.8 | 93.9 | 25
456 | 601.3 | 25 | 589.9 | 98.1 | 25 | 584.7 | 97.2 | 25 | 566.2 | 94.2 | 25
484 | 603.4 | 25 | 595.5 | 98.7 | 25 | 589.1 | 97.6 | 25 | 568.4 | 94.2 | 25
512 | 606.9 | 25 | 597.1 | 98.4 | 25 | 589.5 | 97.1 | 25 | 566.7 | 93.4 | 25
540 | 602.0 | 25 | 596.8 | 99.1 | 25 | 587.0 | 97.5 | 25 | 564.0 | 93.7 | 25
568 | 595.3 | 25 | 594.7 | 99.9 | 23 | 578.2 | 97.1 | 25 | 558.6 | 93.8 | 25
596 | 593.0 | 23 | 588.5 | 99.2 | 22 | 576.8 | 97.3 | 24 | 552.7 | 93.2 | 25
624 | 586.2 | 21 | 589.2 | 100.5 | 21 | 566.4 | 96.6 | 24 | 557.9 | 95.2 | 24
652 | 580.7 | 18 | 572.2 | 98.5 | 21 | 576.3 | 99.3 | 22 | 551.3 | 94.9 | 23
680 | 582.7 | 12 | 551.4 | 94.6 | 19 | 551.0 | 94.6 | 22 | 545.5 | 93.6 | 23
708 | 601.8 | 9 | 559.8 | 93.0 | 15 | 550.9 | 91.5 | 19 | 548.3 | 91.1 | 21
EOS | 587.2 | 9 | 545.7 | 92.9 | 15 | 551.8 | 94.0 | 16 | 545.1 | 92.8 | 21

EOS = end of study; No. of litters = number of litters represented in weight average.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are means of litter means.

Figure 5

Growth Curves for Rats Exposed to Sodium Tungstate Dihydrate in Drinking Water for Two Years

Table 26 Summary of Survival and Mean Body Weights of Female Rats in the Perinatal and Two-year Drinking Water Study of Sodium Tungstate Dihydrate

Study Day^a^ | 0 mg/L | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L
Study Day^a^ | Av. Wt. (g)^b^ | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 51.4 | 25 | 49.7 | 96.6 | 25 | 49.8 | 96.9 | 25 | 52.1 | 101.2 | 25
8 | 78.6 | 25 | 76.9 | 97.9 | 25 | 77.6 | 98.7 | 25 | 76.0 | 96.7 | 25
15 | 113.7 | 25 | 109.1 | 95.9 | 25 | 110.6 | 97.2 | 25 | 100.6 | 88.5 | 25
22 | 139.1 | 25 | 136.0 | 97.8 | 25 | 135.6 | 97.5 | 25 | 122.9 | 88.3 | 25
29 | 166.2 | 25 | 162.9 | 98.0 | 25 | 163.3 | 98.3 | 25 | 144.9 | 87.2 | 25
36 | 180.9 | 25 | 181.7 | 100.5 | 25 | 181.3 | 100.3 | 25 | 164.5 | 90.9 | 25
43 | 198.4 | 25 | 199.3 | 100.4 | 25 | 194.8 | 98.2 | 25 | 185.6 | 93.5 | 25
50 | 211.8 | 25 | 212.5 | 100.3 | 25 | 207.6 | 98.0 | 25 | 201.8 | 95.3 | 25
57 | 222.7 | 25 | 225.0 | 101.1 | 25 | 220.3 | 99.0 | 25 | 215.0 | 96.6 | 25
64 | 227.2 | 25 | 224.8 | 99.0 | 25 | 223.1 | 98.2 | 25 | 215.1 | 94.7 | 25
71 | 233.4 | 25 | 229.9 | 98.5 | 25 | 227.5 | 97.5 | 25 | 226.5 | 97.0 | 25
78 | 241.6 | 25 | 238.9 | 98.9 | 25 | 239.7 | 99.2 | 25 | 235.8 | 97.6 | 25
85 | 247.4 | 25 | 245.0 | 99.0 | 25 | 243.5 | 98.4 | 25 | 241.0 | 97.4 | 25
92 | 254.4 | 25 | 249.5 | 98.1 | 25 | 249.1 | 97.9 | 25 | 246.5 | 96.9 | 25
120 | 266.2 | 25 | 259.3 | 97.4 | 25 | 261.2 | 98.1 | 25 | 258.9 | 97.3 | 25
148 | 275.0 | 25 | 273.4 | 99.4 | 25 | 269.7 | 98.0 | 25 | 266.4 | 96.9 | 25
176 | 286.4 | 25 | 283.1 | 98.9 | 25 | 278.6 | 97.3 | 25 | 275.7 | 96.3 | 25
204 | 290.4 | 25 | 289.3 | 99.6 | 25 | 280.2 | 96.5 | 25 | 284.4 | 97.9 | 25
232 | 295.5 | 25 | 297.6 | 100.7 | 25 | 289.2 | 97.9 | 25 | 291.9 | 98.8 | 25
260 | 303.1 | 25 | 302.8 | 99.9 | 25 | 293.0 | 96.7 | 25 | 297.7 | 98.2 | 25
288 | 307.0 | 25 | 311.6 | 101.5 | 25 | 299.8 | 97.7 | 25 | 301.7 | 98.3 | 25
316 | 317.7 | 25 | 320.1 | 100.7 | 25 | 305.5 | 96.1 | 25 | 307.1 | 96.6 | 25
344 | 324.4 | 25 | 324.8 | 100.1 | 25 | 309.8 | 95.5 | 25 | 312.8 | 96.4 | 25
372 | 332.0 | 25 | 329.6 | 99.3 | 25 | 314.9 | 94.8 | 25 | 316.9 | 95.4 | 25
400 | 343.4 | 25 | 338.1 | 98.5 | 25 | 321.6 | 93.6 | 25 | 323.3 | 94.2 | 25
428 | 348.4 | 25 | 342.8 | 98.4 | 25 | 325.4 | 93.4 | 25 | 325.7 | 93.5 | 25
456 | 354.2 | 25 | 353.0 | 99.7 | 25 | 337.2 | 95.2 | 24 | 327.5 | 92.5 | 25
484 | 364.9 | 25 | 359.6 | 98.6 | 25 | 345.8 | 94.8 | 24 | 331.8 | 90.9 | 25
512 | 365.5 | 25 | 363.0 | 99.3 | 25 | 355.2 | 97.2 | 24 | 333.2 | 91.2 | 25
540 | 381.5 | 25 | 371.1 | 97.3 | 25 | 365.8 | 95.9 | 24 | 342.6 | 89.8 | 25
568 | 377.9 | 24 | 377.3 | 99.8 | 25 | 376.4 | 99.6 | 24 | 339.0 | 89.7 | 25
596 | 385.4 | 24 | 384.3 | 99.7 | 25 | 363.6 | 94.3 | 22 | 345.3 | 89.6 | 25
624 | 393.9 | 24 | 388.1 | 98.5 | 25 | 370.7 | 94.1 | 22 | 342.5 | 86.9 | 24
652 | 392.7 | 24 | 390.5 | 99.4 | 25 | 381.9 | 97.3 | 21 | 335.4 | 85.4 | 23
680 | 384.1 | 24 | 381.9 | 99.4 | 25 | 366.2 | 95.3 | 21 | 330.1 | 85.9 | 23
708 | 386.1 | 22 | 384.4 | 99.6 | 24 | 372.8 | 96.5 | 21 | 326.9 | 84.7 | 22
EOS | 414.9 | 20 | 399.2 | 96.2 | 23 | 368.9 | 88.9 | 20 | 325.5 | 78.4 | 20

EOS = end of study; No. of litters = number of litters represented in weight average.

^a^ Study day 1 is the day animals were placed on study after pups were weaned.

^b^ Average weights shown are means of litter means.

Over the course of the chronic study, the respective mean water consumption for the 250, 500, and 1,000 mg/L groups averaged 93%, 99%, and 84% of the vehicle control males and averaged 95%, 100%, and 91% of the vehicle control females (Table 27, Table 28). The daily ST consumption averaged 14.2, 30.4, and 54.5 mg/kg/day for males, and 18.2, 39.3, and 74.3 mg/kg/day for females, respectively (Appendix G). Consumption at weeks 1, 13, 54, and 102 is presented in Table 27 and Table 28. Overall, the consumed dose of ST was of similar proportionality (ranging from 1.9- to 2.1-fold increase from one dose to the next) to the increase in ST concentration in drinking water (2-fold increases from one concentration to the next). Dose proportionality was consistent for both male and female rats (Table 27, Table 28). No clinical observations were considered exposure related (Appendix G).

Table 27 Summary of Water and Sodium Tungstate Dihydrate Consumption of Male Rats in the Perinatal and Two-year Drinking Water Study

Week | 0 mg/L | 250 mg/L | | 500 mg/L | | 1,000 mg/L
Week | Water (g/day)^a^ | Water (g/day) | Dose (mg/kg/day)^b^ | Water (g/day) | Dose (mg/kg/day) | Water (g/day) | Dose (mg/kg/day)
1 | 8.9 | 8.8 | 42.1 | 8.3 | 78.9 | 9.6 | 182.5
13 | 24.9 | 23.4 | 14.4 | 24.8 | 30.8 | 23.3 | 60.3
54 | 26.5 | 24.9 | 10.9 | 25.4 | 22.6 | 22.9 | 41.7
102 | 42.4 | 35.9 | 16.0 | 42.2 | 38.0 | 27.7 | 49.8

^a^ Grams of water consumed/animal/day.

^b^ Milligrams of sodium tungstate dihydrate consumed/kilogram body weight/day.

Table 28 Summary of Water and Sodium Tungstate Dihydrate Consumption of Female Rats in the Perinatal and Two-year Drinking Water Study of Sodium Tungstate Dihydrate

Week | 0 mg/L | 250 mg/L | | 500 mg/L | | 1,000 mg/L
Week | Water (g/day)^a^ | Water (g/day) | Dose (mg/kg/day)^b^ | Water (g/day) | Dose (mg/kg/day) | Water (g/day) | Dose (mg/kg/day)
1 | 10.2 | 9.9 | 49.8 | 10.3 | 103.3 | 9.9 | 190.1
13 | 20.0 | 18.2 | 18.6 | 18.9 | 38.8 | 17.6 | 73.0
54 | 22.7 | 21.0 | 15.8 | 22.3 | 35.5 | 19.9 | 62.7
102 | 27.0 | 24.7 | 16.1 | 29.0 | 39.6 | 28.1 | 87.4

^a^ Grams of water consumed per animal/day.

^b^ Milligrams of sodium tungstate dihydrate consumed/kilogram body weight/day.

#### Histopathology

This section describes the significant or biologically noteworthy changes in the incidence of neoplasms and nonneoplastic lesions of the thyroid gland, kidney, and uterus. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms are presented as supplemental data in Appendix G.

Thyroid Gland: There was a significant increase in the incidence of thyroid gland C-cell adenomas in the 500 mg/L females relative to the vehicle control group (Table 29). There was no significant increase in C-cell carcinomas, although the 1,000 mg/L females had a slightly higher incidence than the other exposure groups (Table 29). There were no significant differences in the incidences of C-cell adenoma or carcinoma (combined) in any exposed group compared to the vehicle control group; however, the incidences in the 250 and 500 mg/L groups were outside of the historical control range (Table 29). The incidences of C-cell hyperplasia were not significantly increased in any exposed group when compared to the vehicle control group (Table 29). In males, the incidence of C-cell neoplasms was greater in the 500 and 1,000 mg/L groups than in the control group, but the differences were not significant, and the incidences in all the groups were within the historical control range. C-cell adenomas consisted of a discrete proliferation of C-cells that was larger than five follicles in diameter and caused compression of surrounding follicles (Figure 6). C-cell carcinomas tended to be large neoplasms that replaced the normal architecture of the thyroid gland and were diagnosed when there was evidence of invasion into the thyroid gland capsule or surrounding tissue (Figure 7).

Table 29 Incidences of Neoplastic and Nonneoplastic Lesions of the Thyroid Gland in Female Rats in the Perinatal and Two-year Drinking Water Study of Sodium Tungstate Dihydrate

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n^a^ | 50 | 50 | 49 | 50
C-cell, Hyperplasia^b^ | 14 (2.5)^c^ | 13 (1.8) | 9 (2.0) | 12 (1.8)
C-cell Adenoma^d^
Overall rate^e^ | 5/50 (10%) | 13/50 (26%) | 13/49 (27%) | 8/50 (16%)
Rate per litters^f^ | 4/25 (16%) | 12/25 (48%) | 10/25 (40%) | 8/25 (32%)
Adjusted rate^g^ | 12.1% | 29.7% | 31.9% | 18.5%
Terminal rate^h^ | 2/30 (7%) | 12/33 (36%) | 8/31 (26%) | 5/31 (16%)
First incidence (days) | 676 | 701 | 585 | 583
Rao-Scott-adjusted Poly-3 test^i^ | p = 0.451 | p = 0.057 | p = 0.040 | p = 0.321
C-cell Carcinoma^j^
Overall rate | 2/50 (4%) | 2/50 (4%) | 2/49 (4%) | 4/50 (8%)
Rate per litters | 2/25 (8%) | 2/25 (8%) | 2/25 (8%) | 4/25 (16%)
Adjusted rate | 4.9% | 4.6% | 5% | 9.5%
Terminal rate | 1/30 (3%) | 1/33 (3%) | 1/31 (3%) | 4/31 (13%)
First incidence (days) | 708 | 630 | 716 | 730 (T)
Rao-Scott-adjusted Poly-3 test | p = 0.228 | p = 0.651N | p = 0.659 | p = 0.344
C-cell Adenoma or Carcinoma (Combined)^k^
Overall rate | 7/50 (14%) | 15/50 (30%) | 14/49 (29%) | 11/50 (22%)
Rate per litters | 6/25 (24%) | 13/25 (52%) | 11/25 (44%) | 11/25 (44%)
Adjusted rate | 16.9% | 34% | 34.4% | 25.4%
Terminal rate | 3/30 (10%) | 13/33 (39%) | 9/31 (29%) | 8/31 (26%)
First incidence (days) | 676 | 630 | 585 | 583
Rao-Scott-adjusted Poly-3 test | p = 0.369 | p = 0.073 | p = 0.072 | p = 0.260

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 70/488 (15.05% ± 7.65%); range: 4% to 24%.

^e^ Number of animals with neoplasm/number of animals necropsied.

^f^ Number of litters with neoplasm-bearing animals/number of litters examined at site.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at terminal euthanasia.

^i^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidences are the p values corresponding to pairwise comparisons between the vehicle control group and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^j^ Historical control incidence: 7/488 (1.56% ± 1.67%); range: 0% to 4%.

^k^ Historical control incidence: 76/488 (16.38% ± 8.21%); range: 4% to 28%.

Figure 6

C-cell Adenoma in the Thyroid Gland of a Female Sprague Dawley Rat Exposed to 1,000 mg/L Sodium Tungstate Dihydrate for Two Years (H&E)

A) The C-cell adenoma is a mass of several nests, or clusters, of cells separated by a delicate fibrovascular stroma. B) Higher magnification of the C-cell adenoma in panel A; at this magnification, the fibrovascular stroma that separates the nests of C-cells is more apparent (arrows). The cells that make up the adenoma have oval nuclei and pale eosinophilic cytoplasm. A few follicles are entrapped (asterisks).

Figure 7

C-cell Carcinoma in the Thyroid Gland of a Female Sprague Dawley Rat Exposed to 1,000 mg/L Sodium Tungstate Dihydrate for Two Years (H&E)

A) The C-cell carcinoma completely obliterates the normal architecture of the thyroid gland. B) Higher magnification of the C-cell carcinoma in panel A; the cells tend to have slightly less cytoplasm than those of the C-cell adenoma (Figure 6), but the main feature of C-cell carcinomas is invasion through the capsule (arrows).

Kidney: The incidences of suppurative inflammation of the renal tubules were significantly increased in the 1,000 mg/L males and females, and the incidence of renal tubule regeneration was significantly increased in the 1,000 mg/L females, relative to the respective vehicle control groups (Table 30). Renal tubule suppurative inflammation consisted of dilated renal tubules filled with neutrophils and necrotic debris (Figure 8). One to five affected renal tubules in a section of kidney was graded as minimal; 6 to 15 affected tubules in a section of kidney was graded as mild; and more than 15 affected tubules in a section of kidney was graded as moderate. Renal tubule regeneration was characterized by cytoplasmic basophilia, karyomegaly, hypertrophy and hyperplasia of the renal tubule epithelium (Table 30; Figure 9). Occasional mitotic figures were also present. Severity grading was based on the amount of renal cortex involved, with minimal regeneration involving <10% of the cortex; mild regeneration involving approximately 10%–25% of the cortex; moderate or marked regeneration was not observed. In males and some females, regeneration could not be distinguished as a separate morphologic finding when more advanced CPN was present (Table 30).

CPN was recorded in almost every male rat in the study; however, the mean severity score was the highest in the vehicle control group, and lowest in the 1,000 mg/L males (Table 30; Figure 10). Although no statistical comparison was conducted on the mean severity scores, the scores did parallel the incidences of several other lesions that are considered secondary to kidney failure associated with CPN. These lesions, which occurred at lower incidences in higher exposure concentration groups than in the vehicle control group, include diffuse hyperplasia of the parathyroid and mineral of the kidney, blood vessel, heart, large intestine (cecum), and glandular stomach (Appendix G).

Table 30 Incidences of Nonneoplastic Lesions of the Kidney in Male and Female Rats in the Perinatal and Two-year Drinking Water Study of Sodium Tungstate Dihydrate

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n^a^ | 50 | 50 | 50 | 50
Male
Renal Tubule, Regeneration^b^ | 0 | 1 (2.0)^c^ | 0 | 0
Nephropathy, Chronic Progressive | 50 (3.4) | 50 (3.2) | 50 (3.2) | 49 (2.5)
Renal Tubule, Inflammation, Suppurative | 25** (1.2) | 33 (1.3) | 35 (1.3) | 41** (1.6)
Female
Renal Tubule, Regeneration | 0** | 0 | 0 | 18** (1.8)
Nephropathy, Chronic Progressive | 49 (1.8) | 49 (1.4) | 48 (1.4) | 47 (1.7)
Renal Tubule, Inflammation, Suppurative | 8** (1.0) | 9 (1.0) | 6 (1.0) | 19* (1.1)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Rao-Scott test; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Figure 10

Chronic Progressive Nephropathy in the Kidney of a Female Sprague Dawley Rat Exposed to 1,000 mg/L Sodium Tungstate Dihydrate for Two Years (H&E)

Compared with renal tubule regeneration (Figure 9), thickened basement membranes are visible surrounding the renal tubules (arrows).

Figure 9

Renal Tubule Regeneration in the Kidney of a Female Sprague Dawley Rat Exposed to 1,000 mg/L Sodium Tungstate Dihydrate for Two Years (H&E)

A) At this magnification, the regenerative tubules are evidenced by basophilic tubules (arrows). B) Higher magnification of the renal tubule regeneration shown in panel A in which the affected tubules (asterisks) are basophilic, and there is slight crowding of the nuclei compared with the cells in the normal, more eosinophilic tubules (arrowheads). No thickening of the basement membrane is observed, as is seen in chronic progressive nephropathy; compare these tubules with those seen in Figure 10.

Figure 8

Suppurative Inflammation in the Renal Tubules of the Kidney from a Male Sprague Dawley Rat Exposed to 1,000 mg/L Sodium Tungstate Dihydrate for Two Years (H&E)

A) Numerous dilated tubules in the kidney are filled with neutrophils and necrotic debris (arrows). B) Higher magnification of the renal tubule suppurative inflammation shown in panel A; the tubules are filled with neutrophils and cell debris, and there is a mixed inflammatory response in the interstitium.

Uterus: A significant increase in the incidence of atypical hyperplasia of the uterus, relative to the vehicle control group, occurred in the 500 mg/L females (Table 31). Atypical hyperplasia is considered a preneoplastic lesion,^91^ which can progress to uterine adenomas and then uterine adenocarcinoma, or directly to adenocarcinomas. There were no significant differences for the few adenocarcinomas that occurred in this study and the group incidences were within the historical control range.

Table 31 Incidences of Neoplastic and Nonneoplastic Lesions of the Uterus in Female Rats in the Perinatal and Two-year Drinking Water Study of Sodium Tungstate Dihydrate

| 0 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L
n^a^ | 50 | 50 | 50 | 50
Hyperplasia, Atypical^b^ | 4 (2.3)^c^ | 7 (1.4) | 19** (1.7) | 8 (2.3)
Adenocarcinoma^d^ | 3 | 0 | 2 | 5
Adenoma^e^ | 0 | 0 | 0 | 1

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group.

** Statistically significant at p ≤ 0.01 by the Rao-Scott test.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 20/350 (5.71% ± 3.35%); range: 2% to 10%.

^e^ Historical control incidence: 1/350 (0.29% ± 0.76%); range: 0% to 2%.

Atypical hyperplasia involved both the endometrial glands and the surface epithelium (Figure 11). Affected endometrial glands were characterized by clusters of enlarged glands lined by disorganized, large epithelial cells that were crowded and piled up on each other to form multiple layers; this often resulted in blebbing (small protrusions of cells in the glandular lumen). The involved cells displayed pleomorphism and anisokaryosis, and an occasional mitotic figure was present.

Figure 11

Atypical Hyperplasia in the Uterus of a Female Sprague Dawley Rat Exposed to 500 mg/L Sodium Tungstate Dihydrate for Two Years (H&E)

A) A low magnification photomicrograph of atypical hyperplasia of the uterus shows proliferation of the surface and glandular epithelium; the proliferative epithelium does not extend past the thick endometrial stroma into the underlying myometrial layers. This lack of invasion is consistent with atypical hyperplasia. B) A higher magnification of the atypical hyperplasia seen in panel A. There are vacuoles within the cytoplasm of numerous cells; this vacuolation of the epithelial cells is a common feature of atypical hyperplasia. C) A photomicrograph of atypical hyperplasia affecting an endometrial gland with large epithelial cells containing large nuclei, which are piling up on each other, resulting in protrusions into the glandular lumen. The large number of degenerate neutrophils within the lumen are incidental to the finding of atypical hyperplasia.

Atypical hyperplasia affecting the surface epithelium consisted of branching, frond-like projections of epithelial cells on a fibrovascular stalk that extended into the uterine lumen. These thickened papillary projections were composed of cells that often contained clear vacuoles.

The severity (minimal, mild, moderate, marked) of atypical hyperplasia was graded based on the amount of uterus that was involved in the lesion, as well as on the extent of the proliferation and cellular atypia. Minimal lesions were small and focal, confined to one small area of the uterus, and involved only one or a few glands or a small area of surface endometrium. Although the cells might display some atypical characteristics (such as having differently sized nuclei or abundant cytoplasm), the cells were not so anaplastic that they resembled those of an adenocarcinoma. Blebbing of the cytoplasm was infrequent, and although the cells might have been crowded, they did not typically form multiple layers. Increasing severity grades reflected the involvement of a larger area of the uterus and a greater degree of cellular pleomorphism, atypia, and proliferation, resulting in frequently vacuolated cells lining frond-like extensions from the surface endometrium and crowded glands lined by multiple layers of abnormal looking epithelial cells.

Other Tissues: In males, there was a significantly increased incidence of focal adrenal cortical hyperplasia in the 1,000 mg/L group, relative to the vehicle control group, when unilateral and bilateral lesions were combined (Appendix G). In the mandibular lymph node, there were significantly increased incidences of plasma cell hyperplasia in the 500 and 1,000 mg/L males, and of sinus dilation in the 250 mg/L males, relative to the vehicle control group (Appendix G). In the nose, goblet cell hyperplasia of the nasopharyngeal duct was significantly increased in incidence in the 250 mg/L males, and hyaline droplet accumulation in the respiratory epithelium was significantly increased in incidence in all exposed groups of females, relative to the vehicle control groups (Appendix G). These lesions were not considered related to ST exposure.

In females, there was a significantly decreased incidence of mammary gland fibroadenomas in the 1,000 mg/L group compared to the vehicle control group (Appendix G). Significant decreases in body weight have been shown to be associated with a decreased incidence of mammary gland tumors in rats.^92^

## Mice

### Three-month Study

There were no early deaths or exposure-related clinical observations in male or female B6C3F1/N mice exposed to ST for 3 months (Table 32, Table 33; Appendix G). Over the course of the study, group mean body weights were below 90% of the vehicle control group mean for the 250, 1,000, and 2,000 mg/L females and the 2,000 mg/L males (Table 32, Table 33; Figure 12). At study termination, the mean body weights of all exposed groups of males and females were within 10% of the vehicle control groups.

Table 32 Summary of Survival and Mean Body Weights of Male Mice in the Three-month Drinking Water Study of Sodium Tungstate Dihydrate

Study Day^a^ | 0 mg/L | | 125 mg/L | | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
1 | 22.2 | 10 | 22.4 | 100.9 | 10 | 22.6 | 101.7 | 10 | 22.7 | 102.3 | 10 | 22.1 | 99.8 | 10 | 22.4 | 100.9 | 10
8 | 24.4 | 10 | 24.8 | 101.5 | 10 | 24.6 | 100.7 | 10 | 24.3 | 99.6 | 10 | 23.9 | 98.0 | 10 | 23.9 | 97.7 | 10
15 | 25.9 | 10 | 26.3 | 101.7 | 10 | 26.0 | 100.5 | 10 | 25.7 | 99.5 | 10 | 25.3 | 97.6 | 10 | 24.8 | 95.7 | 10
22 | 27.9 | 10 | 28.7 | 102.7 | 10 | 28.3 | 101.5 | 10 | 27.9 | 99.9 | 10 | 27.1 | 97.2 | 10 | 26.5 | 95.0 | 10
29 | 28.9 | 10 | 29.6 | 102.4 | 10 | 29.4 | 101.7 | 10 | 29.0 | 100.3 | 10 | 28.4 | 98.1 | 10 | 27.3 | 94.4 | 10
36 | 30.4 | 10 | 31.4 | 103.3 | 10 | 31.0 | 102.0 | 10 | 30.3 | 99.8 | 10 | 29.7 | 97.7 | 10 | 28.4 | 93.3 | 10
43 | 32.7 | 10 | 33.5 | 102.7 | 10 | 33.0 | 101.0 | 10 | 32.4 | 99.2 | 10 | 31.6 | 96.8 | 10 | 30.0 | 91.9 | 10
50 | 34.6 | 10 | 35.6 | 103.0 | 10 | 34.7 | 100.4 | 10 | 34.0 | 98.3 | 10 | 33.9 | 98.1 | 10 | 31.8 | 92.1 | 10
57 | 35.8 | 10 | 37.3 | 104.2 | 10 | 36.5 | 101.9 | 10 | 35.3 | 98.7 | 10 | 35.3 | 98.7 | 10 | 32.8 | 91.5 | 10
64 | 36.2 | 10 | 38.0 | 105.0 | 10 | 37.0 | 102.3 | 10 | 35.9 | 99.1 | 10 | 35.9 | 99.4 | 10 | 32.9 | 91.0 | 10
71 | 37.6 | 10 | 39.3 | 104.5 | 10 | 38.1 | 101.3 | 10 | 37.2 | 98.8 | 10 | 36.9 | 98.2 | 10 | 34.0 | 90.4 | 10
78 | 39.0 | 10 | 40.7 | 104.6 | 10 | 39.2 | 100.5 | 10 | 38.3 | 98.4 | 10 | 38.2 | 98.0 | 10 | 35.0 | 89.7 | 10
85 | 39.4 | 10 | 41.2 | 104.5 | 10 | 40.0 | 101.5 | 10 | 39.1 | 99.3 | 10 | 39.1 | 99.3 | 10 | 35.2 | 89.4 | 10
EOS | 41.2 | 10 | 42.4 | 102.9 | 10 | 41.6 | 100.8 | 10 | 40.7 | 98.6 | 10 | 40.4 | 98.0 | 10 | 37.5 | 91.0 | 10

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Table 33 Summary of Survival and Body Weights of Female Mice in the Three-month Drinking Water Study of Sodium Tungstate Dihydrate

Study Day^a^ | 0 mg/L | | 125 mg/L | | | 250 mg/L | | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Study Day^a^ | Av. Wt. (g) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N | Av. Wt. (g) | Wt. (% of Controls) | N
1 | 17.1 | 10 | 16.7 | 97.6 | 10 | 17.2 | 100.1 | 10 | 17.3 | 101.0 | 10 | 16.9 | 98.8 | 10 | 16.8 | 98.1 | 10
8 | 19.4 | 10 | 18.6 | 95.9 | 10 | 18.8 | 96.9 | 10 | 19.1 | 98.3 | 10 | 18.8 | 96.5 | 10 | 18.5 | 95.1 | 10
15 | 20.3 | 10 | 19.8 | 97.6 | 10 | 19.6 | 96.5 | 10 | 20.2 | 99.5 | 10 | 19.5 | 95.8 | 10 | 19.8 | 97.3 | 10
22 | 21.9 | 10 | 21.3 | 97.4 | 10 | 21.2 | 96.8 | 10 | 22.0 | 100.5 | 10 | 20.8 | 95.1 | 10 | 20.8 | 95.2 | 10
29 | 23.0 | 10 | 22.1 | 96.2 | 10 | 21.2 | 92.2 | 10 | 22.4 | 97.5 | 10 | 21.0 | 91.6 | 10 | 21.6 | 94.0 | 10
36 | 24.8 | 10 | 22.8 | 91.9 | 10 | 22.6 | 91.0 | 10 | 23.6 | 94.9 | 10 | 22.1 | 89.0 | 10 | 22.2 | 89.3 | 10
43 | 26.0 | 10 | 24.3 | 93.6 | 10 | 23.5 | 90.5 | 10 | 24.3 | 93.4 | 10 | 23.1 | 89.0 | 10 | 23.4 | 90.2 | 10
50 | 27.8 | 10 | 26.0 | 93.6 | 10 | 24.6 | 88.4 | 10 | 26.2 | 94.3 | 10 | 24.9 | 89.5 | 10 | 24.5 | 88.1 | 10
57 | 28.9 | 10 | 27.9 | 96.5 | 10 | 25.0 | 86.6 | 10 | 27.0 | 93.4 | 10 | 26.1 | 90.4 | 10 | 26.1 | 90.3 | 10
64 | 30.3 | 10 | 28.5 | 93.9 | 10 | 26.0 | 85.7 | 10 | 28.2 | 92.9 | 10 | 26.4 | 86.9 | 10 | 27.8 | 91.6 | 10
71 | 31.3 | 10 | 29.4 | 93.7 | 10 | 26.7 | 85.3 | 10 | 30.3 | 96.6 | 10 | 27.9 | 89.0 | 10 | 28.1 | 89.8 | 10
78 | 32.1 | 10 | 31.1 | 96.9 | 10 | 27.6 | 86.2 | 10 | 30.3 | 94.4 | 10 | 29.2 | 91.0 | 10 | 28.7 | 89.6 | 10
85 | 31.7 | 10 | 32.7 | 103.1 | 10 | 29.0 | 91.5 | 10 | 31.1 | 98.0 | 10 | 29.5 | 93.1 | 10 | 28.7 | 90.6 | 10
EOS | 31.7 | 10 | 33.8 | 106.6 | 10 | 29.9 | 94.1 | 10 | 31.7 | 99.9 | 10 | 29.5 | 92.8 | 10 | 29.1 | 91.6 | 10

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 12

Growth Curves for Mice Exposed to Sodium Tungstate Dihydrate in Drinking Water for Three Months

Weekly mean water consumption was reduced slightly in the 1,000 mg/L male group (11%), the 2,000 mg/L males (16%), and the 2,000 mg/L females (11%), relative to the respective vehicle control groups (Table 34; Appendix G). Drinking water concentrations of 125, 250, 500, 1,000, and 2,000 mg/L resulted in average daily ST doses of approximately 14, 27, 57, 108, and 212 mg/kg/day for males and 14, 29, 58, 113, and 202 mg/kg/day for females.

Table 34 Summary of Water and Sodium Tungstate Dihydrate Consumption of Male and Female Mice in the Three-month Drinking Water Study

Week | 0 mg/L | 125 mg/L | | 250 mg/L | | 500 mg/L | | 1,000 mg/L | | 2,000 mg/L
Week | Water (g/day)^a^ | Water (g/day) | Dose (mg/kg/day)^b^ | Water (g/day) | Dose (mg/kg/day) | Water (g/day) | Dose (mg/kg/day) | Water (g/day) | Dose (mg/kg/day) | Water (g/day) | Dose (mg/kg/day)
Male
1 | 4.3^d^ | 3.8 | 21.2 | 3.7 | 41.0 | 3.5 | 77.2 | 3.6 | 162.6 | 3.4 | 303.7
4 | 3.7 | 3.5 | 15.3 | 3.4 | 30.0 | 3.4 | 61.0 | 3.3 | 121.7 | 3.1 | 234.0
13 | 3.5 | 3.5 | 10.6 | 3.6 | 22.5 | 3.4 | 43.4 | 3.1 | 79.2 | 3.0 | 170.4
Female
1 | 2.5 | 2.4 | 17.9 | 2.6 | 37.9 | 2.5 | 72.2 | 2.2 | 129.9 | 2.0 | 237.8
4 | 3.0 | 2.6 | 15.2 | 2.6 | 30.7 | 2.7 | 61.4 | 2.7 | 129.8 | 2.3 | 220.9
13 | 2.2 | 2.6 | 9.9 | 2.6 | 22.4 | 2.6 | 41.8 | 2.4 | 81.4 | 2.3 | 160.1

^a^ Water consumption data are presented as grams/animal/day.

^b^ Milligrams of sodium tungstate dihydrate consumed/kilogram body weight/day.

Blood was collected from up to 10 animals per group on the morning of day 91. Total blood tungsten concentrations were determined using a validated analytical method (Appendix E); data are presented in Table 35. Tungsten was not detected in males in the vehicle control group above the LOD of the assay (0.0016 μg/g); however, low concentrations of tungsten were detected in females in the vehicle control group. In both males and females, the blood tungsten concentrations increased proportionally with the exposure concentration; there was no observed sex difference. In females, the tungsten concentrations in exposed groups were significantly higher than in the corresponding vehicle control group.

Table 35 Summary of Blood Tungsten Concentration Data for Male and Female Mice in the Three-month Drinking Water Study of Sodium Tungstate Dihydrate^a^

| 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Blood (μg/g) | BD | 0.17 ± 0.04 | 0.28 ± 0.04 | 0.47 ± 0.10 | 1.56 ± 0.27 | 2.63 ± 0.70
Female
n | 10 | 10 | 10 | 9 | 10 | 10
Blood (μg/g)^b,c^ | 0.03 ± 0.01** | 0.13 ± 0.02** | 0.27 ± 0.05** | 0.44 ± 0.07** | 1.06 ± 0.11** | 2.87 ± 0.40**

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BD = below detection; group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Data presented as mean ± standard error.

^b^ Values below the LOD (0.0016 μg/g), were substituted with 1/2 the LOD value. If 80% or more of the values in the vehicle control group were below the LOD, no mean or standard error were calculated, and no statistical analysis was performed.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

In male mice, the white blood cell count was significantly decreased in the 1,000 and 2,000 mg/L groups relative to the vehicle control group (Table 36). These decreases were driven by a significant decrease in the lymphocyte count in the 1,000 and 2,000 mg/L groups and a significant decrease in the monocyte count in the 500 mg/L and higher groups (Table 36). Additionally, the eosinophil counts were significantly decreased in all ST-exposed male groups. These leukocyte changes are consistent with a stress leukogram (i.e., effects of chronic increase in endogenous corticosterone).^89^

Table 36 Summary of Select Hematology Data for Male Mice in the Three-month Drinking Water Study of Sodium Tungstate Dihydrate^a,b^

| 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
n | 10 | 10 | 10 | 10 | 10 | 10
White Blood Cells (10^3^/μL) | 5.91 ± 0.52** | 4.87 ± 0.61 | 5.32 ± 0.42 | 4.94 ± 0.51 | 4.20 ± 0.37** | 3.83 ± 0.56**
Lymphocytes (10^3^/μL) | 4.83 ± 0.45** | 3.93 ± 0.49 | 4.38 ± 0.34 | 4.07 ± 0.43 | 3.41 ± 0.31** | 3.12 ± 0.45**
Monocytes (10^3^/μL) | 0.20 ± 0.02** | 0.13 ± 0.02 | 0.14 ± 0.02 | 0.10 ± 0.02** | 0.09 ± 0.02** | 0.09 ± 0.03**
Eosinophils (10^3^/μL) | 0.15 ± 0.03** | 0.08 ± 0.01* | 0.08 ± 0.01* | 0.07 ± 0.02* | 0.07 ± 0.01** | 0.06 ± 0.02**

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data displayed as mean ± standard error.

^b^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

A higher group mean relative testis weight was observed in the 2,000 mg/L male group, relative to the vehicle control group, and was likely due to the lower mean body weights in that group (Appendix G). There were no histological lesions in the testes related to ST exposure. In female mice, there were several sporadic increases in group mean organ weights, but they lacked an exposure concentration response or other supporting evidence that they represented anything but biological variation (Appendix G). Relative kidney weights were significantly increased in the 1,000 and 2,000 mg/L females and 2000 mg/L males but were most likely due to reduced mean body weights in those groups compared to the vehicle control group (Table 37).

Table 37 Summary of Renal Findings for Male and Female Mice in the Three-month Drinking Water Study of Sodium Tungstate Dihydrate

| 0 mg/L | 125 mg/L | 250 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy Body Wt. (g)^a^ | 41.2 ± 1.0** | 42.4 ± 0.9 | 41.6 ± 1.5 | 40.7 ± 1.1 | 40.4 ± 0.8 | 37.5 ± 1.1*
R. Kidney Weight^a^
Absolute (g) | 0.30 ± 0.00 | 0.30 ± 0.01 | 0.31 ± 0.01 | 0.31 ± 0.01 | 0.31 ± 0.01 | 0.29 ± 0.00
Relative (mg/g)^b^ | 7.28 ± 0.15** | 7.15 ± 0.16 | 7.47 ± 0.18 | 7.53 ± 0.22 | 7.75 ± 0.16 | 7.84 ± 0.18*
Histological Findings
Kidney^c^ | 10 | 10 | 10 | 10 | 10 | 10
Renal tubule, regeneration^d^ | 0** | 0 | 0 | 0 | 6** (1.0)^e^ | 10** (1.6)
Female
Necropsy Body Wt. (g) | 31.7 ± 1.7* | 33.8 ± 1.3 | 29.9 ± 1.1 | 31.7 ± 1.3 | 29.5 ± 1.1 | 29.1 ± 1.2
R. Kidney Weight
Absolute (g) | 0.15 ± 0.00 | 0.17 ± 0.00 | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.16 ± 0.00
Relative (mg/g) | 4.88 ± 0.19** | 4.91 ± 0.11 | 5.28 ± 0.11 | 5.22 ± 0.13 | 5.48 ± 0.16* | 5.42 ± 0.19*
Histological Findings
Kidney | 10 | 10 | 10 | 10 | 10 | 10
Renal tubule, regeneration | 0* | 0 | 0 | 0 | 1 (1.0) | 2 (1.0)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

Statistical analysis for organ weight data performed by the Jonckheere (trend) and Williams or Dunnett (pairwise) tests. Statistical analysis for histological findings performed by the Poly-3 test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data presented as mean ± standard error.

^b^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

^c^ Number of animals examined microscopically.

^d^ Number of animals with lesion.

^e^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

No exposure-related gross lesions were recorded. The only histological lesion associated with exposure was in the kidney. The incidences of renal tubule regeneration were higher in the 1,000 and 2,000 mg/L male and female groups compared to the respective vehicle control groups; the increases in the male groups were significant (Table 37). The lesion consisted of hyperplastic tubules, predominantly in the deep cortical to medullary region, lined by epithelial cells with increased cytoplasmic basophilia, nuclear crowding, prominent nucleoli, marginated chromatin, and karyomegaly. There were occasional mitotic figures.

In male mice, no significant differences were observed between exposed groups and the vehicle control group in left testis weight, left epididymal weight, left cauda weight, or any of the sperm parameters, including number of sperm/mg cauda epididymis, total number sperm/cauda, sperm motility, number of homogenization-resistant spermatids/mg testis, and total number of spermatids (Appendix G). The testes and epididymides were evaluated to a no-effect level, and no histological findings associated with ST exposure were present at 3 months. Under the conditions of this 3-month study, ST administration via drinking water did not exhibit the potential to be a reproductive toxicant in B6C3F1/N mice. Testicular lesions observed in male mice after 2 years of exposure to ST, however, might possibly impair reproductive performance.

### Exposure Concentration Selection Rationale for Two-year Studies in Mice

In the 3-month studies, there were no effects on survival and mean body weights in any exposure groups that were considered exposure concentration-limiting (Table 32, Table 33). There was a 16% reduction in water consumption in male mice at the top exposure group of 2,000 mg/L (Table 34), and minimal to mild renal tubule regeneration was noted in the 1,000 and 2,000 mg/L groups, but neither effect was considered exposure concentration-limiting (Table 37). Hence, exposure concentrations selected for the 2-year study were 0, 500, 1,000, and 2,000 mg/L.

### Two-year Study (Interim Evaluations – 3, 6, 12, and 18 Months)

At 6 months in males, mean body weights were significantly decreased in the 500 mg/L, 1,000 mg/L, and 2,000 mg/L groups by approximately 7%, 8%, and 13%, respectively, relative to the vehicle control group. Mean body weights of the 2,000 mg/L females were significantly decreased by approximately 13% relative to the vehicle control group at 12 months (Table 38, Table 39). Mean body weights of all other groups, both males and females, were within 10% of the vehicle control groups at all time points.

Table 38 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Mice Exposed to Sodium Tungstate Dihydrate in Drinking Water for 3, 6, 12, and 18 Months^a,b^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Three Months
Necropsy Body Wt. (g) | 34.7 ± 0.8 (10) | 35.3 ± 1.2 (10) | 37.0 ± 1.1 (10) | 31.2 ± 1.0 (10)
Kidneys
Absolute (g) | 0.52 ± 0.01 (10) | 0.57 ± 0.01* (10) | 0.59 ± 0.01** (10) | 0.50 ± 0.01 (10)
Relative (mg/g)^c^ | 15.03 ± 0.36 (10) | 16.40 ± 0.48* (10) | 15.91 ± 0.36 (10) | 16.19 ± 0.27 (10)
Liver
Absolute (g) | 1.37 ± 0.03 (10) | 1.43 ± 0.03 (10) | 1.51 ± 0.06 (10) | 1.30 ± 0.03 (10)
Relative (mg/g) | 39.55 ± 0.30** (10) | 40.72 ± 0.95 (10) | 40.74 ± 0.62 (10) | 41.83 ± 0.67* (10)
Six Months
Necropsy Body Wt. (g) | 45.7 ± 0.8** (10) | 42.5 ± 0.8* (10) | 42.1 ± 1.1** (10) | 39.8 ± 0.8** (10)
Kidneys
Absolute (g) | 0.68 ± 0.02 (10) | 0.67 ± 0.02 (10) | 0.69 ± 0.02 (10) | 0.62 ± 0.01* (10)
Relative (mg/g) | 14.93 ± 0.30 (10) | 15.87 ± 0.20 (10) | 16.47 ± 0.30** (10) | 15.69 ± 0.33 (10)
Liver
Absolute (g) | 2.03 ± 0.05** (10) | 1.77 ± 0.10* (10) | 1.72 ± 0.09** (10) | 1.60 ± 0.05** (10)
Relative (mg/g) | 44.45 ± 0.90* (10) | 41.50 ± 1.63 (10) | 40.67 ± 1.12 (10) | 40.23 ± 0.66* (10)
Twelve Months
Necropsy Body Wt. (g) | 49.4 ± 1.0 (10) | 48.1 ± 0.7 (10) | 48.1 ± 0.8 (10) | 46.9 ± 0.8 (10)
Kidneys
Absolute (g) | 0.81 ± 0.02 (10) | 0.80 ± 0.02 (10) | 0.82 ± 0.03 (10) | 0.78 ± 0.02 (10)
Relative (mg/g) | 16.43 ± 0.29 (10) | 16.70 ± 0.25 (10) | 17.12 ± 0.47 (10) | 16.62 ± 0.29 (10)
Liver
Absolute (g) | 2.42 ± 0.15 (10) | 2.18 ± 0.05 (10) | 2.36 ± 0.14 (10) | 2.13 ± 0.08 (10)
Relative (mg/g) | 48.93 ± 3.00 (10) | 45.37 ± 0.62 (10) | 49.18 ± 3.15 (10) | 45.56 ± 1.79 (10)
Eighteen Months
Necropsy Body Wt. (g) | 49.4 ± 1.7* (9) | 48.4 ± 0.9 (10) | 48.3 ± 1.2 (9) | 46.4 ± 1.0 (6)
Kidneys
Absolute (g) | 0.79 ± 0.02 (9) | 0.79 ± 0.02 (10) | 0.85 ± 0.05 (9) | 0.74 ± 0.02 (6)
Relative (mg/g) | 16.07 ± 0.36 (9) | 16.35 ± 0.24 (10) | 17.69 ± 0.94 (9) | 15.90 ± 0.35 (6)
Liver
Absolute (g) | 2.25 ± 0.19 (9) | 2.45 ± 0.20 (10) | 2.79 ± 0.30 (9) | 1.86 ± 0.14 (6)
Relative (mg/g) | 46.98 ± 6.36 (9) | 50.98 ± 4.76 (10) | 58.20 ± 6.42 (9) | 39.95 ± 2.41 (6)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data presented as mean ± standard error (n).

^b^ Statistical analysis performed by the Jonckheere (trend) and the Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

Table 39 Summary of Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Female Mice Exposed to Sodium Tungstate Dihydrate in Drinking Water for 3, 6, 12, and 18 Months^a,b^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Three Months
Necropsy Body Wt. (g) | 27.3 ± 1.5 (10) | 24.8 ± 0.7 (10) | 29.2 ± 1.0 (10) | 24.8 ± 0.9 (10)
Kidneys
Absolute (g) | 0.32 ± 0.01 (10) | 0.31 ± 0.01 (10) | 0.32 ± 0.01 (10) | 0.31 ± 0.01 (10)
Relative (mg/g)^c^ | 11.88 ± 0.33 (10) | 12.58 ± 0.28 (10) | 10.89 ± 0.30* (10) | 12.41 ± 0.21 (10)
Liver
Absolute (g) | 1.13 ± 0.04 (10) | 1.09 ± 0.03 (10) | 1.17 ± 0.02 (10) | 1.13 ± 0.04 (10)
Relative (mg/g) | 41.97 ± 1.23 (10) | 43.76 ± 0.73 (10) | 40.24 ± 0.92 (10) | 45.60 ± 0.89* (10)
Six Months
Necropsy Body Wt. (g) | 39.8 ± 1.3 (10) | 38.7 ± 1.0 (10) | 39.3 ± 1.5 (10) | 39.4 ± 1.4 (10)
Kidneys
Absolute (g) | 0.36 ± 0.01 (10) | 0.36 ± 0.01 (10) | 0.36 ± 0.01 (10) | 0.36 ± 0.01 (10)
Relative (mg/g) | 9.07 ± 0.26 (10) | 9.36 ± 0.24 (10) | 9.10 ± 0.24 (10) | 9.15 ± 0.30 (10)
Liver
Absolute (g) | 1.37 ± 0.03 (10) | 1.34 ± 0.02 (10) | 1.36 ± 0.04 (10) | 1.34 ± 0.03 (10)
Relative (mg/g) | 34.63 ± 0.77 (10) | 34.75 ± 0.59 (10) | 34.83 ± 0.69 (10) | 34.28 ± 0.86 (10)
Twelve Months
Necropsy Body Wt. (g) | 53.9 ± 0.8** (10) | 50.3 ± 1.7 (10) | 51.1 ± 1.6 (10) | 46.7 ± 1.6** (10)
Kidneys
Absolute (g) | 0.41 ± 0.01 (10) | 0.39 ± 0.02 (10) | 0.41 ± 0.01 (10) | 0.39 ± 0.01 (10)
Relative (mg/g) | 7.51 ± 0.19** (10) | 7.80 ± 0.14 (10) | 8.10 ± 0.16* (10) | 8.34 ± 0.27** (10)
Liver
Absolute (g) | 1.61 ± 0.08 (10) | 1.48 ± 0.07 (10) | 1.58 ± 0.05 (10) | 1.43 ± 0.03 (10)
Relative (mg/g) | 29.84 ± 1.34 (10) | 29.38 ± 0.98 (10) | 30.91 ± 0.71 (10) | 30.97 ± 1.09 (10)
Eighteen Months
Necropsy Body Wt. (g) | 56.3 ± 1.3 (10) | 55.0 ± 1.9 (9) | 53.3 ± 2.6 (9) | 56.3 ± 1.2 (10)
Kidneys
Absolute (g) | 0.44 ± 0.01 (10) | 0.44 ± 0.02 (9) | 0.45 ± 0.02 (9) | 0.47 ± 0.01 (10)
Relative (mg/g) | 7.72 ± 0.12* (10) | 8.06 ± 0.23 (9) | 8.55 ± 0.56 (9) | 8.33 ± 0.17 (10)
Liver
Absolute (g) | 1.57 ± 0.07 (10) | 1.51 ± 0.06 (9) | 1.54 ± 0.06 (9) | 1.61 ± 0.05 (10)
Relative (mg/g) | 27.91 ± 0.78 (10) | 27.61 ± 0.72 (9) | 29.12 ± 1.08 (9) | 28.63 ± 0.57 (10)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Data presented as mean ± standard error (n).

^b^ Statistical analysis performed by the Jonckheere (trend) and the Williams or Dunnett (pairwise) tests.

^c^ Relative organ weights (organ-weight-to-body-weight ratios) are given as mg organ weight/g body weight.

At 3 months in males, mean absolute kidney weights were significantly increased in the 500 mg/L and 1,000 mg/L groups by approximately 10% and 13%, respectively, and mean relative kidney weight was significantly increased in the 500 mg/L group relative to the vehicle control group (Table 38). In females at 3 months, mean relative kidney weight was significantly decreased in the 1,000 mg/L group relative to the vehicle control group (Table 39). At 6 months in males, mean absolute kidney weights were significantly decreased in the 2,000 mg/L group by 9% and mean relative kidney weights were significantly increased in the 1,000 mg/L males relative to the vehicle control group; there were no significant differences in kidney weights among female groups. At 12 months, there were no significant differences in the kidney weights among male groups, but in females, mean relative kidney weights were significantly increased in the 1,000 and 2,000 mg/L groups relative to the vehicle control group. At 18 months, there were no significant pairwise differences in kidney weights in either male or female groups compared to the vehicle control groups.

At 3 months, mean relative liver weights were significantly increased in the 2,000 mg/L males and females relative to the vehicle control groups. At 6 months, mean absolute liver weights were significantly decreased by approximately 13% in the 500 mg/L males, 15% in the 1,000 mg/L males, and 21% in the 2,000 mg/L males relative to the vehicle control males (Table 38, Table 39). The biological importance of these changes in liver weights is unknown, but they are likely of little toxicological significance.

Other sporadic differences in organ weights were considered isolated changes of no toxicological significance (Appendix G).

Plasma, kidney, and urine from up to 10 animals per group were collected at 3, 6, 12, and 18 months from interim animals. Tungsten concentrations in all matrices were determined using validated analytical methods (Appendix E). In male mice, plasma tungsten concentrations increased proportionally with the exposure concentration at all time points (except at the 18 months in the 1,000 mg/L group) (Table 40; Figure 13A). In female mice, plasma tungsten concentrations increased proportionally with the exposure concentration up to 1,000 mg/L for all time points (except at 18 months in the 500 mg/L group); however, at 2,000 mg/L, the trend was toward a more-than-proportional increase in plasma tungsten concentration with increasing exposure concentration (Table 41; Figure 13A). There was also a trend toward decreasing plasma tungsten concentrations with increasing exposure duration in both male and female mice. Low tungsten concentrations were observed in the vehicle control groups at some interim evaluations; however, they were significantly lower than those in the lowest exposure groups (Table 40, Table 41). There was no observed sex difference in plasma tungsten concentration in mice (Table 40, Table 41; Figure 13A).

Table 40 Summary of Plasma, Kidney, and Urine Tungsten Concentration Data for Male Mice Exposed to Sodium Tungstate Dihydrate in Drinking Water for 3, 6, 12, and 18 Months^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Three Months
Kidney (μg/g) | BD | 5.71 ± 0.88 (10) | 6.50 ± 0.57 (10) | 12.15 ± 2.16 (10)
Plasma (μg/mL) | BD | 2.62 ± 0.47 (10) | 4.11 ± 0.58 (10) | 8.10 ± 1.14 (10)
Kidney/Plasma Ratio^b^ | BD | 2.45 ± 0.31 (10) | 1.73 ± 0.16 (10) | 1.51 ± 0.13 (10)
Urine^c,d^
Urine (μg/mL urine) | 0.02 ± 0.01** (7) | 191.56 ± 41.89** (7) | 592.00 ± 69.45** (10) | 1,335.33 ± 148.26** (6)
Urine (μg/mg creatinine) | 0.03 ± 0.01** (7) | 353.16 ± 27.44** (7) | 805.94 ± 70.58** (10) | 1,672.99 ± 147.92** (6)
Six Months
Kidney (μg/g)^c,d^ | 0.06 ± 0.01** (10) | 3.79 ± 0.29** (10) | 5.89 ± 1.23** (10) | 12.10 ± 1.39** (10)
Plasma (μg/mL)^c,d^ | 0.02 ± 0.00** (10) | 1.68 ± 0.22** (10) | 2.43 ± 0.57** (10) | 5.82 ± 0.96** (10)
Kidney/Plasma Ratio^c^ | 3.46 ± 0.42* (10) | 2.40 ± 0.18 (10) | 2.58 ± 0.24 (10) | 2.24 ± 0.19 (10)
Urine^c,d^
Urine (μg/mL urine) | 3.92 ± 2.77** (8) | 204.50 ± 28.06** (8) | 407.89 ± 92.69** (8) | 816.50 ± 144.16** (8)
Urine (μg/mg creatinine) | 6.43 ± 4.14** (8) | 375.17 ± 45.85** (8) | 709.28 ± 117.50** (7) | 1,368.62 ± 149.28** (7)
Twelve Months
Kidney (μg/g) | BD | 3.67 ± 0.61 (10) | 6.69 ± 0.59 (10) | 10.45 ± 1.06 (10)
Plasma (μg/mL)^c,d^ | 0.02 ± 0.00** (10) | 1.07 ± 0.16** (10) | 2.37 ± 0.33** (10) | 4.84 ± 0.73** (10)
Kidney/Plasma Ratio | BD | 3.66 ± 0.48 (10) | 3.10 ± 0.27 (10) | 2.35 ± 0.18 (10)
Urine^c,d^
Urine (μg/mL urine) | 4.00 ± 1.69** (10) | 152.57 ± 27.46** (10) | 349.00 ± 38.70** (10) | 661.09 ± 123.57** (10)
Urine (μg/mg creatinine) | 15.57 ± 8.39** (10) | 404.82 ± 34.78** (9) | 905.34 ± 65.48** (10) | 1,390.13 ± 183.53** (9)
Eighteen Months
Kidney (μg/g)^c,d^ | 0.06 ± 0.01** (9) | 2.67 ± 0.23** (9)^e^ | 5.50 ± 0.73** (8)^f^ | 8.71 ± 0.99** (6)
Plasma (μg/mL)^c,d^ | 0.01 ± 0.00** (9) | 1.27 ± 0.19** (10) | 4.95 ± 2.03** (9) | 4.86 ± 0.65** (6)
Kidney/Plasma Ratio^c^ | 6.28 ± 1.23** (9) | 2.41 ± 0.21** (9) | 2.42 ± 0.34** (8) | 1.85 ± 0.16** (6)
Urine^c,d^
Urine (μg/mL urine) | 0.02 ± 0.00** (9) | 104.52 ± 11.81** (10) | 194.00 ± 14.23** (8) | 661.00 ± 161.34** (6)
Urine (μg/mg creatinine) | 0.05 ± 0.01** (9) | 278.92 ± 30.45** (10) | 579.75 ± 52.95** (8) | 1,279.52 ± 155.83** (6)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

BD = below detection; group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Data presented as mean ± standard error (n).

^b^ For the kidney/plasma ratio calculation, a plasma density of 1 g/mL was assumed.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests.

^d^ Values below the LOD (0.013 μg/mL) were substituted with 1/2 the LOD value. If 80% or more of the values in the vehicle control group were below the LOD, no mean or standard error were calculated, and no statistical analysis was performed.

^e^ The kidney concentration value for one male in the 500 mg/L group at 18 months was excluded from the analysis as an implausible value.

^f^ The kidney concentration value for one male in the 1,000 mg/L group at 18 months was excluded from the analysis as an implausible value.

Figure 13

Tungsten Concentrations in Plasma, Kidney, and Urine in Mice Exposed to Sodium Tungstate Dihydrate in Drinking Water for 3, 6, 12, and 18 Months

Study day (SD) 93 = 3 months; SD 184 = 9 months; SD 366 = 12 months; SD 548 = 18 months.

Table 41 Summary of Plasma, Kidney, and Urine Tungsten Concentration Data for Female Mice Exposed to Sodium Tungstate Dihydrate in Drinking Water for 3, 6, 12, and 18 Months^a^

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Three Months
Kidney (μg/g) | BD | 3.54 ± 0.27 (10) | 5.34 ± 0.49 (10) | 11.44 ± 1.22 (10)
Plasma (μg/mL) | BD | 1.84 ± 0.23 (10) | 3.25 ± 0.49 (10) | 8.72 ± 1.25 (10)
Kidney/Plasma Ratio^b^ | BD | 2.05 ± 0.12 (10) | 1.86 ± 0.17 (10) | 1.43 ± 0.11 (10)
Urine^c,d^
Urine (μg/mL urine) | 0.08 ± 0.02** (10) | 442.78 ± 33.39** (9) | 681.00 ± 118.08** (7) | 1,470.00 ± 114.30** (10)
Urine (μg/mg creatinine) | 0.14 ± 0.04** (9) | 596.49 ± 57.37** (9) | 872.11 ± 105.33** (7) | 2,149.65 ± 183.59** (10)
Six Months
Kidney (μg/g)^c,d^ | 0.08 ± 0.02** (10) | 2.90 ± 0.17** (10) | 5.52 ± 0.40** (10) | 10.00 ± 0.91** (10)
Plasma (μg/mL)^c,d^ | 0.02 ± 0.00** (10) | 1.11 ± 1.13** (9) | 1.95 ± 0.23** (10) | 4.81 ± 0.61** (10)
Kidney/Plasma Ratio^c^ | 5.50 ± 2.51 (10) | 2.79 ± 0.23 (9) | 3.19 ± 0.40 (10) | 2.19 ± 0.14 (10)
Urine^c,d^
Urine (μg/mL urine) | 0.11 ± 0.03** (9) | 217.11 ± 20.48** (9) | 419.60 ± 49.71** (10) | 855.40 ± 106.56** (10)
Urine (μg/mg creatinine) | 0.21 ± 0.05** (9) | 432.30 ± 32.48** (9) | 788.33 ± 89.19** (10) | 1,594.25 ± 192.88** (10)
Twelve Months
Kidney (μg/g)^c,d^ | 0.05 ± 0.01** (10) | 2.30 ± 0.23** (10) | 3.64 ± 0.22** (10) | 6.59 ± 0.54** (10)
Plasma (μg/mL)^c,d^ | 0.04 ± 0.00** (10) | 0.58 ± 0.09** (10) | 1.35 ± 0.14** (10) | 4.59 ± 1.25** (9)^e^
Kidney/Plasma Ratio^c^ | 1.13 ± 0.15 (10) | 4.36 ± 0.42** (10) | 2.84 ± 0.18** (10) | 2.05 ± 0.32 (9)
Urine^c,d^
Urine (μg/mL urine) | 0.13 ± 0.03** (10) | 167.01 ± 26.29** (10) | 397.40 ± 63.15** (10) | 1,070.20 ± 182.92** (10)
Urine (μg/mg creatinine) | 0.26 ± 0.04** (10) | 309.67 ± 42.88** (10) | 645.14 ± 83.24** (10) | 1,642.14 ± 306.17** (10)
Eighteen Months
Kidney (μg/g) | BD | 2.90 ± 0.26 (9) | 3.85 ± 0.80 (9) | 5.32 ± 0.44 (10)
Plasma (μg/mL) | BD | 1.78 ± 0.32 (9) | 1.66 ± 0.39 (9) | 3.29 ± 1.15 (10)
Kidney/Plasma Ratio | BD | 1.83 ± 0.16 (9) | 2.45 ± 0.16 (9) | 2.76 ± 0.60 (10)
Urine^c,d^
Urine (μg/mL urine) | 0.04 ± 0.01** (9)^f^ | 74.25 ± 15.40** (9) | 106.61 ± 28.16** (9) | 245.04 ± 37.25** (10)
Urine (μg/mg creatinine)^c,d,g^ | 0.19 ± 0.04** (4) | 262.73 ± 28.01** (8) | 397.77 ± 38.06** (6) | 851.15 ± 59.51** (9)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

** Statistically significant at p ≤ 0.01.

BD = below detection, group did not have more than 20% of its values above the limit of detection (LOD).

^a^ Data presented as mean ± standard error (n).

^b^ For the kidney/plasma ratio calculation, a plasma density of 1 g/mL was assumed.

^c^ Statistical analysis performed by the Jonckheere (trend) and Shirley or Dunn (pairwise) tests

^d^ Values below the LOD (0.013 μg/mL) were substituted with 1/2 the LOD value. If 80% or more of the values in the vehicle control group were below the LOD, no mean or standard error were calculated, and no statistical analysis was performed.

^e^ The plasma concentration value for one female in the 2,000 mg/L group at 12 months was excluded from the analysis as an implausible value.

^f^ The urine concentration value for one female in the 0 mg/L group at 18 months was excluded from the analysis as an implausible value.

^g^ The urine concentration values for five females in the 0 mg/L group, one female in the 500 mg/L group, three females in the 1,000 mg/L group, and one female in the 2,000 mg/L group were excluded because samples were determined to be dilute.

In male and female mice, tungsten concentrations in the kidney increased with increasing exposure concentration, but the trend was less than proportional (Figure 13B). There was also a trend toward decreasing tungsten concentrations with increasing exposure duration in both male and female mice, with the highest concentrations at 3 months. Low tungsten concentrations were observed in the kidneys of some animals in the vehicle control group; however, they were significantly lower than those in the lowest exposure group (Table 40, Table 41). The kidney-to-plasma ratios ranged from 1.43 to 4.36 suggesting retention of tungsten in the kidney. There were no consistent trends in the kidney-to-plasma ratios with increasing exposure concentration or duration. There was no observed sex difference in kidney tungsten concentrations in mice (Table 40, Table 41; Figure 13B).

The concentrations of tungsten in urine are presented as both μg/g of urine and μg/mg creatinine. Creatinine-corrected tungsten concentrations in urine increased proportionally with the exposure concentration for both males and females (Figure 13C). As with plasma and kidney, the trend was toward decreasing tungsten concentrations in urine with increasing exposure duration in both male and female mice. Low tungsten concentrations were observed in the urine of some vehicle control groups; however, tungsten concentrations in exposed groups were significantly higher than those in corresponding vehicle control groups (Table 40, Table 41). There was no observed sex difference in urinary tungsten concentrations in mice (Table 40, Table 41; Figure 13C).

### Two-year Study

#### Survival

More mice in the exposed groups of males survived to study termination than in the vehicle control group of males; however, the differences were not significant (Table 42; Figure 14). Survival in females was similar across all groups.

Table 42 Summary of Survival of Male and Female Mice in the Two-year Drinking Water Study of Sodium Tungstate Dihydrate

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
Male
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 5 | 3 | 4 | 6
Natural Deaths | 18 | 16 | 11 | 9
Accidental Deaths | 1 | – | – | –
Animals Surviving to Study Termination | 26 | 31 | 35 | 35
Percent Probability of Survival at End of Study^a^ | 53.1%^b^ | 62.0% | 70.0% | 70.0%
Mean Survival (Days)^c^ | 683.4 ± 9.7 | 684.4 ± 11.6 | 710.4 ± 6.4 | 686.4 ± 13.1
Survival Analysis^d^ | p = 0.107N | p = 0.530N | p = 0.081N | p = 0.158N
Female
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 2 | 1 | 2 | 0
Natural Deaths | 10 | 8 | 10 | 10
Animals Surviving to Study Termination | 38 | 41^e^ | 38 | 40
Percent Probability of Survival at End of Study | 76.0% | 82.0% | 76.0% | 80.0%
Mean Survival (Days) | 699.9 ± 10.2 | 713.5 ± 5.9 | 702.0 ± 10.9 | 704.0 ± 14.8
Survival Analysis | p = 0.809N | p = 0.582N | p = 1.000N | p = 0.743N

^a^ Kaplan-Meier determinations.

^b^ Calculation does not include the accidental death animal.

^c^ Mean of litter means of all deaths (uncensored, censored, and study termination) ± standard error.

^d^ The result of the Cox proportional hazards trend test with random litter effects is in the vehicle control group column, and the results of the proportional hazards pairwise comparisons to the vehicle control with random litter effects are in the exposed group columns. A negative trend or lower mortality in an exposure group is indicated by N.

^e^ Includes one animal that died naturally during the last week of the study.

Figure 14

Kaplan-Meier Survival Curves for Mice Exposed to Sodium Tungstate Dihydrate in Drinking Water for Two Years

#### Body Weights, Water and Compound Consumption, and Clinical Observations

At study termination, the mean body weight of the 2,000 mg/L males was 88% of the vehicle control group; all other groups of exposed males and all groups of exposed females had mean body weights within 10% of their respective vehicle control groups (Table 43, Table 44; Figure 15).

Table 43 Summary of Survival and Mean Body Weights of Male Mice in the Two-year Drinking Water Study of Sodium Tungstate Dihydrate

Study Day^a^ | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Study Day^a^ | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 21.7 | 50 | 21.6 | 99.1 | 50 | 21.6 | 99.3 | 50 | 21.5 | 98.7 | 50
8 | 23.5 | 50 | 23.3 | 99.1 | 50 | 22.9 | 97.4 | 50 | 22.5 | 95.4 | 50
15 | 25.0 | 50 | 24.8 | 99.4 | 50 | 24.4 | 97.9 | 50 | 23.5 | 94.1 | 50
22 | 26.3 | 50 | 25.8 | 98.2 | 50 | 25.6 | 97.5 | 50 | 24.5 | 93.3 | 50
29 | 27.5 | 50 | 27.1 | 98.7 | 50 | 26.7 | 97.3 | 50 | 25.3 | 92.2 | 50
36 | 28.6 | 50 | 28.3 | 98.9 | 50 | 27.8 | 97.3 | 50 | 26.3 | 92.0 | 50
43 | 29.9 | 50 | 29.6 | 99.0 | 50 | 28.9 | 96.6 | 50 | 26.9 | 90.1 | 50
50 | 31.4 | 50 | 31.2 | 99.2 | 50 | 30.4 | 96.6 | 50 | 28.1 | 89.3 | 50
57 | 32.1 | 50 | 32.1 | 100.2 | 50 | 31.3 | 97.5 | 50 | 28.7 | 89.4 | 50
64 | 33.6 | 50 | 33.6 | 100.1 | 50 | 32.2 | 95.9 | 50 | 29.2 | 87.0 | 50
71 | 34.9 | 50 | 34.1 | 97.7 | 50 | 33.8 | 96.7 | 50 | 31.1 | 89.6 | 50
78 | 36.4 | 50 | 35.7 | 97.9 | 50 | 34.8 | 95.4 | 50 | 31.5 | 86.6 | 50
85 | 37.4 | 50 | 36.6 | 97.9 | 50 | 35.6 | 95.3 | 50 | 31.9 | 85.2 | 50
92 | 38.7 | 50 | 37.7 | 97.3 | 50 | 37.0 | 95.5 | 50 | 33.1 | 85.4 | 50
120 | 43.2 | 50 | 42.2 | 97.6 | 50 | 41.0 | 94.9 | 50 | 36.8 | 85.1 | 50
148 | 45.9 | 50 | 45.1 | 98.1 | 50 | 43.8 | 95.4 | 50 | 39.3 | 85.5 | 50
176 | 48.0 | 50 | 46.8 | 97.4 | 50 | 46.0 | 95.9 | 50 | 42.5 | 88.5 | 50
204 | 49.3 | 50 | 48.3 | 98.0 | 50 | 47.3 | 96.1 | 50 | 44.6 | 90.5 | 50
232 | 50.0 | 50 | 48.9 | 97.8 | 50 | 48.2 | 96.2 | 50 | 45.9 | 91.7 | 50
260 | 50.7 | 50 | 49.7 | 97.9 | 50 | 48.8 | 96.3 | 50 | 46.6 | 91.8 | 50
288 | 51.7 | 50 | 50.2 | 97.2 | 50 | 49.4 | 95.7 | 50 | 47.4 | 91.7 | 50
316 | 52.5 | 50 | 51.2 | 97.6 | 50 | 50.5 | 96.3 | 50 | 48.8 | 93.0 | 50
344 | 52.9 | 50 | 51.1 | 96.6 | 50 | 50.9 | 96.1 | 50 | 49.3 | 93.2 | 50
372 | 53.5 | 50 | 51.6 | 96.5 | 50 | 51.4 | 96.2 | 50 | 49.3 | 92.3 | 49
400 | 54.1 | 50 | 51.7 | 95.5 | 50 | 52.1 | 96.2 | 50 | 50.1 | 92.7 | 49
428 | 54.2 | 50 | 51.4 | 94.7 | 50 | 52.2 | 96.3 | 50 | 50.3 | 92.7 | 47
456 | 54.3 | 50 | 51.6 | 95.0 | 48 | 52.5 | 96.7 | 50 | 50.5 | 92.9 | 47
484 | 54.5 | 49 | 51.9 | 95.3 | 47 | 52.5 | 96.3 | 50 | 50.1 | 91.9 | 47
512 | 54.5 | 47 | 52.4 | 96.1 | 46 | 52.5 | 96.4 | 49 | 49.3 | 90.5 | 47
540 | 54.6 | 47 | 52.2 | 95.7 | 45 | 52.5 | 96.2 | 49 | 49.0 | 89.7 | 45
568 | 53.8 | 46 | 50.9 | 94.6 | 44 | 52.3 | 97.3 | 49 | 47.7 | 88.8 | 43
596 | 53.2 | 43 | 50.0 | 93.9 | 42 | 51.5 | 96.7 | 48 | 46.6 | 87.6 | 43
624 | 51.8 | 41 | 49.7 | 96.0 | 41 | 50.5 | 97.5 | 46 | 46.5 | 89.9 | 42
652 | 50.9 | 38 | 49.0 | 96.2 | 39 | 50.1 | 98.3 | 44 | 46.3 | 91.0 | 40
680 | 49.1 | 34 | 46.6 | 94.8 | 37 | 47.4 | 96.5 | 44 | 45.3 | 92.1 | 39
708 | 48.8 | 27 | 44.6 | 91.4 | 35 | 45.2 | 92.6 | 38 | 42.4 | 87.0 | 38
EOS | 49.8 | 26 | 47.1 | 94.4 | 31 | 45.9 | 92.0 | 35 | 43.9 | 88.0 | 35

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Table 44 Summary of Survival and Mean Body Weights of Female Mice in the Two-year Drinking Water Study of Sodium Tungstate Dihydrate

Study Day^a^ | 0 mg/L | | 500 mg/L | | | 1,000 mg/L | | | 2,000 mg/L
Study Day^a^ | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 15.9 | 50 | 15.7 | 99.2 | 50 | 16.1 | 101.4 | 50 | 16.1 | 101.3 | 50
8 | 17.5 | 50 | 17.5 | 99.8 | 50 | 17.0 | 97.1 | 50 | 17.3 | 98.9 | 50
15 | 18.5 | 50 | 18.4 | 99.6 | 50 | 18.2 | 98.3 | 50 | 18.2 | 98.6 | 50
22 | 19.5 | 50 | 19.4 | 99.3 | 50 | 18.9 | 96.7 | 50 | 19.2 | 98.5 | 50
29 | 20.5 | 50 | 20.5 | 100.3 | 50 | 20.1 | 98.3 | 50 | 19.9 | 97.2 | 50
36 | 21.2 | 50 | 21.1 | 99.4 | 50 | 21.0 | 99.0 | 50 | 20.7 | 97.6 | 50
43 | 22.6 | 50 | 22.4 | 99.1 | 50 | 22.0 | 97.7 | 50 | 21.7 | 96.2 | 50
50 | 22.9 | 50 | 22.8 | 99.9 | 50 | 22.2 | 97.1 | 50 | 22.4 | 98.1 | 49
57 | 23.7 | 50 | 23.3 | 98.4 | 50 | 23.0 | 97.2 | 50 | 23.3 | 98.5 | 49
64 | 24.6 | 50 | 24.7 | 100.0 | 50 | 23.9 | 97.2 | 50 | 23.9 | 97.1 | 49
71 | 25.5 | 50 | 25.5 | 99.8 | 50 | 25.0 | 98.0 | 50 | 25.1 | 98.2 | 49
78 | 26.7 | 50 | 26.5 | 99.2 | 50 | 26.0 | 97.2 | 50 | 25.7 | 96.4 | 49
85 | 27.8 | 50 | 27.0 | 96.9 | 50 | 26.8 | 96.2 | 50 | 26.9 | 96.6 | 49
92 | 28.6 | 50 | 28.2 | 98.7 | 50 | 27.5 | 96.0 | 50 | 27.5 | 96.2 | 49
120 | 33.5 | 50 | 32.5 | 97.2 | 50 | 31.5 | 94.2 | 50 | 31.5 | 94.2 | 49
148 | 38.1 | 50 | 37.6 | 98.7 | 50 | 35.6 | 93.5 | 50 | 36.3 | 95.2 | 49
176 | 41.7 | 50 | 41.2 | 98.8 | 50 | 38.9 | 93.4 | 50 | 39.7 | 95.3 | 49
204 | 45.6 | 50 | 44.6 | 97.8 | 50 | 42.0 | 92.2 | 50 | 42.8 | 93.9 | 49
232 | 48.2 | 50 | 47.0 | 97.5 | 50 | 44.3 | 91.8 | 50 | 45.2 | 93.8 | 49
260 | 50.2 | 50 | 49.3 | 98.2 | 50 | 47.0 | 93.7 | 49 | 47.9 | 95.3 | 49
288 | 52.3 | 50 | 51.7 | 98.9 | 50 | 48.5 | 92.7 | 49 | 49.5 | 94.5 | 49
316 | 54.9 | 50 | 53.9 | 98.3 | 50 | 51.1 | 93.0 | 49 | 51.8 | 94.3 | 49
344 | 55.0 | 50 | 54.3 | 98.7 | 50 | 51.7 | 93.9 | 49 | 52.2 | 94.8 | 49
372 | 56.8 | 50 | 56.7 | 99.8 | 50 | 53.7 | 94.4 | 49 | 54.3 | 95.6 | 49
400 | 58.5 | 50 | 58.2 | 99.4 | 50 | 55.3 | 94.4 | 49 | 55.1 | 94.2 | 49
428 | 57.9 | 49 | 58.2 | 100.5 | 50 | 55.3 | 95.5 | 49 | 55.9 | 96.6 | 49
456 | 59.8 | 48 | 59.1 | 98.9 | 50 | 56.8 | 95.0 | 49 | 56.9 | 95.1 | 48
484 | 60.8 | 48 | 60.1 | 98.8 | 50 | 57.9 | 95.2 | 49 | 57.6 | 94.8 | 48
512 | 61.4 | 48 | 60.0 | 97.8 | 50 | 58.2 | 94.9 | 49 | 57.7 | 94.1 | 48
540 | 61.6 | 48 | 61.1 | 99.2 | 49 | 59.1 | 96.0 | 49 | 58.6 | 95.2 | 48
568 | 61.2 | 45 | 60.7 | 99.0 | 49 | 58.6 | 95.7 | 49 | 57.8 | 94.3 | 48
596 | 61.2 | 44 | 59.4 | 97.2 | 49 | 57.6 | 94.2 | 49 | 58.1 | 95.0 | 48
624 | 61.1 | 44 | 59.0 | 96.5 | 48 | 58.2 | 95.2 | 44 | 57.4 | 93.8 | 48
652 | 59.9 | 44 | 59.5 | 99.4 | 45 | 58.3 | 97.3 | 43 | 56.3 | 93.9 | 48
680 | 59.0 | 42 | 57.6 | 97.6 | 44 | 57.8 | 97.9 | 42 | 56.0 | 95.0 | 45
708 | 56.6 | 39 | 53.6 | 94.7 | 42 | 54.3 | 96.0 | 41 | 52.7 | 93.1 | 43
EOS | 57.1 | 38 | 54.9 | 96.1 | 40 | 54.9 | 96.2 | 38 | 53.8 | 94.2 | 40

EOS = end of study.

^a^ Study day 1 is the day animals were placed on study.

Figure 15

Growth Curves for Mice Exposed to Sodium Tungstate Dihydrate in Drinking Water for Two Years

Group mean water consumption over the course of the study for ST-exposed males for the 500, 1,000, and 2,000 mg/L groups averaged 96%, 90%, and 85% of the vehicle control group, respectively (Table 45). For the ST-exposed females, group water consumption values for the 500, 1,000, and 2,000 mg/L groups averaged 105%, 97%, and 93% of the vehicle control group, respectively (Table 46). Daily ST consumption for the 500, 1,000, and 2,000 mg/L groups averaged 42.5, 80.0 and 158.1 mg/kg/day, respectively, for the males and 29.0, 56.2, and 107.0 mg/kg/day, respectively, for the females (Table 45, Table 46). In general, ingested dose increased proportionally with the exposure concentration for both sexes. More occurrences of thinness and ruffled fur were recorded in exposed groups of male mice compared to vehicle control males; clinical observations were similar in all groups of females (Appendix G).

Table 45 Summary of Water and Sodium Tungstate Dihydrate Consumption of Male Mice in the Two-year Drinking Water Study

Week | 0 mg/L | 500 mg/L | | 1,000 mg/L | | 2,000 mg/L
Week | Water (g/day)^a^ | Water (g/day) | Dose (mg/kg/day)^b^ | Water (g/day) | Dose (mg/kg/day) | Water (g/day) | Dose (mg/kg/day)
1 | – | – | – | – | – | – | –
13 | 3.2 | 3.3 | 45.1 | 3.0 | 84.2 | 2.8 | 175.7
54 | 4.1 | 4.1 | 39.7 | 3.7 | 72.0 | 3.3 | 133.8
102 | 4.9 | 4.1 | 46.0 | 4.3 | 95.1 | 3.8 | 179.1

^a^ Grams of water consumed/animal/day.

^b^ Milligrams of sodium tungstate dihydrate consumed/kilogram body weight/day.

Table 46 Summary of Water and Sodium Tungstate Dihydrate Consumption of Female Mice in the Two-year Drinking Water Study

Week | 0 mg/L | 500 mg/L | | 1,000 mg/L | | 2,000 mg/L
Week | Water (g/day)^a^ | Water (g/day) | Dose (mg/kg/day)^b^ | Water (g/day) | Dose (mg/kg/day) | Water (g/day) | Dose (mg/kg/day)
1 | 1.9 | 1.8 | 57.2 | 1.8 | 111.9 | 1.7 | 211.5
13 | 2.5 | 2.6 | 48.2 | 2.3 | 85.9 | 2.2 | 163.7
54 | 2.4 | 2.5 | 22.0 | 2.3 | 42.9 | 2.4 | 88.4
102 | 2.9 | 3.4 | 31.7 | 2.8 | 51.5 | 2.6 | 98.6

^a^ Grams of water consumed/animal/day.

^b^ Milligrams of sodium tungstate dihydrate consumed/kilogram body weight/day.

#### Histopathology

This section describes the significant or biologically noteworthy changes in the incidences of neoplasms and nonneoplastic lesions of the kidney, liver, large intestine (cecum), and testes. Summaries of the incidences of neoplasms and nonneoplastic lesions and statistical analyses of primary neoplasms are presented as supplemental data in Appendix G.

Kidney: Renal tubule neoplasms were only recorded in exposed males; there was one renal tubule adenoma in the 1,000 mg/L males and two renal tubule carcinomas in the 2,000 mg/L males (Table 47). Additional step sections of the kidneys were examined from all male and female mice, but additional renal tubule neoplasms were not observed. Proliferative lesions identified by the kidney step section pathologist were considered part of the spectrum of lesions associated with CPN by the pathology working group (PWG). Renal tubule regeneration was significantly increased in all exposed groups of males and in the 1,000 and 2,000 mg/L females, relative to vehicle control groups (Table 47). The incidences of pigment in the kidney were significantly increased compared to the vehicle control groups in the 2,000 mg/L males and 1,000 mg/L females, and lower in the 500 and 1,000 mg/L males compared to the vehicle control group (Table 47). Given the high incidence of pigment in the male vehicle control group, and the lack of an exposure concentration response in either the males or females, the finding of pigment in the kidney of exposed animals is of questionable toxicological importance. Also, in males, there was a positive trend for renal tubule necrosis with increased exposure (Table 47).

Table 47 Incidences of Neoplastic and Nonneoplastic Lesions of the Kidney in Male and Female Mice in the Two-year Drinking Water Study of Sodium Tungstate Dihydrate

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
n ^a^ | 50 | 50 | 50 | 50
Male
Renal Tubule, Regeneration^b^ | 2** (1.0)^c^ | 21** (1.4) | 32** (1.4) | 38** (1.6)
Renal Tubule, Necrosis | 0* | 0 | 0 | 3 (1.3)
Pigment | 30** (1.0) | 10 (1.0) | 18 (1.2) | 44** (1.0)
Renal Tubule, Adenoma^d^ | 0 | 0 | 1 | 0
Renal Tubule, Carcinoma^e^
Overall rate^f^ | 0/50 (0%) | 0/50 (0%) | 0/50 (0%) | 2/50 (4%)
Adjusted rate^g^ | 0% | 0% | 0% | 4.6%
Terminal rate^h^ | 0/26 (0%) | 0/31 (0%) | 0/35 (0%) | 2/35 (6%)
First incidence (days) | _^i^ | _ | _ | 730 (T)
Poly-3 test^j^ | p = 0.047 | (e) | (e) | p = 0.244
Renal Tubule, Adenoma or Carcinoma (Combined)^k^
Overall rate | 0/50 (0%) | 0/50 (0%) | 1/50 (2%) | 2/50 (4%)
Adjusted rate | 0% | 0% | 2.2% | 4.6%
Terminal rate | 0/26 (0%) | 0/31 (0%) | 1/35 (3%) | 2/35 (6%)
First incidence (days) | _ | _ | 730 (T) | 730 (T)
Poly-3 test | p = 0.073 | (e) | p = 0.520 | p = 0.244
Female
Renal Tubule, Regeneration | 0** | 1 (3.0) | 7** (1.1) | 7** (1.3)
Renal Tubule, Necrosis | 1 (2.0) | 5 (1.0) | 1 (1.0) | 3 (2.7)
Pigment | 0 | 0 | 6* (1.0) | 1 (1.0)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Poly-3 test; **p ≤ 0.01.

(T) = study termination; (e) = statistic could not be computed.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 1/687 (0.15% ± 0.55%); range: 0% to 2%.

^e^ Historical control incidence: 2/687 (0.31% ± 1.11%); range: 0% to 4%.

^f^ Number of animals with neoplasm/number of animals necropsied.

^g^ Poly-3 estimated neoplasm incidence after adjustment for intercurrent mortality.

^h^ Observed incidence at terminal euthanasia.

^i^ Not applicable; no neoplasms in group.

^j^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidences are the p values corresponding to pairwise comparisons between the vehicle control group and that exposed group. The Poly-3 test accounts for differential mortality in animals that do not reach terminal euthanasia. A negative trend or a lower incidence in an exposure group is indicated by N.

^k^ Historical control incidence: 3/687 (0.46% ± 1.66%); range: 0% to 6%.

The renal tubule adenoma was a discrete nodule that protruded slightly above the cortical surface (Figure 16). It was a well-circumscribed cellular mass composed of well-differentiated renal tubule epithelial cells. The renal cell carcinomas, in contrast to the adenoma, were large and invasive, effacing and replacing more than 60% of the renal parenchyma (Figure 17). The carcinomas had solid and cystic areas and displayed marked cellular pleomorphism and a high mitotic rate.

Figure 16

Renal Tubule Adenoma in a Male B6C3F1/N Mouse Exposed to 1,000 mg/L Sodium Tungstate Dihydrate for Two Years (H&E)

The adenoma is a well-circumscribed mass, which is protruding above the surface of the kidney. It is composed of a solid sheet of well-differentiated epithelial cells.

Figure 17

Renal Tubule Carcinoma in a Male B6C3F1/N Mouse Exposed to 2,000 mg/L Sodium Tungstate Dihydrate for Two Years (H&E)

A) The neoplasm is very large and has almost completely obliterated the kidney; only a small amount of uninvolved kidney remains (arrows). B) Higher magnification of the renal tubule carcinoma in panel A; the neoplasm is densely cellular and one area in particular (circle) displays cells with a very high nuclear-to-cytoplasmic ratio.

A normal kidney from a B6C3F1/N mouse is shown in Figure 18. Renal tubule regeneration was characterized by basophilia, karyomegaly, hypertrophy, and hyperplasia of the renal tubule epithelium (Figure 19). Occasional mitotic figures were also present. Severity grading was based on the amount of renal cortex involved, with minimal regeneration involving <10% of the cortex; mild regeneration involving approximately 10%–25% of the cortex; moderate regeneration involving approximately 26%–75% of the cortex, and marked regeneration involving over 75% of the cortex. Renal tubule regeneration often occurred in kidneys that also had CPN, and the lesions had to be separated diagnostically. Basophilic and hyperplastic tubules could also be seen in CPN, but with CPN, the tubules would also have thickened basement membranes. Affected renal tubules of CPN tended to lack the amount of karyomegaly, hypertrophy, and hyperplasia that was characteristic of the epithelium seen in regeneration. Also, the pattern of the regeneration was somewhat different from that of CPN—with low magnification, moderate to severe regeneration could be seen to affect the cortex in a thick band sparing the medulla (generally affecting the proximal convoluted tubule); the lesions of CPN typically were not so evenly distributed.

Figure 18

Normal Kidney from a Vehicle Control Female B6C3F1/N Mouse in the Two-year Study of Sodium Tungstate Dihydrate (H&E)

A) This normal kidney is from a vehicle control female B6C3F1/N mouse. B) This shows a higher magnification of the normal kidney in panel A.

Figure 19

Moderate Renal Tubule Regeneration in a Female B6C3F1/N Mouse Exposed to 2,000 mg/L Sodium Tungstate Dihydrate for Two Years (H&E)

A) This low magnification photomicrograph shows a thick band of basophilia due to regeneration of the renal tubules involving the cortex (arrows). Compare with the kidney in Figure 18A. B) This higher magnification of the renal tubule regeneration in panel A shows that the tubules are basophilic and the cells are crowded, consistent with hyperplasia and regeneration. There are no thickened basement membranes or other evidence of chronic progressive nephropathy, such as associated interstitial inflammation. Compare with the section of kidney in Figure 18B.

Pigment in the kidney was light golden brown and was usually located in or around tubules with CPN or regeneration, either in the renal tubule epithelium or in macrophages. All of the occurrences of kidney pigment in females, and almost all in males, were of minimal severity. This pigment most likely represents a background change, with the high incidences due to the lack of any threshold used for diagnosis.

Renal tubule necrosis was recorded in three 2,000 mg/L males and was characterized by renal tubule epithelial cells with brightly eosinophilic cytoplasm and pyknotic or missing nuclei; affected cells were often shrunken, irregular in shape, or sloughed off of their basement membrane (Table 47).

Large Intestine, Cecum: The incidences of pigment in the cecum were significantly increased in the 1,000 and 2,000 mg/L males and females (Table 48). The pigment was found in macrophages, and possibly fibroblasts, within the lamina propria of the cecum, and was similar in character to that observed in the kidney; it was light golden brown (Figure 20). Cells containing pigment were usually observed in small clusters, but were not associated with other lesions, such as mucosal inflammation or ulceration. Special staining with Perl’s stain for iron did not reveal iron in the pigment, therefore, the pigment was not hemosiderin. Other possibilities include pigments associated with cell breakdown, such as lipofuscin or ceroid.

Testes: There were increased incidences of germinal epithelium degeneration recorded in the testes of all exposed groups of males compared to the vehicle control group, and the increase was significant in the 500 mg/L group (Table 48). Germinal epithelial degeneration consisted of several changes, including vacuolation of the germinal epithelium, disorganization of the germinal epithelium, or depletion of germs cells (Figure 21). Typically, especially with minimal and mild lesions, only one or two seminiferous tubules were affected; however, the involvement of only one seminiferous tubule might present as several cross sections of tubules within a section of testis. Marked lesions were characterized by seminiferous tubules with only Sertoli cells remaining (atrophy); this was usually a widespread to diffuse change throughout the testis.

Table 48 Incidences of Select Nonneoplastic Lesions in Male and Female Mice in the Two-year Drinking Water Study of Sodium Tungstate Dihydrate

| 0 mg/L | 500 mg/L | 1,000 mg/L | 2,000 mg/L
n^a^ | 50 | 50 | 50 | 50
Male
Large Intestine, Cecum
Pigment^b^ | 3** (1.0)^c^ | 7 (1.0) | 17** (1.0) | 32** (1.0)
Testis
Germinal epithelium, degeneration | 11 (1.5) | 20* (1.3) | 20 (1.5) | 20 (2.2)
Female
Large Intestine, Cecum
Pigment | 0** | 3 (1.0) | 7** (1.0) | 14** (1.0)

Statistical significance for an exposure group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the vehicle control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05 by the Poly-3 test; **p ≤ 0.01.

^a^ Number of animals examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of observed lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Figure 21

Germinal Epithelium Degeneration in the Testis from B6C3F1/N Mice Exposed to 2,000 mg/L Sodium Tungstate Dihydrate for Two Years (H&E)

A) Testis from a B6C3F1/N mouse exposed to 2,000 mg/L sodium tungstate dihydrate (ST) is within normal limits. B) Testis from a B6C3F1/N mouse exposed to 2,000 mg/L ST shows widespread degeneration of the germinal epithelium. A thinning of the germinal epithelium of the seminiferous tubules is observed due to a decrease in the number of cells; compare with the testis in panel A.

Bone Marrow and Spleen: Hypercellularity of the bone marrow was significantly increased in incidence in the 500 and 1,000 mg/L males; the incidence of extramedullary hematopoiesis in the spleen was significantly increased in the 500 and 1,000 mg/L females (Table 48). Hypercellularity of the bone marrow was characterized by cells filling the marrow cavity, throughout the length of the femur. Little adipose tissue was observed. Both the erythroid and myeloid cell lines appeared to have increased in most cases. Megakaryocytes were also abundant in affected animals. Most of the cases were minimal to mild in severity, although an occasional animal had moderate to marked hypercellularity recorded; severity was graded subjectively and was based on the amount of blood cell precursors and the lack of adipocytes compared to the vehicle control animals and what would be expected in a chronic study. Extramedullary hematopoiesis in the spleen is common in mice, even at 2 years. As such, extramedullary hematopoiesis was recorded when it appeared increased over that which would be expected in the spleen. It usually involved an expansion of the red pulp, which was filled with cells containing little cytoplasm and dense basophilic nuclei. Evidence of both erythroid and myeloid lineages were typically present, as were abundant megakaryocytes. The toxicological significance of the differences in the incidences of bone marrow hyperplasia and extramedullary hematopoiesis in the spleen is unknown.

Other Tissues: There were significantly increased incidences of hepatocellular adenomas and carcinomas, combined, in the 500 mg/L females. This group also had a significant increase in the incidences of eosinophilic foci and focal inflammation. Hepatocellular neoplasms are common in B6C3F1 female mice, with a historical control range of up to 28% for adenomas, and up to 40% for adenomas and carcinomas combined. There was no exposure concentration relationship in the incidences of either the neoplastic or nonneoplastic lesions observed in the liver, and the incidences of hepatocellular adenomas and hepatocellular carcinomas were within the historical control range for each group (Appendix G). Therefore, the increased incidence in the 500 mg/L females was considered biological variation, and not related to ST exposure.

Figure 20

Pigment in the Cecum of B6C3F1/N Mice Exposed to 0 or 2,000 mg/L Sodium Tungstate Dihydrate for Two Years (H&E)

A) This normal cecum is from a B6C3F1/N vehicle control female mouse. B) In this cecum in a female B6C3F1/N mouse exposed to 2,000 mg/L sodium tungstate dihydrate, the golden-brown pigment is contained primarily in macrophages within the lamina propria (circle). Compare with the section of cecum in panel A.

## Genetic Toxicology

The genetic toxicity of ST was evaluated in bacterial reverse mutation assays and in both the peripheral blood micronucleus test and the comet assay in rats and mice. ST significantly increased DNA damage in the comet assay in liver cells from male and female rats, and in cells from liver and ileum tissues in male mice (Appendix D).

ST (12.5 to 6,000 μg/plate) was not mutagenic in Salmonella typhimurium strains TA98 or TA100, or in Escherichia coli WP2 uvrA (pKM101), when tested with or without exogenous metabolic activation provided by phenobarbital/benzoflavone-induced rat S9 and cofactors (Table D-1).

At the end of the 3-month studies, peripheral blood samples were obtained from male and female rats and mice and analyzed for the frequency of micronucleated reticulocytes and erythrocytes (Table D-2, Table D-3). In male and female rats, the reticulocyte population (polychromatic erythrocytes, or PCEs)—which is the only red blood cell population that can be accurately assessed for micronucleus frequency in peripheral blood of rats due to efficient splenic scavenging of damaged erythrocytes—did not show an increase in micronucleated cells after 3 months of exposure to ST via drinking water (0, 125, 250, 500, 1,000, and 2,000 mg/L) (Table D-2). Significant increases in the percent reticulocytes were seen in both male and female rats suggesting that ST could have stimulated erythropoiesis in the bone marrow; however, the absolute increases in the percentages were small compared to the vehicle control animals.

In male and female mice, there were no significant increases in micronucleated reticulocytes or in micronucleated erythrocytes in either sex following 3 months of exposure to ST via drinking water (0, 125, 250, 500, 1,000, and 2,000 mg/L) (Table D-3). A significant increase in the percent reticulocytes was seen in male mice suggesting that ST could have stimulated erythropoiesis in the bone marrow; however, the absolute increase was small compared to the vehicle control group.

In addition to evaluating the potential for chromosomal damage, the potential for DNA damage was assessed using the comet assay in the same animals in which micronucleus induction was evaluated. DNA damage from exposure to ST was assessed in liver, ileum, and kidney cell samples and in blood leukocytes (Table D-4, Table D-5). Significant increases in DNA damage, measured as percent tail DNA, were observed in liver cells from male and female rats. Significant increases in DNA damage were also observed in liver and ileum cells from male mice. No increases in percent tail DNA were observed in female mice. Although cells from kidney tissue were evaluated for male and female rats, and ileum tissue was evaluated from male rats, results from these tissues were considered invalid due to unusually high percent tail DNA in the vehicle control group.