# Materials and Methods

## Procurement and Characterization of Sodium Tungstate Dihydrate

Sodium tungstate dihydrate (ST) was procured from Sigma-Aldrich (St. Louis, MO) in two lots (lot 12330JO and lot MKBG9975V). Lot 12330JO was obtained directly from Sigma-Aldrich (St. Louis, MO), whereas lot MKBG9975V was produced by Sigma-Aldrich and obtained from Government Scientific Source, Inc. (Reston, VA). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory and study laboratory at Battelle (Columbus, OH) (Appendix A). Reports on analyses performed in support of the ST studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

Lots 12330JO and MKBG9975V were white solids composed of fine crystals. The 3-month studies used lot 12330JO. For the 2-year studies, the remainder of lot 12330JO was combined with lot MKBG9975V to create lot 07072011.

The identities of the lots were confirmed using infrared spectroscopy. X-ray diffraction patterns were in good agreement with reference standards, and proton-induced x-ray emission spectroscopy yielded expected percent weights of tungsten and sodium. Magnesium (0.7%–0.9%) and aluminum (approximately 0.3%) impurities were identified in both lots. The purities of lots 12330JO and 07072011 were both determined to be approximately 99% using inductively coupled plasma atomic emission spectrometry based on weight percentages of tungsten (55.2%–56.4%) and sodium (13.4%–13.8%). Karl Fisher titration yielded a water content of 9.5% for lot 12330JO and 10.0%–10.3% for lot 07072011, slightly lower than the anticipated 10.9%. Titration of tungstate ion with lead nitrate indicated a purity of 97.6% for lot 12330JO and 98.2% for lot 07072011. Ion chromatography (IC) with a suppressed conductivity detector and liquid chromatography with an inductively coupled plasma-mass spectrometer indicated a purity of 100% for both lots.

Accelerated stability studies were conducted on lot 12330JO and lot MKBG9975V using IC with a suppressed conductivity detector. Stability was confirmed for at least 2 weeks when ST was stored in sealed amber glass bottles at 25°C, 5°C, and −20°C. Therefore, bulk ST was stored in sealed amber glass bottles at 25°C. Periodic analyses of the bulk chemical were conducted during the 3-month and 2-year studies by the study laboratory, and no degradation of the bulk chemical was detected.

## Preparation and Analysis of Dose Formulations

The feed (NIH-07 and NTP-2000) and deionized water used in the 3-month and 2-year studies were analyzed for tungsten and molybdenum concentrations. NIH-07 feed contained approximately 2 ppm tungsten and the concentration in NTP-2000 feed was at the detection limit of the assay (0.80 ppm). Concentrations of tungsten in the deionized water, and the concentration of molybdenum in all feed and water samples, were below the limits of detection of the assay (0.20 to 0.80 ppm).

Stability studies conducted on the 20 mg/L formulation by the analytical chemistry laboratory found that the formulation was stable when sealed and stored in Nalgene bottles for 42 days at 5°C and at room temperature (approximately 25°C). An animal room simulation was conducted using the 20 mg/L formulation stored in a drinking water bottle with aliquots periodically removed to simulate animal drinking. There was no significant loss in tungsten over 7 days at room temperatures.

Dose formulations of ST were prepared monthly (Table A-2). Dose formulations were prepared in deionized water. The 3-month study dose formulations were 0, 125, 250, 500, 1,000, and 2,000 mg/L for both mice and rats. The 2-year mouse study used 0, 500, 1,000 and 2,000 mg/L dose formulations, whereas the 2-year rat study used 0, 250, 500, and 1,000 mg/L dose formulations. Dose formulations were stable for 42 days at room temperature (Appendix A).

Preadministration and postadministration (animal room) analyses of dose formulations were conducted monthly throughout the 3-month studies (Table A-3, Table A-4). During the 2-year studies, preadministration dose formulations were analyzed every 1–3 months, whereas postadministration dose formulations were analyzed every 6–8 months (Table A-5, Table A-6). All preadministration formulations in the 3-month rat and mouse studies were within 10% of the target concentration. In the 3-month mouse study, four postadministration samples were more than 10% below the target concentration, with the largest difference being 12.8% below the target. Three postadministration samples collected from carboys or bottles for the 125, 500, and 2,000 mg/L dose formulations in the 3-month rat study were 10.8% to 12.3% below the corresponding target concentration. In the 2-year studies, all preadministration and postadministration samples were within 10% of the target concentration.

## Animal Source

Time-mated (F_0_) female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Harlan Inc. (now Envigo, Indianapolis, IN) for the 3-month and 2-year studies. B6C3F1/N mice were obtained from Taconic Biosciences, Inc. (Germantown, NY) for the 3-month and 2-year studies.

## Animal Welfare

Animal care and use were in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle (Columbus, OH) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health (NIH) and National Toxicology Program (NTP) animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

### Initial Exposure Concentration Selection Rationale

For the perinatal and 3-month study in rats and the 3-month study in adult mice, selection of exposure concentrations of 125, 250, 500, 1,000, and 2,000 mg/L ST was based on available data including a study evaluating the antidiabetic effects of ST in rats following 8 months of exposure via drinking water, which showed no effect on survival and some effect on body weight.^36^ The effects from these exposures were then evaluated for selecting exposures for the chronic study, a study focused on determining the potential chronic toxicity and carcinogenic hazard of sodium tungstate.

### Study Design for Rats

F_0_ female rats were 11 to 12 weeks old upon receipt. Gestation day (GD) 1 was defined as the first day with evidence of mating. F_0_ females were received on GD 1 and held for 5 days. F_0_ females were randomly assigned to one of six exposure groups on GD 5 (eight dams/group). Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Cedar Knolls, NJ).

F_0_ females were quarantined for 39 days after receipt. Ten nonmated females received in the same shipment as the time-mated dams were designated for disease monitoring and were used for gross necropsies 2 days after arrival; samples were collected for the presence of disease. The health of the F_1_ animals was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Beginning on GD 6, groups of eight F_0_ time-mated females were provided ST in drinking water throughout gestation and lactation at one of five exposure concentrations (125, 250, 500, 1,000, or 2,000 mg/L) or the vehicle control (deionized water). Groups of 10 F_1_ rats per sex continued on in the study after weaning and were provided drinking water containing the same respective ST concentration for 3 months.

F_0_ female rats were housed individually during gestation and with their respective litters during lactation. Feed and dosed water were available ad libitum. Dam body weights were recorded on GDs 5, 6, 9, 12, 15, 18, and 21 and on lactation days (LDs) 1, 4, 7, 14, and 21. During gestation, water consumption was measured over 3-day intervals from GD 6 through GD 21 (GDs 6–9, 9–12, 12–15, 15–18, and 18–21). The day of parturition was considered to be postnatal (PND) 0. On apparent GD 25, all time-mated females that failed to deliver were euthanized and the uteri were examined and stained for evidence of implantation. Total litter weight and litter weights by sex were collected on PND 1. Individual pup weights were recorded on PNDs 4, 7, 14, and 21. On PND 1, clinical observations, including general appearance were recorded. Pup survival was evaluated and recorded. During lactation, water consumption was measured over 3-day intervals from PND 1 through PND 21 (PNDs 1–4, 4–7, 7–10, 10–14, 14–17, 17–21).

F_1_ litters were standardized on PND 4 to eight pups per litter, with at least two pups of each sex and a preference for four males and four females each. Litters that did not meet the minimum of eight pups (or if they had fewer than two pups of either sex) were removed from the study. On the day the last litter reached PND 20, pups were randomly assigned to the 3-month study. For all exposure concentrations, except the 2,000 mg/L group, two pups per sex from five randomly selected litters per exposure group were chosen. For the 2,000 mg/L group, a third male pup was selected from two of the four available litters and a third female pup was selected from the other two litters to obtain the complete number of animals needed for the study. After assignments to the 3-month study were complete, five pups per sex from the remaining vehicle control pups were randomly selected as the end-of-study sentinel animals. On the day the last litter reached PND 21, dams were removed, and the pups were weaned. Weaning marked the beginning of the 3-month study.

After weaning, F_1_ rats were housed five per cage. Feed and dosed water were available ad libitum. Water consumption was measured weekly for 3 months. Cages were changed weekly though PND 4, then changed twice weekly. Racks were changed and rotated at least every 2 weeks. Further details of animal maintenance are given in Table 1.

Table 1 Experimental Design and Materials and Methods in the Three-month and Two-year Drinking Water Studies of Sodium Tungstate Dihydrate

Three-month Studies | Two-year Studies
Study Laboratory
Rats: Battelle (Columbus, OH) | Same as 3-month studies
Mice: Battelle (Columbus, OH)
Strain and Species
Rats: Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) | Same as 3-month studies
Mice: B6C3F1/N
Animal Source
Rats: Harlan Laboratories, Inc. (now Envigo; Indianapolis, IN) | Same as 3-month studies
Mice: Taconic Biosciences, Inc. (Germantown, NY)
Time Held Before Studies
F_0_ female rats: 5 days | F_0_ female rats: 4 days
Mice: 11 days | Mice: 11 days
Average Age When Studies Began
F_0_ female rats: 12 to 13 weeks | F_0_ female rats: 12 to 15 weeks
Mice: 5 to 6 weeks | Mice: 5 to 6 weeks
Date of First Exposure
F_0_ female rats: May 23, 2009 F_1_ rats: June 30 (males) or July 1 (females), 2009 | F_0_ female rats: December 23, 2011 F_1_ rats: January 30 (males) or 31 (females), 2012
Mice: June 1 (females) or 2 (males), 2009 | Mice: January 16 (females) or 17 (males), 2012
Duration of Exposure
F_0_ female rats: GD 6 to LD 21 F_1_ rats: 3 months | F_0_ female rats: GD 6 to LD 21 F_1_ rats (interim evaluations): 3, 6, 12, and 18 months F_1_ rats (2-year study): 105 weeks
Mice: 3 months | Mice (interim evaluations): 3, 6, 12, and 18 months Mice (2-year study): 105 weeks
Date of Last Exposure
F_0_ female rats: June 30, 2009 F_1_ rats: September 28 (males) or 29 (females), 2009 | F_0_ female rats: January 30, 2012 F_1_ rats (3-month interim): May 1 (males) or 2 (females), 2012 F_1_ rats (6-month interim): August 1 (males) or 2 (females), 2012 F_1_ rats (12-month interim): January 30 (males) or 31 (females), 2013 F_1_ rats (18-month interim): July 31 (males) or August 1 (females), 2013 F_1_ rats (2-year study): January 28 (males) or 31 (females), 2014
Mice: August 31 (females) or September 1 (males), 2009 | Mice (3-month interim): April 17 (females) or 18 (males), 2012 Mice (6-month interim): July 17 (females) or 18 (males), 2012 Mice (12-month interim): January 15 (females) or 16 (males), 2013 Mice (18-month interim): July 16 (females) or 17 (males), 2013 Mice (2-year study): January 15 (females) or 17 (males), 2014
Necropsy Dates
F_1_ rats: September 28 (males) or 29 (females), 2009 | F_1_ rats (2-year study): January 27 and 28 (males) or 29 to 31 (females), 2014
Mice: August 31 (females) or September 1 (males), 2009 | Mice (2-year study): January 13 to 15 (females) or 15 to 17 (males), 2014
Average Age at Necropsy
F_1_ rats: 15 to 16 weeks | F_1_ rats (2-year study): 108 weeks
Mice: 18 to 19 weeks | Mice (2-year study): 109 to 110 weeks
Size of Study Groups
F_0_ female rats: 8 F_1_ rats: 10/sex | F_0_ female rats: 47 (0 mg/L) or 41 (250, 500, and 1,000 mg/L) F_1_ rats (interim evaluations): 40/sex F_1_ rats (2-year study): 50/sex
Mice: 10/sex | Mice (interim evaluations): 40/sex Mice (2-year study): 50/sex
Method of Distribution
Rats: Dams were distributed randomly into groups of approximately equal initial mean body weights. Pups were standardized on each litter’s respective PND 4 to a maximum of eight pups per litter. Weaned pups were randomized on PND 20. | Rats: Dams were distributed randomly into groups of approximately equal initial mean body weights. Pups were standardized on each litter’s respective PND 4 to a maximum of eight pups per litter. Weaned pups were randomized on PND 19.
Mice: Animals were distributed randomly into groups of approximately equal initial mean body weights. | Mice: Same as 3-month study
Animals per Cage
F_0_ female rats: 1 (with litter) F_1_ rats: 5 (males) or 5 (females) | F_0_ female rats: 1 (with litter) F_1_ rats: up to 2 (males) or up to 5 (females)
Mice: 1 (male) or 5 (females) | Mice: 1 (male) or up to 4 (females)
Method of Animal Identification
F_0_ female rats: Cage card and tail marking with permanent pen F_1_ rats: Cage card and tail tattoo | Same as 3-month studies
Mice: Cage card and tail tattoo
Diet
Irradiated NIH-07 wafer feed (rats; perinatal phase) or irradiated NTP-2000 wafer feed (rats and mice; 3-month studies) (Zeigler Brothers Inc., Gardners, PA), available ad libitum, changed weekly | Same as 3-month studies
Water
Tap water (Columbus municipal supply), deionized, either untreated or containing a formulation of ST via glass bottles (Wheaton Science Products, Millville, NJ [rats and female mice] or Supelco, Bellefonte, PA [male mice]), available ad libitum, changed twice weekly | Tap water (Columbus municipal supply), deionized, either untreated or containing a formulation of ST via glass bottles (Fisher Scientific, Pittsburgh, PA [rats], Qorpak, Bridgeville, PA [female mice], or VWR, West Chester, PA [male mice]), available ad libitum, changed twice weekly (rats and female mice) or once weekly (male mice)
Cages
Solid polycarbonate (Lab Products, Inc., Seaford, DE) Rats: changed weekly through PND 4, then twice weekly, rotated every 2 weeks | Same as 3-month studies
Mice: Changed weekly (males) or twice weekly (females), rotated every 2 weeks
Bedding
Irradiated Sani-Chips^®^ (P.J. Murphy Forest Products Corporation, Montville, NJ), changed with cage changes | Same as 3-month studies
Rack Filters
Spun-bonded polyester (Snow Filtration Company, Cincinnati, OH), changed every 2 weeks | Same as 3-month studies
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed and rotated every 2 weeks | Same as 3-month studies
Animal Room Environment
Temperature: 72°F ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Same as 3-month studies
Exposure Concentrations
0, 125, 250, 500, 1,000, or 2,000 mg/L | Rats: 0, 250, 500, or 1,000 mg/L
| Mice: 0, 500, 1,000, or 2,000 mg/L
Type and Frequency of Observation
F_0_ female rats: Observed twice daily. Weighed on GDs 5, 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 14, and 21. Water consumption was measured over 3-day intervals from GD 6 through LD 21. F_1_ rats: Observed twice daily. Litter data (total litter weight, litter weights by sex, and litter observations) were recorded on PND 1. Pup survival was evaluated and recorded. Individual pups were weighed on PNDs 4, 7, 14, and 21, weekly for 3 months, and at the end of the study. Clinical observations were recorded weekly and at the end of the study. Water consumption was recorded weekly for the duration of the study. | F_0_ female rats: Observed twice daily. Weighed on GDs 2, 5, 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 10, 14, 17, and 21. Water consumption was measured over 3-day intervals from GD 6 through LD 21. F_1_ rats: Observed twice daily. Litter data (total litter weight, litter weights by sex, and litter observations) were recorded on PND 1. Pups per litter were recorded on PNDs 2 and 3. Pups were weighed on PNDs 4, 7, 10, 14, and 21, weekly for 3 months, then every 4 weeks, and at the end of the study. Clinical observations were recorded every 4 weeks beginning at week 6 and at the end of the study. Water consumption was recorded initially, weekly for 3 months, and then at 4-week intervals thereafter.
Mice: Observed twice daily. Weighed initially, weekly for 3 months, and at the end of the study. Clinical observations were recorded weekly and at the end of the study. Water consumption was recorded weekly for the duration of the study. | Mice: Observed twice daily. Weighed initially, weekly for 3 months, then every 4 weeks, and at the end of the study. Clinical observations were recorded at week 6 then every 4 weeks and at the end of the study. Water consumption was measured initially, weekly for 3 months, and then at 4-week intervals thereafter.
Method of Euthanasia
Carbon dioxide | Same as 3-month studies
Necropsy
Necropsies were performed on all animals. Organs weighed at the end of the study were: liver, thymus, right kidney, right testis, heart, and lungs. | Necropsies were performed on all core animals. Organs collected and weighed at the 3-, 6-, 12-, and 18-month interim evaluations were: liver, left and right kidneys, stomach, small intestine, and bone (femur).
Clinical Pathology
At the end of the studies, blood was collected from the retroorbital plexus (rats) or sinus (mice) for clinical chemistry (rats only), hematology, and insulin determination (rats only). | None
Hematology: erythrocyte count, mean corpuscular volume, hemoglobin, hematocrit, mean corpuscular hemoglobin, mean corpuscular hemoglobin concentration, leukocyte count and differentials, reticulocyte count, and platelet count
Clinical chemistry (rats): alanine aminotransferase, albumin, alkaline phosphatase, bile acids, cholesterol, creatinine, creatine kinase, glucose, sorbitol dehydrogenase, total protein, triglycerides, and urea nitrogen
Histopathology
Complete histopathology was performed on all F_1_ rats and all mice in the vehicle control and 2,000 mg/L groups. The kidney was identified as a target organ and examined to a no-effect level. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart, kidney, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), larynx, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pharynx, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spinal cord, spleen, sternum, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, tongue, trachea, urinary bladder, uterus, vagina, and Zymbal’s gland. | Complete histopathology was performed on all core F_1_ rats and all core mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart, kidney, large intestine (cecum, colon, and rectum), small intestine (duodenum, jejunum, and ileum), liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, uterus (including cervix), and vagina.
Sperm Motility
At the end of the studies, sperm samples were collected from F_1_ male rats and male mice in the vehicle control, 500, 1,000, and 2,000 mg/L groups for sperm evaluations. The following parameters were evaluated: spermatid heads per testis and per gram testis, and epididymal spermatozoal motility and concentration. The left cauda, left epididymis, and left testis were weighed. | None
Urinalysis
During week 12, urine samples were collected from F_1_ rats in metabolism cages for urinalysis. | At the 3-, 6-, 12-, and 18-month interim evaluations, urine was collected from up to 10 predesignated rats/sex/exposure group in metabolism cages for urinalysis.
Parameters Evaluated (rats): specific gravity, volume, sediment exam, protein, glucose, creatinine, calcium, phosphorous, N-acetyl-β-glucosaminidase, alkaline phosphatase, and aspartate aminotransferase | Parameters Evaluated (rats): volume and creatinine
Xanthine and Methionine Analysis
At the end of the studies, urine samples were collected from all F_1_ rats for xanthine/methionine determination. | None
Internal Dose Assessment
At the end of the studies, urine (F_1_ rats) and blood (F_1_ rats, mice) samples were collected for tungsten determinations. | At the 3-, 6-, 12-, and 18-month interim evaluations, urine, plasma, and kidney were collected from up to 10 predesignated animals/sex/exposure group for tungsten determination. Tungsten concentrations were determined using validated analytical methods (Appendix E). On PND 21, tungsten concentrations were determined in plasma from dams (five/exposure group) and their pups (one male and one female from each selected dam’s litter).

GD = gestation day; LD = lactation day; PND = postnatal day.

Two diets were used in the rat studies: (1) NIH-07 during the perinatal phase, and (2) NTP-2000 during the postweaning phase. The NIH-07 diet is a higher protein diet that supports reproduction and lactation in rodents, whereas the NTP-2000 diet is a lower protein diet that decreases the incidence of chronic nephropathy in adult rats. Information on feed composition and contaminants for both diets is provided in Appendix B.

Because tungsten is capable of replacing molybdenum (Mo) in Mo-containing enzymes, NTP evaluated the enzyme activity of xanthine oxidase and sulfite oxidase in the liver, kidney, and intestine. Also, because tungsten has been shown to accumulate in femurs of rats and mice after repeated oral gavage administration, urinary calcium and phosphorus concentrations were measured. Other endpoints in the urine, including acetyl glucosaminidase, alkaline phosphatase, and aspartate aminotransferase activities, were also measured.

Urine and blood were also analyzed for tungsten concentrations using validated analytical methods as described in Appendix E.

### Study Design for Mice

Male and female B6C3F1/N mice were 4 to 5 weeks old upon receipt and were quarantined for 11 days before study start. Mice were randomly assigned to one of six exposure groups (n = 10 mice/sex/group). Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Cedar Knolls, NJ). Mice were provided ST in drinking water for 3 months at one of five exposure concentrations (125, 250, 500, 1,000, or 2,000 mg/L) or were provided the vehicle control (deionized water).

Five male and five female mice were randomly selected for parasite evaluation and gross observation of disease. The health of the mice was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Mice were housed individually (males) or five per cage (females). Feed and dosed water were available ad libitum. Water consumption was measured weekly for 3 months. Cages were changed at least once weekly (males) or twice weekly (females) and rotated every 2 weeks. Racks were changed and rotated every 2 weeks. Further details of animal maintenance are in Table 1. Information on feed composition and contaminants is given in Appendix B.

### Clinical Examinations and Pathology

In the 3-month studies in rats and mice, animals were observed twice daily for signs of morbidity and moribundity and were weighed before dosed water administration on day 1, weekly for 3 months, and at study termination. Clinical observations were recorded weekly and at study termination. Water consumption was recorded weekly throughout the study.

At week 12, all F_1_ rats were placed in metabolism cages and urine samples were collected during a 16-hour overnight period for urinalysis. Rats were fasted during the collection period and had access to untreated deionized water while in the metabolism cages. The parameters evaluated are listed in Table 1. Once all urine parameters had been determined, 1 mL of urine from each rat was designated for tungsten analysis, frozen at approximately −20°C, and shipped to Battelle Toxicology Northwest (Richland, WA) for analysis. From the remaining urine, a minimum of 1 mL was frozen at approximately −20°C for xanthine/methionine analysis.

Blood was collected from the retroorbital plexus (rats) or sinus (mice) at the end of the 3-month studies for hematology, clinical chemistry (rats only), erythrocyte micronuclei determination, tungsten determination, serum retention for insulin determination (rats only), and for the comet assay. Animals were anesthetized with a carbon dioxide/oxygen mixture and bled in a random order. Blood was collected into tubes containing ethylenediaminetetraacetic acid (EDTA) (for hematology, erythrocyte micronuclei, and tungsten determination/comet assay) or into serum separator tubes (for clinical chemistry). Hematology parameters were analyzed using an Advia^®^ 120 system (Bayer Diagnostics Division, Tarrytown, NY). Clinical chemistry parameters were analyzed using the Roche cobas c501 Chemistry Analyzer (Roche Diagnostics, Indianapolis, IN). The parameters measured are listed in Table 1. After evaluation of clinical chemistry parameters, the remaining rat serum was frozen at approximately −80°C and shipped to the NTP Frozen Tissue Bank (Durham, NC) for serum insulin analysis. Samples for erythrocyte micronuclei determination were stored at 2°C–8°C immediately after collection and shipped to Integrated Laboratory Systems, LLC (Durham, NC) for analysis. Samples for the comet assay were transferred to a cryogenic vial, frozen in liquid nitrogen, and stored at −80°C for at least 24 hours before shipment to Integrated Laboratory Systems, LLC (Durham, NC) for analysis. Remaining blood (not used for the comet assay) was designated for tungsten determination, frozen at approximately −80°C, and shipped to Battelle Toxicology Northwest (Richland, WA).

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations from F_1_ male and female rats and from male and female mice in the 0, 500, 1,000, and 2,000 mg/L groups. The parameters evaluated are listed in Table 1. Due to inconsistent sample collection and slide staining, an assessment of estrous cyclicity could not be made for F_1_ female rats or female mice. Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides, and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. After completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was determined microscopically with the aid of a hemocytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemocytometer.

Necropsies were performed on all rats and mice at the end of the 3-month study. Organ weights were recorded for the liver, thymus, right kidney, right testis, heart, and lungs. Tissue samples of 3–5 mm were collected from the left lateral liver lobe, ileum, and a longitudinal section of the left kidney for the comet assay. These samples were transferred to cryogenic vials, frozen in liquid nitrogen, and stored at −80°C for at least 24 hours before shipment to Integrated Laboratory Systems, LLC (Durham, NC) for analysis. Tissues for microscopic examination were fixed in 10% neutral buffered formalin (except eyes, which were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides, which were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 μm, and stained with hematoxylin and eosin (H&E). Complete histopathological examinations were performed by the study laboratory pathologist on all organs with gross lesions and on all vehicle control and 2,000 mg/L rats and mice. The kidney was identified as a target organ and examined to a no-effect level. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to an NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer-review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^37^ and Boorman et al.^38^

## Two-year Studies

### Study Design for Rats

F_0_ female rats were 11 to 14 weeks old upon receipt. GD 1 was defined as the first day with evidence of mating. F_0_ females were received on GD 2 and held for 4 days. F_0_ females were randomly assigned to one of four exposure groups on GD 5. Forty-seven females were assigned to the 0 mg/L group, whereas 41 females were assigned to each of the 250, 500, and 1,000 mg/L groups. Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Cedar Knolls, NJ).

F_0_ females were quarantined for 23 days after receipt. Nonmated females designated for disease monitoring and gross necropsies were not received, and therefore 10 undelivered dams were used instead for disease monitoring and gross necropsies on GD 25; samples were collected for the presence of disease or parasites. The health of the F_1_ animals was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). Pinworms (Syphacia spp.) were diagnosed in sentinel animals during routine health monitoring evaluations. Infected animals did not display clinical signs, and no pathological lesions were noted in relation to the presence of the pinworms. Study animals did not receive medication for potential pinworm infection. In accordance with this finding, NTP, in coordination with the testing laboratory, developed and implemented a successful plan of pinworm containment and eradication. NTP required the testing laboratories to actively monitor animals to ensure the continued exclusion of pinworms from all studies going forward. All other test results were negative.

Beginning on GD 6, F_0_ females were provided ST in drinking water throughout gestation and lactation at one of four exposure concentrations (0, 250, 500, or 1,000 mg/L); deionized water served as the vehicle control. Groups of 50 F_1_ rats/sex/exposure group continued on in the study after weaning and were provided drinking water containing the same respective ST concentration as their dam for 2 years. An additional 40 F_1_ rats/sex/exposure group were used for interim evaluations and provided dosed drinking water for 3, 6, 12, and 18 months.

F_0_ female rats were housed individually during gestation and with their respective litters during lactation. Feed and dosed water were available ad libitum. Dam body weights were recorded on GDs 2, 5, 6, 9, 12, 15, 18, and 21 and on LDs 1, 4, 7, 10, 14, 17, and 21. During gestation, water consumption was continuously measured over 3-day intervals from GD 6 through GD 21 (GDs 6–9, 9–12, 12–15, 15–18, and 18–21). The day of parturition was considered to be PND 0. On apparent GD 25, all time-mated females that failed to deliver were euthanized and the uteri were examined and stained for evidence of implantation. Total litter weight and litter weights by sex were collected on PND 1. Individual pup weights were recorded on PNDs 4, 7, 10, 14, and 21. Clinical observations and survival were evaluated throughout lactation. During lactation, water consumption was measured over 3-day intervals from PND 1 through PND 21 (PNDs 1–4, 4–7, 7–10, 10–14, 14–17, 17–21).

F_1_ litters were standardized on PND 4 to eight pups per litter, with at least two pups of each sex and a preference for four males and four females each. Litters that did not meet the minimum of eight pups (or if they had fewer than two pups of either sex) were removed from the study. Before weaning, pups (generally two/sex/litter) were randomly assigned to the 2-year study. After assignments to the 2-year study were complete, five pups per sex from the remaining vehicle control pups were randomly selected as the sentinel animals. On the day the last litter reached PND 21, dams were removed, and the pups were weaned. Weaning marked the beginning of the 2-year study.

On the morning of the final PND 21, randomly selected dams (five/exposure group) and one male and one female pup from each selected dam’s litter were used for biological sample collection. Blood was collected via cardiac puncture into tubes containing EDTA, the tubes were centrifuged, and the resulting plasma was harvested and stored at −85°C to −60°C until transferred for tungsten analysis.

F_1_ rats were housed up to two (males) or five (females) per cage. Feed and dosed water were available ad libitum. Water consumption was measured at the beginning of the study, weekly for 13 weeks, and then at 4-week intervals thereafter. Cages were changed weekly though PND 4, then changed twice weekly. Racks were changed and rotated at least every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is provided in Appendix B.

### Study Design for Mice

Male and female B6C3F1/N mice were 3 to 4 weeks old upon receipt and were quarantined for 11 days before study start. Mice were randomly assigned to one of four groups (n = 50 mice/sex/exposure group). Mice were provided ST in drinking water for 2 years at one of three exposure concentrations (500, 1,000, or 2,000 mg/L) or were given the vehicle control (deionized water). An additional 40 mice/sex/exposure group were included for interim evaluations at 3, 6, 12, and 18 months. Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM software (Xybion Medical Systems Corporation, Cedar Knolls, NJ).

Before study start, five male and five female mice were randomly selected for parasite evaluation and gross observation of disease. The health of the mice was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All test results were negative.

Mice were housed individually (males) or four (females) per cage. Feed and dosed water were available ad libitum. Water consumption was measured at the beginning of the study, weekly for 13 weeks, and then at 4-week intervals thereafter. Cages were changed at least once weekly (males) or twice weekly (females) and rotated every 2 weeks. Racks were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 1. Information on feed composition and contaminants is given in Appendix B.

### Clinical Examinations, Tungsten Concentrations, and Pathology

In the 2-year studies in rats and mice, animals were observed twice daily for signs of morbidity and moribundity and were weighed before dosed water administration on day 1, weekly for the next 13 weeks, every 4 weeks thereafter, and at study termination. Clinical observations were recorded every 4 weeks beginning on day 36 and at study termination. Water consumption was recorded at the beginning of the study, weekly for 13 weeks, and at 4-week intervals thereafter.

At the 3-, 6-, 12-, and 18-month interim evaluations, urine, feces, blood, and tissues (liver, kidneys, stomach, small intestine, and bone) were collected from up to 10 predesignated F_1_ rats/sex/exposure group and up to 10 predesignated mice/sex/exposure group for determination of tungsten concentrations. Organ weights were recorded for selected tissues. Early death animals were not replaced. On the morning of the day before scheduled blood collection, animals were moved to metabolism cages (one animal/cage); while in the metabolism cages, the animals had ad libitum access to feed and their assigned concentration of dosed drinking water. Urine and feces were collected over a 24-hour period, and urine volume, urine creatinine, and fecal weights were recorded. Blood was collected via cardiac puncture into tubes containing K_3_ EDTA, centrifuged, and the plasma harvested. Immediately after blood collection, the animals were euthanized and the entire liver, both kidneys, stomach (separated into glandular and non-glandular), small intestine, and both femurs were collected, weighed, and maintained on dry ice until moved into storage. All samples were stored at −85°C to −60°C until transferred for analysis.

Complete necropsies and microscopic examinations were performed on all F_1_ rats and all mice at the end of the 2-year studies. At necropsy, all organs and tissues were examined for grossly visible lesions and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes, which were first fixed in Davidson’s solution, and testes, vaginal tunics, and epididymides, which were first fixed in modified Davidson’s solution). Tissues were processed and trimmed, embedded in paraffin, sectioned at a thickness of 4 to 6 μm, and stained with H&E for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. In the original evaluation of the uterus, a transverse section through each uterine horn, approximately 0.5 cm cranial to cervix, was collected for histopathology evaluation. For the residual tissue evaluation of the uterus, all remaining uterine tissue, including the cervix and vaginal tissue, was sectioned longitudinally, processed, and examined histologically. Results from the residual uterine evaluation were combined with those from the original, transverse section of uterus. Tissues examined microscopically are listed in Table 1.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by an independent QA laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all neoplasms and all potential target organs, which included the kidney of rats and mice; the liver of male rats and male mice; the uterus of female rats and female mice; the cecum of mice; the adrenal cortex and mandibular lymph node of male rats; the testis and epididymis of male mice; the ovary and nose of female rats; and the spleen and mesenteric lymph node of female mice.

The QA report and the reviewed slides were submitted to the NTP pathologist, who reviewed and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologist. The QA pathologist, who served as the coordinator of the Pathology Working Group (PWG) presented representative histopathology slides containing examples of lesions related to test agent administration, examples of disagreements in diagnoses between the laboratory and QA pathologist, or lesions of general interest to the PWG for review. The PWG consisted of the NTP pathologist and other pathologists experienced in rodent toxicological pathology. When the PWG consensus differed from the opinion of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, QA pathologist, and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^37^ and Boorman et al.^39^ or subsequent analyses of the pathology data; the decision of whether to evaluate the diagnosed lesions for each tissue type separately or combined was generally based on the guidelines of Brix et al.^40^

In addition to the routine pathology review, a step section analysis of the kidneys from the chronic mouse study was performed. Paraffin-embedded kidneys were sectioned at 1 mm intervals to obtain three to four additional sections per kidney to allow for the observation of additional renal neoplasms. The evaluation of these additional kidney slides was conducted by a board-certified pathologist other than the QA pathologist. The step section pathologist shared the evaluation findings with the NTP pathologist and the QA pathologist. Representative slides from the kidney step section review were taken to the PWG for the chronic ST mouse study and were examined by the members of that PWG. The final diagnosis of the kidney step section review constitutes a consensus of the kidney step section pathologist, the NTP pathologist, and the PWG participants.

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^41^ and is presented graphically. Animals surviving to the end of the observation period are treated as censored observations, as are animals dying from unnatural causes within the observation period. Animals dying from natural causes are included in analyses and are treated as uncensored observations. For the 2-year mouse study, exposure concentration-related trends are identified with Tarone’s life-table test,^42^ and pairwise exposure concentration-related effects are assessed using Cox’s method.^43^ For the rat perinatal study, exposure concentration-related trends and pairwise exposure concentration-related effects on survival are assessed using a Cox proportional hazards model^43^ with a random litter effect. All reported p values for the survival analyses are two-sided.

### Calculation of Incidence

The incidences of neoplasms or nonneoplastic lesions are presented as the numbers of animals bearing such lesions at a specific anatomical site. For calculation of incidence rates, the denominator for most neoplasms and all nonneoplastic lesions is the number of animals where the site was examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominator consists of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominator consists of the number of animals on which a necropsy was performed. Additional study data also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below) accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidence

Statistical analyses of neoplasm and nonneoplastic lesion incidence considered two features of the data. Some animals did not survive the entire 2 years of the study, so survival differences between groups had to be considered. Also, for the rat study, up to two animals per sex were randomly selected from each rat litter to participate in the study. The statistical analysis of lesion incidence used the Poly-3 test to account for survival differences, with a Rao-Scott adjustment for litter effects as needed. This analysis is described below.

The Poly-k test^44-46^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to account for survival differences. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is 1 if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died before terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only on the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^44^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^44^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control Fischer 344 rats and B6C3F1 mice.^47^ Bailer and Portier^44^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^48^ Poly-3 tests used the continuity correction described by Nam.^49^

Littermates tend to be more like each other than fetuses/pups in other litters. Failure to account for correlation within litters leads to underestimates of variance in statistical tests, resulting in higher probabilities of Type I errors (“false positives”). Because up to two pups/sex/litter were present in the core rat study, the Poly-3 test was modified to accommodate litter effects using the Rao-Scott approach.^50^ The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Poly-3 test as recommended by Fung et al.,^51^ formula ₸_RS2_.

Tests of significance included pairwise comparisons of each exposure group with control groups and a test for an overall exposure concentration-related trend. Continuity-corrected Rao-Scott-adjusted Poly-3 tests were used in the analysis of lesion incidence and reported p values are one-sided. The significance of a lower incidence or negative trend in lesions is approximated as 1−p with the letter N added (e.g., p = 0.99 is presented as p = 0.01N). For neoplasms and nonneoplastic lesions observed without litter structure (e.g., for the mouse studies), Poly-3 tests that included the continuity correction, but without adjustment for potential litter effects, were used for trend and pairwise comparisons to the control group.

To evaluate incidence rates by litter, the proportions of litters affected by each lesion type were tested among groups. Cochran-Armitage trend tests and Fisher’s exact tests^52^ were used to test for trends and pairwise differences from the control group, respectively.

### Analysis of Continuous Variables

Before statistical analysis, extreme values identified by the outlier test of Dixon and Massey^53^ for small samples (n < 20) and Tukey’s outer fences method^54^ for large samples (n ≥ 20) were examined by NTP personnel, and implausible values were eliminated from the analysis.

For the perinatal and 2-year study in rats and the 3-month and 2-year studies in mice, litter effects were not considered in the analysis of the continuous data. Organ and body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^55^ and Williams.^56,57^ Dam gestational and lactational feed consumption, litter sizes, pup survival, implantations, number of resorptions, and proportions of male pups per litter for all rat studies were analyzed using the nonparametric multiple comparison methods of Shirley^58^ (as modified by Williams^59^ and Dunn^60^) given that these endpoints typically have skewed distributions. For all quantitative endpoints unaffected by litter structure, the Jonckheere test^61^ was used to assess the significance of the exposure concentration-related trends and to determine, at the 0.01 level of significance, whether a trend-sensitive test (the Williams or Shirley test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic exposure concentration-related trend (the Dunnett or Dunn test).

For the perinatal and 3-month study in rats, there were two or more littermates in each exposure group analyzed. Consequently, organ and body weight endpoints were analyzed using linear mixed models, with litter as a random effect. To adjust for multiple comparisons, a Dunnett-Hsu adjustment was used.^62^ For other endpoints, for which normality was not assumed, the trend across exposure groups was analyzed by a permutation test based on the Jonckheere trend test implemented by randomly permuting whole litters across exposure groups and bootstrapping within the litters (see, for example, Davison and Hinckley^63^). Pairwise comparisons were made by using a modified Wilcoxon test that incorporated litter effects.^64^ The Hommel procedure was used to adjust for multiple comparisons.^65^

Postweaning body weights were measured on two pups/sex/litter in the perinatal and 2-year and perinatal and 3-month rat studies; more than two pups/sex/litter were possible in preweaning body weight measurements. The analyses of pup body weights and body weights adjusted for litter size (described below) took litter effects into account using a mixed model with litter as random effect. To adjust for multiple comparisons, a Dunnett-Hsu adjustment was used.^62^ Dam body weights during gestation and lactation were analyzed with the parametric multiple comparison procedures of Dunnett^55^ or Williams,^56,57^ depending on whether the Jonckheere test indicated the use of a trend-sensitive test. P values for these analyses are two-sided.

### Analysis of Gestational and Fertility Indices

Cochran-Armitage trend tests were used to test the significance of trends in gestational and fertility data across exposure groups. Fisher’s exact test was used to conduct pairwise comparisons of each exposure group with the control group. P values for these analyses are two-sided.

### Body Weight Adjustments

To adjust preweaning pup body weights for live litter size, a linear model was fit to body weights as a function of exposure concentration and litter size. The estimated coefficient of litter size was then used to adjust each pup body weight based on the difference between its litter size and the mean litter size. Prestandardization PND 4 body weights were adjusted for PND 1 litter size, and body weights measured between PND 4 poststandardization and PND 21 were adjusted for PND 4 poststandardization litter size. After adjustment, body weights were analyzed with a linear mixed model with a random litter effect.

### Historical Control Data

The concurrent control group is the most valid comparison to the exposed groups and is the only control group analyzed statistically in NTP bioassays. Historical control data are often helpful in interpreting potential exposure-related effects, however, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control data must be generally similar. Significant factors affecting the background incidence of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathological findings in control animals completed within the most recent 5-year period^66-68^ including the concurrent control for comparison across multiple technical reports. In general, the historical control data for a given study includes studies using the same route of administration, and the overall incidence of neoplasms in control groups for all routes of administration are included for comparison, including the current study.

## Quality Assurance Methods

The 3-month and 2-year studies were conducted in compliance with U.S. Food and Drug Administration Good Laboratory Practice Regulations.^69^ In addition, the 3-month and 2-year study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.

## Genetic Toxicology

The genetic toxicity of ST was assessed by testing the ability of the chemical to induce mutations in various strains of Salmonella typhimurium and Escherichia coli, to increase the frequency of micronucleated erythrocytes in rat and mouse peripheral blood, and to increase DNA damage in cells from liver, kidney, ileum, and peripheral blood from rats and mice. The protocols and results for these studies are given in Appendix D.

The genetic toxicity studies are an outcome of an earlier effort by NTP to develop a comprehensive database permitting a critical anticipation of a chemical’s carcinogenicity in experimental animals based on the results from several in vitro and in vivo short-term tests measuring functionally distinct genotoxicity endpoints. The short-term tests were originally developed to clarify proposed mechanisms of chemical-induced DNA damage on the basis of the relationship between electrophilicity and mutagenicity^70^ and the somatic mutation theory of cancer.^71,72^ It should be noted, however, that not all cancers arise through genotoxic mechanisms.

### Bacterial Mutagenicity

DNA reactivity combined with Salmonella mutagenicity is highly correlated with induction of carcinogenicity in multiple species/sexes of rodents and at multiple tissue sites.^73^ A positive response in the Salmonella test was shown to be the most predictive in vitro indicator for rodent carcinogenicity (89% of the Salmonella mutagens are rodent carcinogens).^74,75^ Additionally, no battery of tests that included the Salmonella test improved the predictivity of the Salmonella test alone; however, these other tests can provide useful information on the types of DNA and chromosomal damage induced by the chemical under investigation. The protocol for these studies and the results are given in Appendix D.

### Peripheral Blood Micronucleus Test

Micronuclei are biomarkers of induced structural or numerical chromosomal alterations and are formed when acentric fragments or whole chromosomes fail to incorporate into either of two daughter nuclei during cell division.^76,77^ The predictivity for carcinogenicity of a positive response in acute in vivo bone marrow chromosome aberration or micronucleus tests appears to be less than that of the Salmonella test.^78,79^ However, clearly positive results in long-term peripheral blood micronucleus tests have high predictivity for rodent carcinogenicity; a weak response in one sex only or negative results in both sexes in this assay do not correlate well with either negative or positive results in rodent carcinogenicity studies.^80^ Because of the theoretical and observed associations between induced genetic damage and adverse effects in somatic and germ cells, the determination of in vivo genetic effects is important to the overall understanding of the risks associated with exposure to a particular chemical. The protocol for these studies and the results are given in Appendix D.

### Comet Assay

The alkaline (pH > 13) comet assay^81^ (also known as the single cell gel electrophoresis assay) detects DNA damage in any of a variety of eukaryotic cell types^82-85^; cell division is not required. The type of DNA damage detected includes nicks, adducts, strand breaks, and abasic sites that are converted to DNA strand breaks after treatment of cells in an alkaline (pH > 13) solution. Transient DNA strand breaks generated by the process of DNA excision repair might also be detected. DNA damage caused by crosslinking agents has been detected as a reduction of DNA migration.^86,87^ The fate of the DNA damage detected by the comet assay is varied; most of the damage is rapidly repaired and results in no sustained effect on the tissue, but some might result in cell death or be incorrectly processed by repair proteins and lead to a fixed mutation or chromosomal alteration. The protocol for these studies and the results are given in Appendix D.

In the rat study, ileum (male rats) and kidney (male and female rats) samples were tested in the comet assay, but due to inconsistencies of the results, the assay was deemed an invalid test for these samples.