# Introduction

Figure 1

Sodium Tungstate Dihydrate (CASRN 10213-10-2; Chemical Formula: Na_2_WO_4_ • 2H_2_O; Molecular Weight: 329.86)

Synonyms: Tungstic acid sodium salt dihydrate.

## Chemical and Physical Properties

Tungsten, also called wolfram, is a steel-gray to tin-white metal with a high melting point and good electrical conductivity. Along with chromium and molybdenum (Mo), it is in group VI of the periodic table. It can replace Mo in Mo-containing enzymes,^1,2^ such as aldehyde oxidase, sulfite oxidase,^3^ and xanthine oxidase,^4^ and renders the enzymes inactive. Sodium tungstate dihydrate (ST) is a chemical intermediate for tungsten and tungsten compounds.^5^ ST has high solubility in water and is not volatile. It effloresces in dry air and loses its water at 100°C. As an aqueous solution, it is slightly alkaline (pH 8–9). When heated to decomposition, it emits toxic fumes of sodium oxide.

## Production, Use, and Human Exposure

Tungsten and its salts are present naturally in the environment and can enter waterways through the weathering of rocks and soils.^6^ Atmospheric tungsten-containing particulates eventually settle to the earth's surface by dry deposition or can be removed from the atmosphere by wet deposition (i.e., precipitation). Upon reaching water and soil, tungsten will be in either soluble (e.g., tungstate ion, WO_4_^2-^) or insoluble forms (e.g., tungsten trioxide) in sediment and soil. Environmental exposure to ST by the general public occurs mainly through contaminated drinking water. For example, tungsten has been detected in the municipal water of Fallon, Nevada. However, the amount of tungsten in drinking water is generally not known.^6^

ST is a high-production volume compound and is produced for industrial purposes by the reaction of a mixture of soft and hard tungsten carbide when combined with a mixture of sodium nitrate and sodium hydroxide in a fusion process. ST is used in a variety of commercial applications including fire- and waterproofing fabrics, in the preparation of complex compounds (e.g., phosphotungstate and silicotungstate), as a reagent for biological products, and as a precipitant for alkaloids. Occupational exposure can occur through inhalation of dusts and dermal contact during the production or use of tungsten-containing compounds.^6,7^

Clinically, ST is used as an antidiabetic agent to improve pancreatic function through a combination of hyperglycemia-independent pathways and by its own direct and indirect effects^8,9^; it is also used to treat infertility in people with diabetes.^10^

## Regulatory Status

The American Conference of Governmental Industrial Hygienists limits for tungsten and its soluble compounds include a time-weighted average (TWA) air concentration of 1 mg/m^3^ and a short-term exposure limit (STEL) of 3 mg/m^3^. The National Institute for Occupational Safety and Health (NIOSH) recommends a 10-hour TWA air concentration of 1 mg/m^3^ for tungsten and its soluble compounds. When developing a final rule, the Occupational Safety and Health Administration (OSHA) proposed an 8-hour TWA permissible exposure limit of 1 mg/m^3^ and a 15-minute STEL of 3 mg/m^3^ for tungsten. NIOSH concurred with OSHA’s addition of the STEL, and therefore the final rule established limits for tungsten and its soluble compounds of 1 mg/m^3^ as an 8-hour TWA and 3 mg/m^3^ as a 15-minute STEL, measured as tungsten.^11^ No federal drinking water standard or ambient water quality criterion have been established for tungsten.^12^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

The National Toxicology Program (NTP) previously evaluated the disposition of tungsten (administered as ST) in female Sprague Dawley rats or C57BL/6N mice.^13,14^ Following a single gavage administration of 1, 10, or 100 mg ST/kg body weight (mg/kg), animals were euthanized 1, 2, 4, and 24 hours postadministration.^13^ Plasma, liver, kidney, femur, and uterus concentrations of tungsten increased with increasing dose in both species, with higher tissue concentrations relative to plasma at each respective time point. Tissue concentrations were generally higher in rats relative to mice, with some variation by tissue and time point. In general, tungsten concentrations peaked approximately 4 hours postadministration in rats and 1–4 hours postadministration in mice; concentrations then decreased over time with values approaching background/endogenous concentrations detected in the study (0.04–0.15 μg/g, depending on the matrix) by 24 hours postadministration. After a single intravenous administration of ST at 1 mg/kg in rats and mice, concentrations of tungsten peaked at approximately 1 hour postadministration and steadily decreased through 24 hours postadministration.^13^

After 14 days of gavage administration of ST to rats and mice (10 mg/kg; animals necropsied 24 hours after the last administration), tungsten concentrations in plasma, liver, kidney, femur, and uterus were either similar to or slightly higher than those in animals receiving a single administration of a similar dose and necropsied 24 hours postadministration; this observation suggests minimal accumulation of tungsten following repeat gavage dosing in rats and mice.^14^ After exposure via drinking water for 14 days (560 mg/L; dosed water offered until study termination) in rats and mice, tungsten was detected in plasma and tissues; however, a direct comparison between repeat gavage dosing and drinking water exposure cannot be established due to the differences in the time of necropsy after the last exposure. In pregnant rats and mice, following a similar drinking water exposure paradigm, tungsten was also detected in the fetus, which demonstrated gestational transfer.^14^

### Humans

Studies of human exposure to tungsten compounds are limited. The daily dietary intake of tungsten is about 0.01 mg (0.05 μmol), whereas the median for daily urinary excretion is 0.007 mg (0.04 μmol).^15^ Tungsten (VI) is well absorbed, and approximately 75% of the amount ingested is excreted in the urine.^16^ In a limited study with no specific exposure, four healthy young adults eliminated trace quantities of tungsten in urine (2.0–13.0 μg [0.01–0.07 μmol]) and feces (1.6–5.7 μg [8.7–31 nmol]) over 24-hour periods.^17^

## Toxicity

### Experimental Animals

Acute toxicity values (i.e., median lethal dose [LD_50_]) for ST range from 240 to 1,904.1 mg/kg in mice and from 1,904 to 1,928 mg/kg in rats.^18,19^ Acute oral or intravenous administration of ST in mice and rats decreased motor activity and muscle tone, and the animals exhibited ataxia, palpebral ptosis, hunched back, pallor, prostration, and dyspnea.^19^

In a relatively recent study, the subchronic toxicity of an aqueous ST solution in male and female Sprague Dawley rats was evaluated following daily administration via oral gavage to 0, 10, 75, 125, or 200 mg ST/kg body weight/day (mg/kg/day) for 90 days.^20^ The kidney was noted as the main target organ of toxicity in both male and female rats dosed at 125 or 200 mg/kg/day, with mild to severe cortical tubule basophilia observed in those dose groups. In males, intraluminal hypospermia with cell debris was observed in the epididymis after administration of 200 mg/kg/day. In both sexes, histopathological changes were observed in the glandular stomach and included inflammation and metaplasia in the high-dose rats (125 and 200 mg/kg/day). The histopathological effects seen in the kidneys indicate that the lowest-observed-adverse-effect level from this study was 125 mg/kg/day and the no-observed-adverse-effect level was 75 mg/kg/day in both sexes of rats for oral subchronic toxicity. There was a significant decrease in feed consumption and body weight gain in males at 200 mg/kg/day from days 77 to 90; however, there was no effect on feed consumption and body weight in females. There were no changes in the hematological or clinical parameters in this study. Histopathological changes were seen in the kidney of male and female rats and in the epididymis of male rats.

In an older study, ST (equivalent to 2% tungsten) administered via the diet to young rats caused the death of all animals within 10 days.^17,21^ When dietary concentrations were reduced to an equivalent of 0.5% tungsten, death occurred in 75% of rats by the end of the 70-day exposure period. When given by gavage or in drinking water to young rats, ST (15–1,000 mg/kg/day [0.051–3.403 mmol/kg/day]) for 4 or 13 weeks produced emesis, anorexia, cachexia, pallor, and dyspnea.^22,23^ At the highest dose, concentrations of urea, creatinine, and total cholesterol were increased, whereas erythrocyte count, glucose, aspartate aminotransferase/alanine aminotransferase, protein, hematocrit, and hemoglobin levels were decreased. All parameter values returned to normal after a recovery period of 6 weeks. Another study in male rats noted effects on spermatogenesis after inhalation exposure to ST (504 μg/m^3^ [41.9 ppb]) for 24 hours per day for 17 weeks.^24^

In a 28-day study of B6C3F1/N mice exposed to ST via drinking water at concentrations of 125–2,000 mg/L, NTP found limited effects on humoral and innate immunity, on developing hematopoietic cells in the bone marrow, and on unstimulated splenocyte phenotypes. These data indicated that, under conditions of co-exposure to an immune-stimulating agent, such as tumor cells or genetically dissimilar leukocytes, ST may modulate the normal cell-mediated immune response.^25^

Chronic oral exposure to 5 ppm ST in drinking water has been shown to significantly reduce longevity in male Long-Evans rats.^26^ In male Wistar rats, daily gavage administration of <150 mg/kg for up to 300 days produced no significant effects on body weights, organ weights, or survival.^27^

### Humans

The data implicating ST as toxic, hazardous, or carcinogenic in humans are limited, although tungsten poisoning has been reported following continuous occupational exposure to dusts and vapors during the refining of tungsten metal.^28^

## Reproductive and Developmental Toxicity

### Experimental Animals

Although some reproductive and teratological effects have been previously reported in rats and mice exposed to tungsten, those studies are not well characterized. In mice, a single dose of ST (concentration not specified) provided to dams at early fetal organogenesis was shown to produce a high frequency of resorptions but did not induce any fetal malformations.^29^ In pregnant rats, doses that did not produce maternal toxicity increased embryo lethality and inhibited bone ossification in fetuses.^30^ Another study evaluated the reproductive and neurobehavioral effects of ST in Sprague Dawley rats after 70 days of gavage administration with 0, 5, 62.5, or 125 mg/kg/day starting prior to mating and continuing through gestation and weaning (postnatal day 20). The perinatally exposed offspring showed subtle neurobehavioral effects related to motor activity and emotionality.^31^

### Humans

The literature contains no studies about reproductive or developmental toxicity in humans following exposure to tungsten or tungsten compounds.

## Carcinogenicity

The literature contains no carcinogenicity studies of ST in experimental animals or epidemiology studies in humans.

## Genetic Toxicity

Few reports have been published on the genotoxicity of ST. Of these reports, although ST did not induce gene mutations or chromosomal damage, it was capable of causing DNA damage in vivo. ST did not induce morphological transformation of Syrian hamster embryo (SHE) cells exposed in culture or in a host-mediated in vivo/in vitro assay in which cells from embryos excised from Syrian golden hamster dams administered 2.5 or 5 mg ST per 100 g maternal weight (intraperitoneal injection) were grown in a transformation assay.^32^ Chromosomal aberrations and sister chromatid exchanges were not induced in human lymphocytes or in SHE cells exposed to up to 10 μg/mL ST.^33^

In a series of industry-sponsored studies that followed OECD test guidelines, ST was evaluated in bacterial mutagenicity assays, two mammalian cell mutagenicity assays, and an in vivo micronucleus test.^34^ ST was negative in Salmonella typhimurium tester strains TA1535, TA1537, TA98, and TA100, and in Escherichia coli WP2 uvrA when tested up to 5,000 μg/plate in the absence or presence of induced rat liver S9 mix. Chromosomal aberrations were not induced in Chinese hamster ovary cells that were exposed to concentrations of up to 3,500 μg/ml ST for 3 hours (followed by 20 hours of culture) in the absence or presence of S9 mix, or for 20 hours in the absence of S9 mix, which were also up to a top concentration of 3,500 μg/ml ST. ST was negative in the L5178Y Tk^+/-^ mouse lymphoma forward mutation assay when cells were exposed to concentrations of up to 3,500 μg/ml ST for 4 hours in the absence or presence of S9 mix. Lastly, in a bone marrow micronucleus test, micronucleated polychromatic erythrocytes were not induced in male Crl:CD-1 mice exposed to a single dose of 250, 500, or 750 mg/kg ST via gavage at 24 hours after exposure.

A comet assay study revealed significant increases in DNA damage (reported as tail moment) in different types of bone marrow cells obtained from mice exposed to ST via drinking water.^35^ Significant increases in tail moment were observed in nonadherent bone marrow cells obtained from mice following exposure to 15 mg/L ST via drinking water for 1, 4, 12, or 16 weeks; 200 mg/L ST via drinking water for 1, 4, or 8 weeks; and 1,000 mg/L ST via drinking water for 4 or 12 weeks. Significant increases in tail moment were also reported for CD19^+^ B cells obtained from the bone marrow of mice exposed to 15 mg/L ST for 1 week or to 15 or 200 mg/L ST for 4 weeks.

## Study Rationale

Tungsten was nominated to NTP by the Centers for Disease Control and Prevention to evaluate its potential to cause chronic toxicity and carcinogenicity because of concern about potential human exposure via contaminated drinking water and inadequate data to assess human health implications of elevated exposures. ST was selected for study because tungstate (WO_4_^-2^) is the most naturally occurring form of soluble tungsten, and ST was the most water-soluble form of tungstate.

In the studies described in this Technical Report, drinking water was used as the route of exposure to mimic human exposure.