# Appendix G Supplemental Data

Tables with supplemental data can be found here: h[underlined: ttps://doi.org/10.22427/NTP-DATA-TR-599].^88^

## G.1 Perinatal and Three-month Study in Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Water and Compound Consumption Table

Gestational Body Weights (grams)

Gestational Water Consumption (grams)

Gestational and Lactational Chemical Consumption

Lactational Body Weights (grams)

Lactational Water Consumption (grams)

Litter Data by Dam – PND 1

Live Litter Size and Survival – PND 4 and 21

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA41 – Clinical Chemistry Summary

PA43 – Hematology Summary

PA44 – Urinalysis Summary

PA48 – Tissue Concentration Summary

PA48C – Tissue Concentration Curve

Pup Body Weights (grams)

R02 – Reproductive Performance Summary

R06 – Andrology Summary

R07 – Hormone Summary

## G.2 Perinatal and Three-month Study in Rats – Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Clinical Observations

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Andrology Data

Individual Animal Clinical Chemistry Data

Individual Animal DamID and PupID Data

Individual Animal Hematology Data

Individual Animal Hormone Data

Individual Animal Organ Weight Data

Individual Animal Reproductive Performance Data

Individual Animal Tissue Concentration Data

Individual Animal Urinalysis Data

## G.3 Three-month Study in Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Water and Compound Consumption Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA43 – Hematology Summary

PA48 – Tissue Concentration Summary

PA48C – Tissue Concentration Curve

R06 – Andrology Summary

## G.4 Three-month Study in Mice – Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Clinical Observations

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Andrology Data

Individual Animal Hematology Data

Individual Animal Organ Weight Data

Individual Animal Tissue Concentration Data

## G.5 Perinatal and Two-year Study in Rats

Analysis of PND 1 Litter Data

Analysis of PND 4 Live Litter Size and Survival

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves (Litter based)

E04 – Mean Body Weights and Survival (Litter based)

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Water and Compound Consumption Table

E12 – Animal History

I05 – Clinical Observations Summary

Litter Data Analysis of Gestational Body Weight

Litter Data Analysis of Gestational Water Consumption

Litter Data Analysis of Gestational/Lactational Chemical Consumption

Litter Data Analysis of Lactational Body Weight

Litter Data Analysis of Lactational Water Consumption

Litter Data Analysis of Pup Body Weights

Litter Data Analysis of Pup Body Weights (cont’d)

P02 – Incidence Rates of Neoplasms by Anatomic Site

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Litter Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weights Summary

PA48 – Summary of Tissue Concentration

PA48C – Tissue Concentration Curve

R02 – Reproductive Performance Summary

## G.6 Perinatal and Two-year Study in Rats – Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Clinical Observations

Female Individual Animal Neoplastic Pathology Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Female Pup Individual Animal Body Weight Data

Male Individual Animal Body Weight Data

Male Individual Animal Clinical Observations

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Male Pup Individual Animal Body Weight Data

Individual Animal Clinical Observations Data

Individual Animal DamID and PupID Data

Individual Animal Organ Weight Data

Individual Animal Reproductive Performance Data

Individual Animal Tissue Concentration Data

Individual Animal Urinalysis Data

Individual Pup Census and Litter Weight by Sex Data

## G.7 Two-year Study in Mice

E01 – Animal Removal Summary by Treatment Group

E02 – Animals Removed from Experiment

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

E07 – Mean Water Consumption by Treatment Group

E08 – Water and Compound Consumption Table

E12 – Animal History

P02 – Incidence Rates of Neoplasms by Anatomic Site

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P08 – Statistical Analysis of Primary Tumors

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P11 – Statistical Analysis of Survival Data

P14 – Individual Animal Pathology Data

P17 – Neoplasms by Individual Animal (Systemic Lesions Abridged)

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

PA06 – Organ Weight Summary

PA48 – Summary of Tissue Concentration

PA48C – Tissue Concentration Curve

## G.8 Two-year Study in Mice – Individual Animal Data

Female Individual Animal Body Weight Data

Female Individual Animal Clinical Observations

Female Individual Animal Neoplastic Pathology Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Survival Data

Female Individual Animal Terminal Body Weight Data

Male Individual Animal Body Weight Data

Male Individual Animal Clinical Observations

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Individual Animal Organ Weight Data

Individual Animal Tissue Concentration Data

Individual Animal Urinalysis Data

## G.9 Genetic Toxicology

### G.9.1 In Vivo Peripheral Blood Micronucleus Study G03038B in Mice

G03038B G04 In Vivo Micronucleus Summary Data

G03038B Individual Animal In Vivo Micronucleus Data

### G.9.2 In Vivo Peripheral Blood Micronucleus Study G03038C in Rats

G03038C G04 In Vivo Micronucleus Summary Data

G03038C Individual Animal In Vivo Micronucleus Data

### G.9.3 Salmonella/Escherichia coli Mutagenicity Test or Ames Test Study G03038D

G03038D G06 Ames Summary Data

### G.9.4 DNA Damage Study G03038E in Mice

G01 – In Vivo Alkaline Comet Summary Data

Individual Animal In Vivo Alkaline Comet Data

### G.9.5 DNA Damage Study G03038F in Rats

G01 – In Vivo Alkaline Comet Summary Data

Individual Animal In Vivo Alkaline Comet Data