# Appendix E Tungsten Concentration Determination

## E.1 Sample Collection

### E.1.1 Three-month Studies

#### E.1.1.1 Urine

At week 12, all F_1_ rats were removed from exposure and placed in individual metabolism cages to allow for collection of urine. Rats were fasted during the collection period and had access to untreated water ad libitum. Urine samples were collected on wet ice, overnight, for approximately 16 hours. Urine samples (1 mL from each rat) were frozen at −20°C and shipped to the analytical laboratory (Battelle Toxicology Northwest, Richland, WA).

#### E.1.1.2 Blood

At study termination, rats and mice were anesthetized with a CO_2_/O_2_ mixture, and blood was collected from the retroorbital plexus (rats) or sinus (mice) into heparinized centrifuge tubes containing ethylenediaminetetraacetic acid (EDTA). Blood samples were frozen at −80°C and shipped to Battelle Toxicology Northwest (Richland, WA).

### E.1.2 Two-year Studies (Interim Evaluations)

At the beginning of the 2-year study, groups of 40 interim study male and female rats and mice were randomly assigned to the tissue distribution study and exposed identically to the core study groups.

At the 3-, 6-, 12-, and 18-month interim evaluations, urine, feces, blood, and tissues (liver, kidneys, stomach, small intestine, and bone) were collected from up to 10 predesignated F_1_ rats/sex/exposure group and up to 10 predesignated mice/sex/exposure group. Early death animals were not replaced. On the morning of the day before scheduled blood collection, animals were moved to metabolism cages (one animal/cage); while in the metabolism cages, the animals had ad libitum access to feed and their assigned concentration of dosed drinking water. Urine and feces were collected over a 24-hour period. Blood was collected via cardiac puncture into tubes containing K_3_ EDTA, centrifuged, and the plasma harvested. Immediately after blood collection, the animals were euthanized and the entire liver, both kidneys, stomach (separated into glandular and non-glandular), small intestine, and both femurs were collected, weighed, and maintained on dry ice until moved into storage. All samples were stored at −85°C to −60°C until shipped to Battelle Toxicology Northwest (Richland, WA).

## E.2 Sample Analysis

### E.2.1 Three-month Studies

Tungsten concentrations in samples were quantified using validated analytical methods, and method validation data are given in Table E-1. Blood and urine samples from the study were stored at −70°C and −20°C, respectively, following collection. Samples were allowed to thaw at room temperature and mixed well. A 0.1 mL aliquot of blood was transferred into a Teflon digestion tube (CEM Corporation, Matthews, NC) and 0.15 mL of concentrated HNO_3_, 1.5 mL of deionized water, and 0.1 mL of 10 μg/mL bismuth (internal standard) in approximately 1% HNO_3_ (using 1 mg/mL procured from SPEX CertiPrep, Metuchen, NJ) was added. Urine samples were prepared similarly to blood except that to 0.1 mL of urine, 0.375 mL of concentrated HNO_3_, 1 mL of deionized water, and 0.25 mL of 0.2 μg/mL bismuth were added. The final acid strength of samples was approximately 1% HNO_3_. Samples were capped, allowed to stand for approximately 15 minutes, and digested at 1,600 W and 200°C for 40 minutes for blood or 20 minutes for urine using a MARS5 Microwave Digestion System (CEM Corporation, Mathews, NC). Samples were cooled to room temperature and diluted to 10 mL with water.

Corresponding matrix calibration standards, blanks, and quality control (QC) standards were prepared and analyzed similarly to study samples. Calibration curves were run on blood with six calibration standards (blood, 0.1 to 100 μg tungsten/L; urine, 0.5 to 150 μg tungsten/L). Blood QC standards were prepared at 0.5 and 50 μg tungsten/L, and urine QC standards were prepared at 2 and 100 μg/L. Study samples with responses greater than the highest calibration standard were diluted with 1% HNO_3_ such that the final concentration in the sample was within the validated range. All samples were analyzed for tungsten concentration using an inductively coupled plasma-mass spectrometry (ICP-MS) method as described below.

### E.2.2 Two-year Studies (Interim Evaluations)

Tungsten concentrations in samples were quantified using validated analytical methods and corresponding validation data are given in Table E-2, Table E-3, and Table E-4 for urine, plasma, and kidney, respectively. All study samples were stored at −70°C following collection. Plasma and urine samples were prepared using a method similar to the 3-month studies. Kidney samples were weighed and homogenized with approximately 5 volumes of water for 5 minutes using a polytron homogenizer. The homogenate was sonicated for approximately 30 minutes and then vortexed to mix. A 0.1-mL aliquot of the homogenate was digested similar to other matrices as before.

Corresponding solvent calibration standards, blanks, and matrix QC standards were prepared and analyzed similarly to study samples. Calibration curves were run with six calibration standards (0.1 to 100 μg tungsten/mL to quantitate plasma; 0.5 to 150 μg tungsten/mL to quantitate urine; 60 to 2,500 ng/mL to quantitate kidney homogenate). QC samples were prepared in all three matrices at 75 and 1,875 μg tungsten/mL. Study samples with responses greater than the highest calibration standard were diluted with 1% HNO_3_ such that final concentration in the sample was within the validated range. All samples were analyzed for tungsten concentration using an ICP-MS method as described below.

### E.2.3 Instrumentation and Quantitation

Samples from the 3-month studies were analyzed using an Agilent 7500ce (Agilent, Palo Alto, CA) ICP-MS. The detector mode was set to auto with a total acquisition time of 3.3 seconds. The ions monitored were m/z 182 and 209 for tungsten and bismuth, respectively. Samples from the 2-year studies were analyzed using a Perkin Elmer NexION 300 (Waltham, MA) ICP-MS. The detector mode was set to dual and total acquisition time of 4.008 seconds. The ions monitored were m/z 181.948 and 208.980 for tungsten and bismuth, respectively.

The performance of the calibration curve was evaluated before the analysis of each sample set. A successful calibration was indicated by the following: correlation coefficient (r) ≥ 0.98; relative standard deviation (RSD) ≤ ± 15% (except at the limit of quantitation (LOQ) where RSD was ≤ ± 20%); relative error (RE) ≤ ± 15% (except at LOQ where RE was ≤ ± 20%).

Calibration curves relating response ratio of analyte to internal standard (following correction for the background concentrations for the 3-month studies only) and concentration of tungsten in matrix were constructed using a 1/X weighted linear regression. The concentrations of tungsten in samples were calculated using response ratio, the regression equation, initial sample weight or volume, digestion volume, and dilution when applicable. The concentrations were reported as μg tungsten/mL (μg tungsten/g in 3-month studies) for blood, plasma, and urine and μg tungsten/g for kidney in the 2-year studies.

Data from study samples were considered valid if they were bracketed by valid QC sets. In general, each sample set, method blanks, and controls were bracketed by two QC sets, which consisted of a calibration blank and two concentrations of calibration standards (QC low and QC high). A QC set passed when the measured concentration for QC standards were within 20% of its nominal value. If the QC standard failed, it was necessary to reanalyze the bracketed samples. All QC standards were within 20% of nominal concentrations.

## E.3 Analysis of Xanthine and Methionine

Xanthine and methionine concentrations in rat urine were quantified using validated analytical methods using a standard addition approach. Validation data are listed in Table E-5. Study samples were stored at −20°C until used. Samples were allowed to thaw at room temperature and mixed well. Five 50 μL aliquot samples were transferred to individual wells in a 96-well plate, and 50 μL aliquots of the spiking standards of either methionine or xanthine (target concentrations 0, 0.075, 0.15, 0.3, 0.6 μg/mL) were added. After the addition of internal standard (400 μL of 1,500 ng/mL ^15^N_2_ xanthine or 2 μg/mL ^2^H_3_ methionine), the plate was covered with a pierceable sealing mat and the samples were mixed for approximately 10 seconds.

All samples were analyzed by liquid chromatography with tandem mass spectrometry using either an Agilent (Santa Clara, CA) or Shimadzu liquid chromatograph coupled to a Sciex (Toronto, Ontario, Canada) 4000 or 5000 mass spectrometer. For analysis of xanthine, chromatography was performed using a Phenomenex (Torrance, CA) Synergi Hydro RP (2 × 50 mm) column. Mobile phases A (water with 1 mM ammonium acetate, 0.1% formic acid) and B (acetonitrile with 0.1% formic acid) were run at a flow rate of 0.275 mL/minute with a linear gradient from 3% B to 95% B over 3 minutes followed by a 2.5-minute hold. The turbospray ion source was operated in negative mode. Transitions monitored for xanthine and ^15^N_2_ xanthine were 151: >108 and 153: >109, respectively. For analysis of methionine, chromatography was performed using a Phenomenex (Torrance, CA) Develosil C30 (50 × 2 mm) column. Mobile phases were the same as for analysis of xanthine and were run at a flow rate of 0.275 mL/minute with a linear gradient from 3% B (3 minutes) to 95% B over 1 minute followed by a 0.5-minute hold. The turbospray ion source was operated in negative mode. Transitions monitored for methionine and ^2^H_3_ methionine were 150: >104 and 153: >107, respectively.

Calibration curves relating response ratio of analyte to internal standard and concentration of xanthene or methionine in matrix were constructed using linear regression. The xanthine concentration in each was determined as the negative x-intercept of the standard addition curve. The concentration was reported as μg/mL of urine. Data from study samples were considered valid if the QCs were within 30% of the nominal values.

Table E-1 Analytical Method Validation and Stability Data for Tungsten in Blood and Urine for the Three-month Studies^a^

Validation Parameter | Rat Blood | Rat Urine | Mouse Blood plasma
Matrix Concentration Range (μg/g) | 0.01–10 | 0.002–3 | –
LOQ (μg/g) | 0.0068 | 0.0018 | –
LOD (μg/g) | 0.002 | 0.00054 | –
Correlation Coefficient (r) | ≥0.999 | ≥0.999 | –
Recovery (%)^b^ | 101.3–117.2 | 57.1–127.5 | –
Precision and Accuracy^c,d^
Intra-day % RSD | ≤7.9 | ≤4.6 | ≤6.8
Intra-day % RE | ≤ ± 7.1 | ≤ ± 4.4 | ≤ ± 3.1
Inter-day % RSD | ≤5.9 | ≤4.0 | –
Inter-day % RE | ≤ ± 5.0 | ≤ ± 1.9 | –
Dilution Verification | up to 50 μg/g | up to 30 μg/g | up to 100 μg/g
% RSD | 4.4 | 1.3 | 2.8
% RE | −10.5 | −14.0 | −10.8
Extract Stability (Ambient Storage) (Average % RE)^d^ | ≤ ± 2.5 up to 7 days | ≤ ± 4.3 up to 3 days | ≤ ± 1.5 up to 8 days
Matrix Stability (Average % RE)^d^
Freeze-thaw (three cycles) | ≤ ± 9.4 | ≤ ± 6.4 | ≤ ± 6.3
Frozen matrix (−70°C for blood and −20°C for urine, up to approximately 60 days) | ≤ ± 11.8 | ≤ ± 10.0 | ≤ ± 7.6

LOQ = limit of quantitation; LOD = limit of detection; RSD = relative standard deviation; RE = relative error.

^a^ Method was fully validated in Sprague Dawley rat blood and urine and cross-validated in B6C3F1/N mouse blood using quality control (QC) samples prepared in mouse blood at three concentrations (0.05, 1, 5 μg tungsten/g) and analyzed using a rat blood calibration curve.

^b^ Estimated by comparing response of matrix standards to solvent standards.

^c^ Precision was estimated as % RSD. Accuracy was estimated as average % RE.

^d^ Determined for six replicate QCs at three levels: 0.05, 1, and 5 μg tungsten/g for blood and 0.01, 0.2, and 2 μg tungsten/g for urine.

Table E-2 Analytical Method Validation and Stability Data for Tungsten in Urine for the Two-year Studies^a^

Validation Parameter | Rat | Mouse
Solvent Standard Concentration Range (ng/mL) | 60–2,500 | 60–2,500
LOQ (ng/mL) | 60 | 60
LOD (ng/mL) | 13.0 | 13.0
Correlation Coefficient (r) | ≥0.998 | ≥0.999
Recovery (%)^b^ | 102–105 | 104–117
Precision and Accuracy^c,d,e^
Intra-day % RSD | ≤7.1 | ≤2.9
Intra-day % RE | ≤ ± 11.9 | ≤ ± 29.3
Inter-day % RSD | ≤5.8 | –
Inter-day % RE | ≤ ± 10.6 | –
Dilution Verification – Water Predigestion | up to 100,000 ng/mL | up to 100,000 ng/mL
% RSD | 1.4 | 3.3
% RE | 7.9 | −5.1
Dilution Verification – Acid Postdigestion | up to 100,000 ng/mL | up to 100,000 ng/mL
% RSD | 2.9 | 3.4
% RE | 4.0 | 4.0
Matrix Evaluation^d,e,f^
Sprague Dawley rat % RSD | ≤11.4 | –
Sprague Dawley rat % RE | ≤ ± 27.0 | –
B6C3F1/N mouse % RSD | – | ≤3.6
B6C3F1/N mouse % RE | – | ≤ ± 17.1
Postpreparative Stability (Ambient Storage) (% RE)^e,g^ | ≤ ± 15.8 up to 16 days | ≤ ± 9.3 up to 16 days
Matrix Stability (% RE)^d,e^
Freeze-thaw (four cycles) | ≤ ± 11.7 | ≤ ± 2.7
Frozen matrix (−70°C up to approximately 61 days) | ≤ ± 15.0 | ≤ ± 12.8

LOQ = limit of quantitation; LOD = limit of detection; RSD = relative standard deviation; RE = relative error.

^a^ Method was fully validated in Sprague Dawley rat urine using a solvent standard curve and cross-validated in B6C3F1 mouse urine using quality control (QC) samples prepared in mouse urine at three concentrations (75, 375, 1,875 ng tungsten/mL) and analyzed using solvent curve.

^b^ Estimated by comparing response of matrix QC samples to solvent QC samples.

^c^ Precision was estimated as % relative standard deviation (RSD). Accuracy was estimated as average % relative error (RE).

^d^ Determined for six replicate QCs at three concentrations: 75, 375, and 1,875 ng tungsten/mL for rat and mouse urine.

^e^ Corrected for endogenous tungsten in urine.

^f^ Study samples matrices were assessed using six replicate QCs at three concentrations: 75,375,1875 ng tungsten/mL.

^g^ Determined for six replicate QCs at three concentrations: 75, 375, and 1,875 ng tungsten/mL for rat and mouse urine evaluated using freshly extracted standards and stored standard extracts.

Table E-3 Analytical Method Validation and Stability Data for Tungsten in Plasma for the Two-year Studies^a^

Validation Parameter | Rat | Mouse
Solvent Concentration Range (ng/mL) | 60–2,500 | 60–2,500
LOQ (ng/mL) | 60 | 60
LOD (ng/mL) | 13.0 | 13.0
Correlation Coefficient (r) | ≥0.99 | ≥0.99
Recovery (%)^b^ | 103–117 | 90.5–101
Precision and Accuracy^c,d,e^
Intra-day % RSD | ≤5.1 | ≤2.9
Intra-day % RE^e^ | ≤ ± 12.9 | ≤ ± 14.6
Inter-day % RSD | – | –
Inter-day % RE | – | –
Dilution Verification – Water Predigestion | up to 25,000 ng/mL | up to 25,000 ng/mL
% RSD | 2.5 | 2.2
% RE | 5.2 | 5.2
Dilution Verification – Acid Postdigestion | up to 25,000 ng/mL | up to 25,000 ng/mL
% RSD | 2.2 | 1.2
% RE | −1.6 | 10.4
Matrix Evaluation^d,e,f^
Sprague Dawley rat % RSD | ≤4.7 | –
Sprague Dawley rat % RE | ≤ ± 17.4 | –
B6C3F1/N mouse % RSD | – | ≤3.5
B6C3F1/N mouse % RE | – | ≤ ± 19.1
Postpreparative Stability (Ambient Storage) (% RE)^e,g^ | ≤ ± 18.4 up to 14 days | ≤ ± 18.2 up to 14 days
Matrix Stability (Average % RE)^d,e^
Freeze-thaw (four cycles) | ≤ ± 9.3 | ≤ ± 11.8
Frozen matrix (−70°C up to approximately 60 days) | ≤ ± 16.2 | ≤ ± 18.3

LOQ = limit of quantitation; LOD = limit of detection; RSD = relative standard deviation; RE = relative error.

^a^ Method was fully validated in Sprague Dawley rat urine using a solvent curve and crossed-validated in rat plasma and B6C3F1 mouse plasma using three concentrations (75, 375, 1,875 ng tungsten/mL) of quality control (QC) samples prepared in rat and mouse plasma and analyzed using solvent curve.

^b^ Estimated by comparing response of matrix sample to solvent sample.

^c^ Precision was estimated as % relative standard deviation (RSD). Accuracy was estimated as average % relative error (RE).

^d^ Determined for six replicate QCs at three concentrations: 75, 375, and 1,875 ng tungsten/mL for rat and mouse plasma.

^e^ Corrected for endogenous tungsten in plasma.

^f^ Study samples matrices were assessed using six replicate QCs at three concentrations: 75, 375, 1,875 ng tungsten/mL.

^g^ Determined for six replicate QCs at three concentrations: 75, 375, and 1,875 ng tungsten/mL for rat and mouse plasma evaluated using freshly extracted standards and stored standard extracts.

Table E-4 Analytical Method Validation and Stability Data for Tungsten in Kidney for the Two-year Studies^a^

Validation Parameter | Rat | Mouse
Matrix Concentration Range (ng/mL) | 60–2,500 | 60–2,500
LOQ (ng/mL) | 60 | 60
LOD (ng/mL) | 13.0 | 13.0
Correlation Coefficient (r) | ≥0.99 | ≥0.99
Recovery (%)^b^ | 118–120 | 111–124
Precision and Accuracy^c,d,e^
Intra-day % RSD | ≤1.2 | ≤2.1
Intra-day % RE | ≤ ± 14.1 | ≤ ± 11.5
Inter-day % RSD | – | –
Inter-day % RE | – | –
Dilution Verification – Water Predigestion | up to 125,000 ng/g | up to 125,000 ng/g
% RSD | 2.1 | 2.6
% RE | 5.6 | 7.2
Dilution Verification – Acid Postdigestion | up to 125,000 ng/g | up to 125,000 ng/g
% RSD | 1.7 | 1.8
% RE | −3.2 | −3.2
Matrix Evaluation^d,e,f^
Sprague Dawley rat % RSD | ≤4.3 | –
Sprague Dawley rat % RE | ≤ ± 3.5 | –
B6C3F1/N mouse % RSD | – | ≤4.6
B6C3F1/N mouse % RE | – | ≤ ± 9.9
Postpreparative Stability (Ambient Storage) (% RE)^e,g^ | ≤ ± 11.6 up to 28 days | ≤ ± 10.8 up to 28 days
Matrix Stability (% RE)^d,e^
Freeze-thaw (six cycles) | ≤ ± 12.5 | ≤ ± 5.8
Frozen matrix (−70°C up to approximately 55 days) | ≤ ± 10.3 | ≤ ± 11.9

LOQ = limit of quantitation; LOD = limit of detection; RSD = relative standard deviation; RE = relative error.

^a^ Method was fully validated in rat urine and cross-validated in Sprague Dawley rat and B6C3F1 and mouse kidney homogenate using quality control (QC) samples prepared in rat and mouse kidney homogenates at three concentrations (375, 1,875, and 9,375 ng tungsten/g) and analyzed using solvent curve.

^b^ Estimated by comparing response of matrix samples to solvent samples.

^c^ Precision was estimated as % relative standard deviation (RSD). Accuracy was estimated as average % relative error (RE).

^d^ Determined for six replicate QCs at three concentrations: 375, 18,75, and 9,375 ng tungsten/g for kidney homogenate.

^e^ Corrected for endogenous tungsten in kidney.

^f^ Study samples matrices were assessed using six replicates of QCs at three concentrations: 75, 375, and 1,875 ng tungsten/g.

^g^ Determined for six replicate QCs at three concentrations: 75, 375, and 1,875 ng tungsten/mL for rat and mouse kidney evaluated using freshly extracted standards and stored standard extracts.

Table E-5 Analytical Method Validation and Stability Data for Xanthine and Methionine in Rat Urine

Parameter | Xanthine | Methionine
Matrix Concentration Range (μg/mL) | 0.075–0.6 | 0.075–0.6
LOQ (μg/mL) | 0.075 | 0.075
Correlation Coefficient (r) | ≥0.994 | ≥0.999
Precision and Accuracy^a,b^
Intra-day % RSD | ≤27.2 | ≤12.5
Intra-day % RE | ≤ ± 25.4 | ≤ ± 13.5
Inter-day % RSD | 23.1 | 11.9
Inter-day % RE | −13.1 | 4.4
Stability (% RE)^b^
Freeze-thaw (three cycles) | −29.7 | −11.8
Frozen matrix (−20°C up to approximately190 days) | −15.0 | 2.2

LOQ = limit of quantitation; RSD = relative standard deviation; RE = relative error.

^a^ Precision was estimated as % relative standard deviation (RSD). Accuracy was estimated as average % relative error (RE).

^b^ Determined for six replicate quality control samples at 3 μg/mL for xanthine and 1.5 μg/mL for methionine.