# Appendix D Genetic Toxicology

## D.1 Bacterial Mutagenicity

### D.1.1 Bacterial Mutagenicity Test Protocol

Testing procedures were modified from those originally reported by Zeiger et al. (1992). Coded samples of sodium tungstate dihydrate (ST; the same chemical lot that was used in the 2-year bioassays) were incubated with the Salmonella typhimurium (TA98, TA100) or Escherichia coli (WP2 uvrA (pKM101)) tester strains either in buffer or S9 mix (metabolic activation enzymes and cofactors from phenobarbital/benzoflavone-induced male Sprague Dawley rat liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine (or tryptophan for the E. coli strain) and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine- or tryptophan-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of at least five doses of ST. The highest concentration tested was limited by toxicity in strain TA100; the other two strains were tested up to the assay limit dose of 6,000 μg/plate. All trials were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose-related, not reproducible, or not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. No minimum percentage or fold increase is required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### D.1.2 Results

ST (12.5 to 6,000 μg/plate) was not mutagenic in Salmonella typhimurium strains TA98 or TA100, or in Escherichia coli WP2 uvrA (pKM101), when tested with or without exogenous metabolic activation provided by phenobarbital/benzoflavone-induced rat S9 and cofactors (Table D-1).

Table D-1 Mutagenicity of Sodium Tungstate Dihydrate in Bacterial Tester Strains^a^

Strain | Concentration (μg/plate) | Without S9 | Without S9 | With 10% Rat S9 | With 10% Rat S9
TA98
| 0 | 28 ± 2 | 21 ± 2 | 46 ± 2 | 28 ± 1
| 12.5 | 25 ± 1 | 25 ± 5 | 33 ± 3 | 28 ± 3
| 50 | 27 ± 2 | 30 ± 4 | 29 ± 2 | 30 ± 4
| 125 | 23 ± 2 | 19 ± 3 | 32 ± 1 | 31 ± 4
| 500 | 22 ± 6 | 23 ± 5 | 34 ± 5 | 24 ± 1
| 1,500 | 19 ± 2 | 17 ± 3 | 34 ± 6 | 38 ± 4
| 6,000 | 30 ± 2 | 23 ± 6 | 33 ± 4 | 29 ± 6
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control^b^ | | 518 ± 31 | 465 ± 25 | 1,216 ± 77 | 1,017 ± 26
TA100
| 0 | 99 ± 3 | 123 ± 8 | 113 ± 2 | 117 ± 6
| 12.5 | 111 ± 8 | 129 ± 8 | 112 ± 6 | 113 ± 5
| 50 | 106 ± 7 | 100 ± 5 | 106 ± 5 | 108 ± 10
| 125 | 118 ± 8 | 107 ± 9 | 116 ± 3 | 111 ± 1
| 500 | 113 ± 3 | 97 ± 3 | 120 ± 2 | 105 ± 4
| 1,500 | 100 ± 5 | 113 ± 7 | 117 ± 6 | 138 ± 10
| 6,000 | 100 ± 6 | 110 ± 6 | 111 ± 11 | 117 ± 12
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 850 ± 9 | 800 ± 43 | 2,640 ± 135 | 1,724 ± 18
Escherichia coli WP2 uvrA (pKM101)
| 0 | 186 ± 8 | 191 ± 12 | 194 ± 11 | 219 ± 7
| 12.5 | 159 ± 3 | 183 ± 7 | 219 ± 6 | 183 ± 11
| 50 | 183 ± 7 | 161 ± 6 | 221 ± 21 | 179 ± 8
| 125 | 166 ± 18 | 156 ± 6 | 194 ± 4 | 181 ± 12
| 500 | 162 ± 6 | 171 ± 14 | 200 ± 14 | 206 ± 15
| 1,500 | 171 ± 8 | 185 ± 10 | 213 ± 17 | 211 ± 16
| 6,000 | 185 ± 12 | 165 ± 18 | 193 ± 14 | 197 ± 16
Trial Summary | | Negative | Negative | Negative | Negative
Positive Control | | 1,105 ± 49 | 959 ± 21 | 1,234 ± 70 | 1,009 ± 36

^a^ Studies performed at Integrated Laboratory Systems, LLC. Data are presented as revertants/plate (mean ± standard error) from three plates; 0 μg/plate served as the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 2-nitrofluorene (TA98), and methyl methanesulfonate (E. coli). The positive control for metabolic activation with all strains was 2-aminoanthracene.

## D.2 Micronucleus Assay

### D.2.1 Peripheral Blood Micronucleus Test Protocol

At termination of the 3-month toxicity studies of ST, blood samples (approximately 200 μL) were collected from male and female rats and mice, placed in ethylenediaminetetraacetic acid (EDTA)-coated tubes, and shipped overnight to the testing laboratory. Upon arrival, blood samples were fixed in ultracold methanol using a MicroFlowPLUS Kit (Litron Laboratories, Rochester, NY) according to the manufacturer’s instructions. Fixed samples were stored in a −80°C freezer until analysis. Thawed blood samples were analyzed for frequency of micronucleated immature erythrocytes (polychromatic erythrocytes [PCEs], reticulocytes) and mature erythrocytes (normochromatic erythrocytes, NCEs) using a flow cytometer^102^; both the mature and the immature erythrocyte populations can be analyzed separately by employing special cell surface markers to differentiate the two cell types. Because the very young reticulocyte subpopulation (CD71-positive cells) can be targeted using this technique, rat blood samples can be analyzed for damage that occurred in the bone marrow within the past 24–48 hours, before the rat spleen appreciably alters the percentage of micronucleated reticulocytes in circulation.^103^ In mice, both the immature and mature erythrocyte populations can be evaluated for micronucleus frequency because the mouse spleen does not sequester and eliminate damaged erythrocytes. Damaged erythrocytes achieve steady state in the peripheral blood of mice following 4 weeks of continuous exposure. Approximately 20,000 reticulocytes and 1×10^6^ erythrocytes were analyzed per animal for frequency of micronucleated cells, and the percentage of immature erythrocytes (% PCE) was calculated as a measure of bone marrow toxicity resulting from ST exposure.

Prior experience with the large number of cells scored using flow cytometric scoring techniques^104^ suggests it is reasonable to assume that the proportion of micronucleated reticulocytes is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. The Levene test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with exposure concentration and the Williams test is used to test for pairwise differences between each exposed group and the control group. In the case of unequal variances, the Jonckheere test is used to test for linear trend and the Dunn test is used for pairwise comparisons of each exposed group with the control group. To correct for multiple pairwise comparisons, the p value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is >1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the controls are considered significant at p ≤ 0.025.

In the micronucleus test, it is preferable to base a positive result on the presence of both a significant trend as well as at least one significantly elevated exposure group compared with the corresponding control group. In addition, historical control data are used to evaluate the biological significance of any observed response. Both statistical significance and biological significance are considered when arriving at a call. The presence of either a significant trend or a single significant exposure group generally results in an equivocal call. The absence of both a trend and a significant exposure group results in a negative call. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed (in acute studies), and the magnitudes of those effects.

### D.2.2 Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly those concerning pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The summary table in the Abstract of this Technical Report presents a result that is a scientific judgment of the overall evidence for activity of ST in an assay.

### D.2.3 Results

At the end of the 3-month studies, peripheral blood samples were obtained from male and female rats and mice and analyzed for the frequency of micronucleated reticulocytes and erythrocytes (Table D-2, Table D-3). In male and female rats, the reticulocyte population (PCEs), which is the only red blood cell population that can be accurately assessed for micronucleus frequency in peripheral blood of rats due to efficient splenic scavenging of damaged erythrocytes, did not show an increase in micronucleated cells following 3 months of exposure to ST via drinking water (0, 125, 250, 500, 1,000, and 2,000 mg/L) (Table D-2). Significant increases in the percent reticulocytes were seen in both male and female rats, suggesting that ST could have stimulated erythropoiesis in the bone marrow; however, the absolute increases in the percentages were small compared to the vehicle control animals.

In male and female mice, there were no significant increases in micronucleated reticulocytes or in micronucleated erythrocytes in either sex following 3 months of exposure to ST via drinking water (0, 125, 250, 500, 1,000, and 2,000 mg/L) (Table D-3). A significant increase in the percent reticulocytes was seen in male mice suggesting that ST could have stimulated erythropoiesis in the bone marrow; however, the absolute increase was small compared to the vehicle control group.

Table D-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Rats in the Three-month Drinking Water Study of Sodium Tungstate Dihydrate^a^

| Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (mg/L)
0 | 5 | 0.379 ± 0.04 | | 0.055 ± 0.01 | | 1.048 ± 0.08
125 | 5 | 0.447 ± 0.06 | 0.483 | 0.037 ± 0.01 | 0.934 | 1.138 ± 0.08 | 1.000
250 | 5 | 0.320 ± 0.10 | 0.563 | 0.034 ± 0.01 | 0.969 | 0.926 ± 0.04 | 1.000
500 | 5 | 0.450 ± 0.03 | 0.386 | 0.051 ± 0.01 | 0.978 | 1.036 ± 0.04 | 1.000
1,000 | 5 | 0.450 ± 0.06 | 0.400 | 0.033 ± 0.00 | 0.983 | 1.182 ± 0.08 | 0.222
2,000 | 5 | 0.390 ± 0.09 | 0.412 | 0.025 ± 0.00 | 0.985 | 1.318 ± 0.08 | 0.016
Trend^d^ | | p = 0.439 | | p = 0.988 | | p = 0.003
Female
Exposure Concentration (mg/L)
0 | 5 | 0.520 ± 0.03 | | 0.074 ± 0.02 | | 0.891 ± 0.11
125 | 5 | 0.560 ± 0.14 | 0.649 | 0.038 ± 0.00 | 0.861 | 0.799 ± 0.08 | 1.000
250 | 5 | 0.488 ± 0.05 | 0.735 | 0.064 ± 0.02 | 0.921 | 1.050 ± 0.10 | 0.278
500 | 5 | 0.520 ± 0.04 | 0.770 | 0.056 ± 0.01 | 0.939 | 1.085 ± 0.14 | 0.275
1,000 | 5 | 0.506 ± 0.09 | 0.787 | 0.050 ± 0.01 | 0.948 | 1.240 ± 0.07 | 0.042
2,000 | 5 | 0.280 ± 0.04 | 0.800 | 0.045 ± 0.01 | 0.954 | 1.191 ± 0.09 | 0.043
Trend | | p = 0.995 | | p = 0.853 | | p = 0.012

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^d^ Exposure concentration-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).

Table D-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male and Female Mice in the Three-month Drinking Water Study of Sodium Tungstate Dihydrate^a^

| Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs (%)^b^ | P Value^c^
Male
Exposure Concentration (mg/L)
0 | 5 | 2.530 ± 0.22 | | 1.433 ± 0.05 | | 1.558 ± 0.04
125 | 5 | 2.690 ± 0.11 | 0.299 | 1.467 ± 0.04 | 1.000 | 1.444 ± 0.06 | 1.000
250 | 5 | 2.830 ± 0.19 | 0.357 | 1.491 ± 0.04 | 1.000 | 1.552 ± 0.08 | 1.000
500 | 5 | 2.840 ± 0.30 | 0.381 | 1.559 ± 0.04 | 0.181 | 1.608 ± 0.04 | 0.939
1,000 | 5 | 2.380 ± 0.23 | 0.395 | 1.504 ± 0.07 | 1.000 | 1.547 ± 0.04 | 0.955
2,000 | 5 | 2.700 ± 0.12 | 0.383 | 1.470 ± 0.01 | 1.000 | 1.745 ± 0.03 | 0.021
Trend^d^ | | p = 0.580 | | p = 0.240 | | p = 0.002
Female
Exposure Concentration (mg/L)
0 | 5 | 1.810 ± 0.18 | | 0.909 ± 0.01 | | 1.302 ± 0.13
125 | 5 | 2.103 ± 0.15 | 0.339 | 0.952 ± 0.04 | 0.293 | 1.938 ± 0.20 | 0.311
250 | 5 | 1.940 ± 0.09 | 0.875 | 0.992 ± 0.02 | 0.350 | 1.568 ± 0.20 | 0.373
500 | 5 | 1.730 ± 0.13 | 1.000 | 0.890 ± 0.01 | 0.373 | 1.613 ± 0.22 | 0.400
1,000 | 5 | 1.960 ± 0.27 | 1.000 | 0.934 ± 0.04 | 0.387 | 1.187 ± 0.08 | 0.411
2,000 | 5 | 1.930 ± 0.08 | 0.922 | 0.874 ± 0.02 | 0.398 | 1.509 ± 0.13 | 0.418
Trend | | p = 0.522 | | p = 0.968 | | p = 0.567

PCE = polychromatic erythrocyte; NCE = normochromatic erythrocyte.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data presented as mean ± standard error.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^d^ Exposure concentration-related trends evaluated by linear regression or the Jonckheere test (p ≤ 0.025).

## D.3 Comet Assay

### D.3.1 Comet Assay Protocol

For preparation of samples for the comet assay, a 50 μL sample of blood was transferred to a tube containing 1 mL of freshly prepared cold mincing buffer [Mg^+2^, Ca^+2^, and phenol-free Hank’s Balanced Salt Solution (Life Technologies, Carlsbad, CA) with 20 mM EDTA, pH 7.3 to 7.5, and 10% v/v fresh dimethyl sulfoxide (DMSO)]. The ileum, liver, and kidney were rinsed with cold mincing buffer to remove residual blood and were held on ice briefly (≤5 minutes) until processed. Small portions (3 to 4 mm) of the ileum, liver, and kidney were placed in tubes containing cold mincing solution and rapidly minced until finely dispersed. All samples prepared for the comet assay were immediately flash frozen in liquid nitrogen^105^ and subsequently transferred to a −80°C freezer for storage until shipment by overnight courier on dry ice to the analytical laboratory. Upon receipt, all samples were immediately placed in a −80°C freezer for storage until further processing.

Blood and tissue samples were thawed on ice and maintained on ice during slide preparation. Just before use, each cell suspension was shaken gently to mix the cells and placed back on ice for 15 to 30 seconds to allow clumps to settle. A portion of the supernatant was empirically diluted with 0.5% low melting point agarose (Lonza, Walkersville, MD) dissolved in Dulbecco’s phosphate buffer (Ca^+2^, Mg^+2^, and phenol-free) at 37°C and layered onto each well of a 2-well CometSlide™ (Trevigen, Gaithersburg, MD). Slides were immersed in cold lysing solution [2.5 M NaCl, 100 mM Na_2_EDTA, 10 mM tris(hydroxymethyl)aminomethane (Tris), pH 10, containing freshly added 10% DMSO (Fisher Scientific, Pittsburgh, PA), and 1% Triton X-100] overnight in a refrigerator, protected from light. The following day, the slides were rinsed in 0.4 M Trizma base (pH 7.5), randomly placed onto the platform of a horizontal electrophoresis unit, and treated with cold alkali solution (300 mM NaOH, 1 mM Na_2_EDTA, pH > 13) for 20 minutes to allow DNA unwinding, then electrophoresed at 4°C to 9°C for 20 minutes at 25 V (0.7 V/cm), with a current of approximately 300 mA. After electrophoresis, slides were neutralized with 0.4 M Trizma base (pH 7.5) for 5 minutes and then dehydrated by immersion in absolute ethanol (Pharmco-AAPER, Shelbyville, KY) for at least 5 minutes and allowed to air dry. Slides were prepared in a laboratory with a relative humidity no more than 60% and stored at room temperature in a desiccator with a relative humidity of no more than 60% until stained and scored; stained slides were stored in a desiccator. NaCl, Na_2_EDTA, Triton X-100, and Trizma base were purchased from Sigma-Aldrich (St. Louis, MO); NaOH was purchased from Fisher Scientific (Pittsburgh, PA).

After staining with SYBR^®^ Gold (Molecular Probes, Life Technologies, Grand Island, NY), the slides, independently coded to mask treatment, were scored using Comet Assay IV Imaging Software, Version 4.3.1 (Perceptive Instruments, Ltd., Suffolk, UK), validated for Good Laboratory Practice Part 11 compliance. In the alkaline (pH > 13) comet assay, damaged nuclear DNA fragments undergo unidirectional migration through the agarose gel within an electrical field, forming an image that resembles a comet, and the greater the amount of fragmentation, the greater the amount of DNA migration that will occur. The image analysis software partitions the intensity of the fluorescent signal of the DNA in the entire comet image into the percent that is attributable to the comet head and the percent attributable to the tail. Manual adjustment of the automated detection of head and tail features is sometimes required. To evaluate DNA damage levels, the extent of DNA migration was characterized for 100 scorable comet figures per animal/tissue as percent tail DNA (intensity of all tail pixels divided by the total intensity of all pixels in the comet, expressed as a percentage).

### D.3.2 Results

In addition to evaluating the potential for chromosomal damage, the potential for DNA damage was assessed using the comet assay in the same animals in which micronucleus induction was evaluated. DNA damage from exposure to ST was assessed in liver, ileum, and kidney cell samples, and in blood leukocytes (Table D-4, Table D-5). Significant increases in DNA damage, measured as percent tail DNA, were observed in liver cells from male and female rats. Increases in DNA damage were not observed for peripheral blood leukocytes in male or female rats, or for ileum cells in female rats. Although cells from kidney tissue were evaluated from male and female rats, and ileum tissue was evaluated from male rats, results from these tissues were considered invalid due to unusually high levels of percent tail DNA in the control group. In male mice, significant increases in DNA damage were observed in liver and ileum cells, but not in kidney cells or peripheral blood leukocytes. No increases in percent tail DNA were observed in female mice for liver, kidney, ileum, or peripheral blood leukocyte cells.

Table D-4 DNA Damage in Male and Female Rats Exposed to Sodium Tungstate Dihydrate in Drinking Water for Three Months^a^

| Exposure Concentration (mg/L) | Blood | | Ileum | | Kidney | | Liver
| Exposure Concentration (mg/L) | Percent Tail DNA^b^ | P Value^c^ | Percent Tail DNA^b^ | P Value | Percent Tail DNA^b^ | P Value | Percent Tail DNA^b^ | P Value
Male
| 0 | 1.32 ± 0.22 | | IT | | IT | | 3.22 ± 0.12
| 125 | 1.15 ± 0.15 | 0.615 | IT | | IT | | 11.00 ± 1.44 | 0.078
| 250 | 1.21 ± 0.14 | 0.702 | IT | | IT | | 4.87 ± 0.70 | 1.000
| 500 | 1.59 ± 0.11 | 0.313 | IT | | IT | | 16.06 ± 1.43 | 0.003
| 1,000 | 1.49 ± 0.21 | 0.323 | IT | | IT | | 14.74 ± 1.43 | 0.010
| 2,000 | 1.77 ± 0.39 | 0.109 | IT | | IT | | 20.02 ± 2.08 | <0.001
| Trend^d^ | p = 0.021 | | – | | – | | p < 0.001
Female
| 0 | 1.48 ± 0.19 | | 17.38 ± 4.29 | | IT | | 9.84 ± 0.61
| 125 | 1.58 ± 0.17 | 0.679 | 24.02 ± 2.57 | 0.445 | IT | | 13.53 ± 1.63 | 0.460
| 250 | 1.28 ± 0.36 | 0.764 | 16.00 ± 1.73 | 0.522 | IT | | 17.02 ± 2.57 | 0.049
| 500 | 1.35 ± 0.13 | 0.798 | 15.58 ± 3.15 | 0.555 | IT | | 14.51 ± 1.07 | 0.131
| 1,000 | 1.10 ± 0.20 | 0.814 | 17.07 ± 2.73^e^ | 0.588 | IT | | 14.32 ± 1.87 | 0.196
| 2,000 | 1.22 ± 0.18 | 0.827 | 16.95 ± 2.69 | 0.587 | IT | | 22.47 ± 1.91 | <0.001
| Trend | p = 0.892 | | p = 0.741 | | – | | p < 0.001

IT = invalid test due to unusually high control percent tail DNA.

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data presented as mean ± standard error; n = 5.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^d^ Exposure concentration-related trends evaluated by linear regression of the Jonckheere test (p ≤ 0.025).

^e^ n = 4.

Table D-5 DNA Damage in Male and Female Mice Exposed to Sodium Tungstate Dihydrate in Drinking Water for Three Months^a^

| Exposure Concentration (mg/L) | Blood | | Ileum | | Kidney | | Liver
| Exposure Concentration (mg/L) | Percent Tail DNA^b^ | P Value^c^ | Percent Tail DNA^b^ | P Value | Percent Tail DNA^b^ | P Value | Percent Tail DNA^b^ | P Value
Male
| 0 | 2.49 ± 0.43 | | 11.69 ± 2.34 | | 6.20 ± 0.57 | | 4.14 ± 0.32^e^
| 125 | 3.90 ± 0.48 | 0.049 | 20.26 ± 1.91 | 0.019 | 5.48 ± 0.73 | 0.838 | 17.55 ± 0.50 | <0.001
| 250 | 3.86 ± 0.54 | 0.058 | 13.27 ± 0.68 | 0.023 | 5.07 ± 0.70 | 0.904 | 17.51 ± 1.25 | <0.001
| 500 | 3.29 ± 0.37 | 0.061 | 22.91 ± 1.17 | 0.023 | 4.84 ± 0.34 | 0.924 | 17.01 ± 1.03 | <0.001
| 1,000 | 3.34 ± 0.54 | 0.062 | 9.35 ± 1.56 | 0.023 | 5.67 ± 0.54 | 0.867 | 19.86 ± 1.02 | <0.001
| 2,000 | 3.61 ± 0.33 | 0.060 | 19.96 ± 0.91 | <0.001 | 6.63 ± 0.38 | 0.402 | 19.97 ± 1.25 | <0.001
| Trend^d^ | p = 0.199 | | p = 0.212 | | p = 0.308 | | p < 0.001
Female
| 0 | 0.93 ± 0.19 | | 20.50 ± 1.80 | | 6.81 ± 1.87 | | 6.40 ± 0.52
| 125 | 1.24 ± 0.24 | 0.830 | 21.85 ± 1.80 | 0.340 | 4.84 ± 0.47 | 1.000 | 5.92 ± 0.89 | 0.573
| 250 | 1.03 ± 0.11 | 1.000 | 21.07 ± 1.85 | 0.404 | 8.54 ± 3.13 | 1.000 | 10.63 ± 1.22 | 0.053
| 500 | 1.04 ± 0.23 | 1.000 | 24.65 ± 1.01 | 0.131 | 5.36 ± 0.59 | 1.000 | 7.99 ± 1.14 | 0.056
| 1,000 | 1.28 ± 0.29 | 1.000 | 23.91 ± 1.94 | 0.134 | 12.16 ± 3.75 | 0.403 | 8.90 ± 1.00 | 0.056
| 2,000 | 1.42 ± 0.09 | 0.167 | 21.88 ± 1.05 | 0.137 | 7.01 ± 1.02 | 1.000 | 7.50 ± 0.64 | 0.056
| Trend | p = 0.081 | | p = 0.112 | | p = 0.057 | | p = 0.105

^a^ Study was performed at Integrated Laboratory Systems, LLC.

^b^ Data presented as mean ± standard error; n = 5.

^c^ Pairwise comparisons with the vehicle control group performed using the Williams or Dunn test (p ≤ 0.025).

^d^ Exposure concentration-related trends evaluated by linear regression of the Jonckheere test (p ≤ 0.025).

^e^ n = 4.