# Appendix B Ingredients, Nutrient Composition, and Contaminant Levels in NIH-07 Rat Ration and NTP-2000 Rat and Mouse Ration

## B.1 NIH-07 Feed

Table B-1 Ingredients of NIH-07 Rat Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 23.00
Ground #2 Yellow Shelled Corn | 24.25
Wheat Middlings | 10.0
Alfalfa Meal (Dehydrated, 17% Protein) | 4.0
Soybean Meal (47% Protein) | 12.0
Fish Meal (62% Protein) | 10.0
Soy Oil (Without Preservatives) | 2.5
Dried Brewer’s Yeast | 2.0
Calcium Carbonate (USP) | 0.5
Vitamin Premix^a^ | 0.25
Mineral Premix^b^ | 0.15
Calcium Phosphate, Dibasic (USP) | 1.25
Sodium Chloride | 0.5
Choline Chloride (70% Choline) | 0.10
Dried Skim Milk | 5.00
Dried Molasses | 1.50
Corn Gluten Meal (60% Protein) | 3.00
Methionine | 0.0

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-2 Vitamins and Minerals in NIH-07 Rat Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 6,062 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 5,070 IU | D-activated animal sterol
Vitamin K | 3.1 mg | Menadione sodium bisulfite complex
Vitamin E | 22 IU | α-Tocopheryl acetate
Niacin | 33 mg | –
Folic Acid | 2.4 mg | –
d-Pantothenic Acid | 19.8 mg | d-Calcium pantothenate
Riboflavin | 3.8 mg | –
Thiamine | 11 mg | Thiamine mononitrate
B_12_ | 50 μg | –
Pyridoxine | 6.5 mg | Pyridoxine hydrochloride
Biotin | 0.15 mg | d-Biotin
Minerals
Iron | 132 mg | Iron sulfate
Zinc | 18 mg | Zinc oxide
Manganese | 66 mg | Manganese oxide
Copper | 4.4 mg | Copper sulfate
Iodine | 2.0 mg | Calcium iodate
Cobalt | 0.44 mg | Cobalt carbonate

^a^ Per kg of finished product.

Table B-3 Nutrient Composition of NIH-07 Rat Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 24.65 ± 1.344 | 23.7–25.6 | 2
Crude Fat (% by Weight) | 5.3 ± 0.141 | 5.2–5.4 | 2
Crude Fiber (% by Weight) | 3.57 ± 0.184 | 3.44–3.70 | 2
Ash (% by Weight) | 6.565 ± 0.049 | 6.53–6.60 | 2
Amino Acids (% of Total Diet)
Arginine | 1.380 ± 0.06 | 1.3–1.49 | 10
Cystine | 0.322 ± 0.031 | 0.274–0.372 | 10
Glycine | 1.150 ± 0.070 | 1.06–1.31 | 10
Histidine | 0.518 ± 0.024 | 0.497–0.553 | 10
Isoleucine | 0.984 ± 0.024 | 0.952–1.03 | 10
Leucine | 2.018 ± 0.067 | 1.93–2.13 | 10
Lysine | 1.243 ± 0.051 | 1.13–1.32 | 10
Methionine | 0.488 ± 0.016 | 0.468–0.515 | 10
Phenylalanine | 1.097 ± 0.022 | 1.07–1.12 | 10
Threonine | 0.918 ± 0.031 | 0.883–0.961 | 10
Tryptophan | 0.277 ± 0.020 | 0.265–0.326 | 10
Tyrosine | 0.860 ± 0.037 | 0.785–0.894 | 10
Valine | 1.134 ± 0.025 | 1.11–1.17 | 10
Essential Fatty Acids (% of Total Diet)
Linoleic | 2.30 ± 0.219 | 1.99–2.59 | 10
Linolenic | 0.25 ± 0.275 | 0.217–0.296 | 10
Vitamins
Vitamin A (IU/kg) | 4,545 ± 67.2 | 4,070–5,020 | 2
α-Tocopherol (ppm) | 6,704 ± 21,045 | 40.3–66,600 | 10
Thiamine (ppm)^a^ | 14.95 ± 0.778 | 14.4–15.5 | 2
Riboflavin (ppm) | 14.47 ± 3.352 | 10.0–19.8 | 10
Niacin (ppm) | 99.33 ± 8.235 | 87.0–112.0 | 10
Pantothenic Acid (ppm) | 44.38 ± 3.806 | 38.2–51.1 | 10
Pyridoxine (ppm)^a^ | 12.876 ± 3.171 | 9.63–19.7 | 10
Folic Acid (ppm) | 2.482 ± 0.487 | 1.68–3.09 | 10
Biotin (ppm) | 0.3283 ± 0.172 | 0.0–0.638 | 10
B_12_ (ppb) | 49.4 ± 6.83 | 41.8–61.6 | 10
Choline (as chloride) (ppm) | 1,821.0 ± 197.5 | 1,570–2,200 | 10
Minerals
Calcium (%) | 1.205 ± 0.078 | 1.15–1.26 | 2
Phosphorus (%) | 0.938 ± 0.036 | 0.912–0.963 | 2
Potassium (%) | 0.830 ± 0.036 | 0.769–0.88 | 10
Chloride (%) | 0.652 ± 0.106 | 0.441–0.8 | 10
Sodium (%) | 0.378 ± 0.46 | 0.318–0.469 | 10
Magnesium (%) | 0.187 ± 0.014 | 0.17–0.218 | 10
Iron (ppm) | 385.1 ± 54.9 | 276.0–469.0 | 10
Manganese (ppm) | 90.81 ± 7.566 | 80.7–104.0 | 10
Zinc (ppm) | 64.15 ± 10.07 | 52.4–89.2 | 10
Copper (ppm) | 14.13 ± 2.57 | 11.9–21.1 | 10
Iodine (ppm) | 1.811 ± 0.992 | 0.54–3.45 | 10
Chromium (ppm) | 3.946 ± 0.036 | 3.89–4.0 | 8
Cobalt (ppm) | 0.5155 ± 0.267 | 0.01–0.963 | 10

^a^ As hydrochloride.

Table B-4 Contaminant Levels in NIH-07 Rat Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.2965 ± 0.029 | 0.26–0.317 | 2
Cadmium (ppm) | 0.082 ± 0.004 | 0.079–0.085 | 2
Lead (ppm) | 0.0785 ± 0.001 | 0.078–0.079 | 2
Mercury (ppm)^a^ | 0.0135 ± 0.002 | 0.012–0.015 | 2
Selenium (ppm) | 0.4065 ± 0.110 | 0.329–0.484 | 2
Aflatoxins (ppb)^a^ | 5 | – | 2
Nitrate Nitrogen (ppm)^b^ | 19.55 ± 1.344 | 18.6–20.5 | 2
Nitrite Nitrogen (ppm)^a,b^ | <0.61 | – | 2
BHA (ppm)^a,c^ | <1.0 | – | 2
BHT (ppm)^a,c^ | <1.0 | – | 2
Aerobic Plate Count (CFU/gm)^a^ | <10 | – | 2
Coliform (MPN/gm)^a^ | <3 | – | 2
Escherichia coli (MPN/gm)^a^ | <10 | – | 2
Salmonella (MPN/gm) | 0 | – | 2
Total Nitrosamines (ppb)^d^ | 6.6 ± 1.70 | 5.4–7.8 | 2
N-Ndimethylamine (ppb)^d^ | 0 | – | 2
N-Npyrrolidine (ppb)^d^ | 6.6 ± 1.70 | 5.4–7.8 | 2
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 2
β-BHC^a^ | <0.02 | – | 2
γ-BHC^a^ | <0.01 | – | 2
δ-BHC^a^ | <0.01 | – | 2
Heptachlor^a^ | <0.01 | – | 2
Aldrin^a^ | <0.01 | – | 2
Heptachlor Epoxide^a^ | <0.01 | – | 2
DDE^a^ | <0.01 | – | 2
DDD^a^ | <0.01 | – | 2
DDT^a^ | <0.01 | – | 2
HCB^a^ | <0.01 | – | 2
Mirex^a^ | <0.01 | – | 2
Methoxychlor^a^ | <0.05 | – | 2
Dieldrin^a^ | <0.01 | – | 2
Endrin^a^ | <0.01 | – | 2
Telodrin^a^ | <0.01 | – | 2
Chlordane^a^ | <0.05 | – | 2
Toxaphene^a^ | <0.10 | – | 2
Estimated PCBs^a^ | <0.20 | – | 2
Ronnel^a^ | <0.01 | – | 2
Ethion^a^ | <0.02 | – | 2
Trithion^a^ | <0.05 | – | 2
Diazinon^a^ | <0.10 | – | 2
Methyl Chlorpyrifos | 0.0391 ± 0.027 | 0.0200–0.0582 | 2
Methyl Parathion^a^ | <0.02 | – | 2
Ethyl Parathion^a^ | <0.02 | – | 2
Malathion^a^ | <0.02 | – | 2
Endosulfan I^a^ | <0.01 | – | 2
Endosulfan II^a^ | <0.01 | – | 2
Endosulfane Sulfate^a^ | <0.03 | – | 2

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.

## B.2 NTP-2000 Feed

Table B-5 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percent by Weight
Ground Hard Winter Wheat | 22.26
Ground #2 Yellow Shelled Corn | 22.18
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 5.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table B-6 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration

| Amount^a^ | Source
Vitamins
Vitamin A | 4,000 IU | Stabilized vitamin A palmitate or acetate
Vitamin D | 1,000 IU | D-activated animal sterol
Vitamin K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
d-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 μg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table B-7 Nutrient Composition of NTP-2000 Rat and Mouse Ration

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.61 ± 0.537 | 13.9–16.5 | 32
Crude Fat (% by Weight) | 8.39 ± 0.376 | 7.7–9.2 | 32
Crude Fiber (% by Weight) | 9.26 ± 0.603 | 7.1–10.1 | 32
Ash (% by Weight) | 4.93 ± 0.138 | 4.66–5.2 | 32
Amino Acids (% of Total Diet)
Arginine | 0.805 ± 0.075 | 0.67–0.97 | 29
Cystine | 0.220 ± 0.021 | 0.15–0.25 | 29
Glycine | 0.702 ± 0.038 | 0.62–0.8 | 29
Histidine | 0.342 ± 0.070 | 0.27–0.68 | 29
Isoleucine | 0.549 ± 0.040 | 0.43–0.66 | 29
Leucine | 1.100 ± 0.063 | 0.96–1.24 | 29
Lysine | 0.700 ± 0.104 | 0.31–0.86 | 29
Methionine | 0.409 ± 0.042 | 0.26–0.49 | 29
Phenylalanine | 0.623 ± 0.047 | 0.471–0.72 | 29
Threonine | 0.513 ± 0.041 | 0.43–0.61 | 29
Tryptophan | 0.155 ± 0.027 | 0.11–0.2 | 29
Tyrosine | 0.422 ± 0.066 | 0.28–0.54 | 29
Valine | 0.666 ± 0.040 | 0.55–0.73 | 29
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.94 ± 0.235 | 3.49–4.55 | 29
Linolenic | 0.30 ± 0.064 | 0.005–0.368 | 29
Vitamins
Vitamin A (IU/kg) | 3,757 ± 70.50 | 2,520–5,450 | 32
Vitamin D (IU/kg)^a^ | 1,000 | – | –
α-Tocopherol (ppm) | 2,456 ± 128.17 | 13.6–69,100 | 29
Thiamine (ppm)^b^ | 7.5 ± 0.614 | 6.1–9.0 | 32
Riboflavin (ppm) | 8.17 ± 2.841 | 42–17.5 | 29
Niacin (ppm) | 78.66 ± 8.11 | 66.4–98.2 | 29
Pantothenic Acid (ppm) | 26.42 ± 11.05 | 17.4–81.0 | 29
Pyridoxine (ppm)^b^ | 9.75 ± 2.045 | 6.44–14.3 | 29
Folic Acid (ppm) | 1.58 ± 0.43 | 1.15–3.27 | 29
Biotin (ppm) | 0.323 ± 0.093 | 0.2–0.704 | 29
B_12_ (ppb) | 50.41 ± 34.89 | 18.3–174 | 29
Choline (as Chloride) (ppm) | 2,593 ± 633.8 | 1,160–3,790 | 29
Minerals
Calcium (%) | 0.902 ± 0.056 | 0.697–1.02 | 32
Phosphorus (%) | 0.551 ± 0.023 | 0.504–0.615 | 32
Potassium (%) | 0.668 ± 0.029 | 0.626–0.733 | 29
Chloride (%) | 0.392 ± 0.044 | 0.3–0.517 | 29
Sodium (%) | 0.195 ± 0.027 | 0.16–0.283 | 29
Magnesium (%) | 0.217 ± 0.054 | 0.185–0.49 | 29
Sulfur (%) | 0.170 ± 0.029 | 0.116–0.209 | 14
Iron (ppm) | 191.6 ± 36.18 | 135–311 | 29
Manganese (ppm) | 50.11 ± 9.42 | 21–73.1 | 29
Zinc (ppm) | 57.3 ± 25.54 | 43.3–184 | 29
Copper (ppm) | 7.57 ± 2.49 | 3.21–16.3 | 29
Iodine (ppm) | 0.513 ± 0.221 | 0–0.972 | 29
Chromium (ppm) | 1.02 ± 1.04 | 0.33–3.97 | 28
Cobalt (ppm) | 0.222 ± 0.152 | 0.0857–0.864 | 27

^a^ From formulation.

^b^ As hydrochloride.

Table B-8 Contaminant Levels in NTP-2000 Rat and Mouse Ration

| Mean ± Standard Deviation | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.199 ± 0.045 | 0.143–0.307 | 32
Cadmium (ppm) | 0.065 ± 0.080 | 0.015–0.5 | 32
Lead (ppm) | 0.16 ± 0.202 | 0.059–1.19 | 32
Mercury (ppm)^a^ | 0.012 ± 0.004 | 0.01–0.026 | 32
Selenium (ppm) | 0.169 ± 0.039 | 0.029–0.266 | 32
Aflatoxins (ppb)^a^ | <5.0 | – | 32
Nitrate Nitrogen (ppm)^b^ | 18.88 ± 9.5 | 10.0–45.9 | 32
Nitrite Nitrogen (ppm)^a,b^ | 0.61 | – | 32
BHA (ppm)^a,c^ | <1.00 | – | 32
BHT (ppm)^a,c^ | 1.03 ± 0.156 | 1.0–1.88 | 32
Aerobic Plate Count (CFU/gm) | 14.84 ± 18.56 | 10.0–110.0 | 32
Coliform (MPN/gm) | 3.0 | – | 32
Escherichia coli (MPN/gm)^a^ | <10.0 | – | 32
Salmonella (MPN/gm) | Negative | – | 32
Total Nitrosamines (ppb)^d^ | 9.8 ± 5.12 | 0–19.9 | 32
N-Ndimethylamine (ppb)^d^ | 2.3 ± 2.6 | 0–11.1 | 32
N-Npyrrolidine (ppb)^d^ | 7.8 ± 4.24 | 0–18.6 | 32
Pesticides (ppm)
α-BHC^a^ | <0.01 | – | 32
β-BHC^a^ | <0.02 | – | 32
γ-BHC^a^ | <0.01 | – | 32
δ-BHC^a^ | <0.01 | – | 32
Heptachlor^a^ | <0.01 | – | 32
Aldrin^a^ | <0.01 | – | 32
Heptachlor Epoxide^a^ | <0.01 | – | 32
DDE^a^ | <0.01 | – | 32
DDD^a^ | <0.01 | – | 32
DDT^a^ | <0.01 | – | 32
HCB^a^ | <0.01 | – | 32
Mirex^a^ | <0.01 | – | 32
Methoxychlor^a^ | <0.05 | – | 32
Dieldrin^a^ | <0.01 | – | 32
Endrin^a^ | <0.01 | – | 32
Telodrin^a^ | <0.01 | – | 32
Chlordane^a^ | <0.05 | – | 32
Toxaphene^a^ | <0.10 | – | 32
Estimated PCBs^a^ | <0.20 | – | 32
Ronnel^a^ | <0.01 | – | 32
Ethion^a^ | <0.02 | – | 32
Trithion^a^ | <0.05 | – | 32
Diazinon^a^ | <0.10 | – | 32
Methyl Chlorpyrifos | 0.112 ± 0.141 | 0.02–0.686 | 32
Methyl Parathion^a^ | <0.02 | – | 32
Ethyl Parathion^a^ | <0.02 | – | 32
Malathion | 0.07 ± 0.07 | 0.02–0.234 | 32
Endosulfan I^a^ | <0.01 | – | 32
Endosulfan II^a^ | <0.01 | – | 32
Endosulfane Sulfate^a^ | <0.03 | – | 32

All samples were irradiated.

BHA = butylated hydroxyanisole; BHT = butylated hydroxytoluene; CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; DDE = dichlorodiphenyldichloroethylene; DDD = dichlorodiphenyldichloroethane; DDT = dichlorodiphenyltrichloroethane; HCB = hexachlorobenzene; PCB = polychlorinated biphenyl.

^a^ All values were below the detection limit. The detection limit is given as the mean.

^b^ Sources of contamination include alfalfa, grains, and fish meal.

^c^ Sources of contamination include soy oil and fish meal.

^d^ All values were corrected for percent recovery.