# Appendix A Chemical Characterization and Dose Formulation Studies

## A.1 Procurement and Characterization of Sodium Tungstate Dihydrate

Sodium tungstate dihydrate (ST) was procured from Sigma-Aldrich (St. Louis, MO) in two lots (lot 12330JO and lot MKBG9975V). Lot 12330JO was obtained directly from Sigma-Aldrich (St. Louis, MO), whereas lot MKBG9975V was produced by Sigma-Aldrich and obtained from Government Scientific Source, Inc. (Reston, VA). Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory and study laboratory at Battelle (Columbus, OH). Reports on analyses performed in support of the ST studies are on file at the National Institute of Environmental Health Sciences.

ST is a white solid composed of fine crystals. The 3-month studies used lot 12330JO, which was homogenized by mixing for 15 minutes and transferred to 1 L amber storage bottles. For the 2-year studies, the remainder of lot 12330JO was combined with lot MKBG9975V to create lot 07072011 by mixing in a blender for 15 minutes.

The identities of the lots were confirmed using infrared spectroscopy (Figure A-1). The x-ray diffraction patterns of both lots were in good agreement with the reference pattern. Purity assessment with proton-induced x-ray emission identified magnesium (0.7%–0.9%) and aluminum (approximately 0.3%) impurities in both lots. The average concentrations of tungsten and sodium in lot 12330JO were 54.09% and 18.24%, respectively. Lot 07072011 had average tungsten and sodium concentrations of 47.6% and 15.8%, respectively. Elemental analysis using inductively coupled plasma atomic emission spectrometry yielded purities of approximately 99%, based on weight percentages of tungsten (55.2%–56.4%) and sodium (13.4%–13.8%). Karl Fisher titration yielded a water content of 9.5% for lot 12330JO and 10.0%–10.3% for lot 07072011, slightly lower than the anticipated 10.9%. Titration with lead nitrate indicated a purity of 97.6% for lot 12330JO and 98.2% for lot 07072011. Ion chromatography (IC) with a suppressed conductivity detector and liquid chromatography with an inductively coupled plasma (ICP) mass spectrometer indicated a purity of 100% for both lots. Additional information on chromatography systems used can be found in Table A-1.

Accelerated stability studies were conducted on samples of ST stored at 60°C, 25°C, 5°C, and −20°C using IC with a suppressed conductivity detector. Stability was confirmed for at least 2 weeks when stored in sealed amber glass bottles at 25°C, 5°C, and −20°C. Given these findings, bulk ST was stored in sealed amber glass bottles at 25°C. Periodic analyses of the bulk chemical using IC with a suppressed conductivity detector were conducted during the 3-month and 2-year studies by the study laboratory and confirmed that no degradation occurred.

## A.2 Preparation and Analysis of Dose Formulations

The presence of tungsten and molybdenum in animal feed (NIH-07 and NTP-2000) and deionized water used in the 3-month and 2-year studies were evaluated with ICP optical emission spectrometry at Galbraith Laboratories, Inc. (Knoxville, TN). NIH-07 feed contained approximately 2 ppm tungsten, and the concentration in NTP-2000 feed was at the detection limit of the assay (0.80 ppm). Concentrations of tungsten in deionized water, and the concentration of molybdenum in all feed and water samples, were below the limits of detection of the assay (0.20 to 0.80 ppm).

Stability analysis conducted on the 20 μg/mL (20 mg/mL) formulation found that the formulations were stable when sealed and stored in Nalgene bottles for 42 days at 5°C and room temperature (approximately 25°C). An animal room simulation was conducted using the 20 mg/mL formulation stored in a drinking water bottle filled near capacity with aliquots periodically removed to simulate animal drinking. There was no significant loss in tungsten over 7 days at room temperatures.

Dose formulations of ST were prepared monthly (Table A-2). Formulations were prepared with deionized water. The 3-month studies used formulations of 0, 125, 250, 500, 1,000, and 2,000 mg/L for both mice and rats. These formulations were prepared four times in the mouse study (May–July 2009) and five times in the rat study (May–August 2009). The 2-year mouse study used 0, 500, 1,000, and 2,000 mg/L formulations prepared 27 times from January 2012 to January 2014. The 2-year rat study used 0, 250, 500, and 1,000 mg/L formulations prepared 28 times from December 2011 to January 2014. Formulations were determined to be homogeneous and of appropriate concentration using IC with a suppressed conductivity detector. Stability was confirmed for 42 days at room temperature.

Preadministration and postadministration (animal room) analysis of formulations was conducted monthly throughout the 3-month studies (Table A-3, Table A-4). During the 2-year studies, preadministration formulations were analyzed every 1–3 months, whereas postadministration (animal room) formulation were analyzed every 6–8 months (Table A-5, Table A-6). All preadministration formulations in the 3-month rat and mouse studies were within 10% of the target concentration. In the 3-month mouse study, four postadministration samples were more than 10% below the target concentration in postadministration samples collected from bottles used to expose females and carboys, with the largest difference being 12.8% below the target (Table A-4). Postadministration samples collected from bottles or carboys in the 3-month rat study prepared in May 2009 (125 mg/L), July 2009 (500 mg/L), and August 2009 (2,000 mg/L) were 12.3%, 11.5%, and 10.8% below the target concentrations, respectively. All preadministration and postadministration samples in the 2-year studies were within 10% of the target concentration.

Table A-1 Chromatography Systems Used in the Three-month and Two-year Studies of Sodium Tungstate Dihydrate

Chromatography | Detection System | Column | Mobile Phase
System A
Ion chromatography | Suppressed conductivity (50 mA) | Dionex IonPac AS11-HC, 250 mm × 2 mm ID | 24 mM sodium hydroxide, flow rate 0.4 mL/min
System B
Ion chromatography | Suppressed conductivity (40°C) | Dionex IonPac AS11-HC, 250 mm × 4 mm ID | 27 mM sodium hydroxide, flow rate 0.9 mL/min
System C
Liquid chromatography | Inductively coupled plasma-mass spectrometer | IonPac AS11-HC, 250 × 2 mm ID | Approximately 14.4 mM sodium hydroxide, flow rate 0.4 mL/min

ID = internal diameter.

Table A-2 Preparation and Storage of Dose Formulations in the Three-month and Two-year Studies of Sodium Tungstate Dihydrate

Preparation
Stock solutions of sodium tungstate dihydrate were created by weighing an appropriate amount of lot 12330JO (3-month studies) or lot 07072011 (2-year studies) in a weighing container. The contents were transferred to a volumetric flask and rinsed with water to ensure complete transfer. Flasks were brought to volume with deionized water. Dose formulations were prepared monthly throughout the 3-month and 2-year studies.
Chemical Lot Number
3-month: 12330JO 2-year: 07072011 (Sigma lot 12330JO and MKBG9975V)
Maximum Storage Time
42 days
Storage Conditions
Formulations were stored in sealed Nalgene bottles at 5°C or 25°C
Study Laboratory
Battelle (Columbus, OH)

Table A-3 Results of Analyses of Dose Formulations Administered to Rats in the Perinatal and Three-month Study of Sodium Tungstate Dihydrate

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration (mg/L)^a^ | Difference from Target (%)
May 11, 2009 | May 12, 2009 | 125 | 118 ± 9 | −5.6
May 11, 2009 | May 12, 2009 | 250 | 257 ± 2 | 2.7
May 11, 2009 | May 12, 2009 | 500 | 511 ± 12 | 2.2
May 11, 2009 | May 12, 2009 | 1,000 | 1,070 ± 20 | 6.7
May 11, 2009 | May 12, 2009 | 2,000 | 2,200 ± 10 | 10.0
May 11, 2009 | June 25, 2009 (bottle)^b^ | 125 | 123 ± 6 | −1.9
May 11, 2009 | June 25, 2009 (bottle)^b^ | 250 | 259 ± 2 | 3.7
May 11, 2009 | June 25, 2009 (bottle)^b^ | 500 | 515 ± 9 | 3.0
May 11, 2009 | June 25, 2009 (bottle)^b^ | 1,000 | 945 ± 53 | −5.5
May 11, 2009 | June 25, 2009 (bottle)^b^ | 2,000 | 1,890 ± 130 | −5.5
May 11, 2009 | June 25, 2009 (carboy)^c^ | 125 | 110 ± 8 | −12.3
May 11, 2009 | June 25, 2009 (carboy)^c^ | 250 | 245 ± 8 | −2.1
May 11, 2009 | June 25, 2009 (carboy)^c^ | 500 | 485 ± 27 | −2.9
May 11, 2009 | June 25, 2009 (carboy)^c^ | 1,000 | 973 ± 19 | −2.7
May 11, 2009 | June 25, 2009 (carboy)^c^ | 2,000 | 2,120 ± 70 | 6.0
June 5, 2009 | June 16, 2009 | 125 | 123 ± 3 | −1.6
June 5, 2009 | June 16, 2009 | 250 | 243 ± 4 | −2.7
June 5, 2009 | June 16, 2009 | 500 | 494 ± 4 | −1.2
June 5, 2009 | June 16, 2009 | 1,000 | 1,000 ± NA^d^ | 0.0
June 5, 2009 | June 16, 2009 | 2,000 | 1,940 ± 40 | −3.2
June 5, 2009 | July 24, 2009 (bottle)^b^ | 125 | 121 ± 4 | −3.5
June 5, 2009 | July 24, 2009 (bottle)^b^ | 250 | 245 ± 8 | −1.9
June 5, 2009 | July 24, 2009 (bottle)^b^ | 500 | 508 ± 11 | 1.6
June 5, 2009 | July 24, 2009 (bottle)^b^ | 1,000 | 1,040 ± 10 | 3.7
June 5, 2009 | July 24, 2009 (bottle)^b^ | 2,000 | 2,070 ± 20 | 3.7
June 5, 2009 | July 24, 2009 (carboy)^c^ | 125 | 127 ± 7 | 1.3
June 5, 2009 | July 24, 2009 (carboy)^c^ | 250 | 248 ± NA^e^ | −0.8
June 5, 2009 | July 24, 2009 (carboy)^c^ | 500 | 523 ± NA^e^ | 4.5
June 5, 2009 | July 24, 2009 (carboy)^c^ | 1,000 | 1,050 ± 10 | 4.7
June 5, 2009 | July 24, 2009 (carboy)^c^ | 2,000 | 2,080 ± 30 | 4.2
July 31, 2009 | August 3, 2009 | 125 | 118 ± 7 | −5.6
July 31, 2009 | August 3, 2009 | 250 | 254 ± 4 | 1.6
July 31, 2009 | August 3, 2009 | 500 | 510 ± 13 | 2.0
July 31, 2009 | August 3, 2009 | 1,000 | 1,010 ± 80 | 1.3
July 31, 2009 | August 3, 2009 | 2,000 | 1,950 ± 170 | −2.5
July 31, 2009 | September 22, 2009 (bottles)^b^ | 125 | 117 ± 4 | −6.7
July 31, 2009 | September 22, 2009 (bottles)^b^ | 250 | 243 ± 22 | −2.7
July 31, 2009 | September 22, 2009 (bottles)^b^ | 500 | 442 ± 32 | −11.5
July 31, 2009 | September 22, 2009 (bottles)^b^ | 1,000 | 1,050 ± 30 | 4.7
July 31, 2009 | September 22, 2009 (bottles)^b^ | 2,000 | 1,870 ± 130 | −6.7
July 31, 2009 | September 22, 2009 (carboy)^c^ | 125 | 129 ± 8 | 3.2
July 31, 2009 | September 22, 2009 (carboy)^c^ | 250 | 271 ± 8 | 8.5
July 31, 2009 | September 22, 2009 (carboy)^c^ | 500 | 479 ± 24 | −4.2
July 31, 2009 | September 22, 2009 (carboy)^c^ | 1,000 | 1,030 ± 80 | 2.9
July 31, 2009 | September 22, 2009 (carboy)^c^ | 2,000 | 1,920 ± 20 | −3.8
August 27, 2009 | August 31, 2009 | 125 | 114 ± 4 | −8.5
August 27, 2009 | August 31, 2009 | 250 | 244 ± 3 | −2.4
August 27, 2009 | August 31, 2009 | 500 | 467 ± 19 | −6.5
August 27, 2009 | August 31, 2009 | 1,000 | 964 ± 4 | −3.6
August 27, 2009 | August 31, 2009 | 2,000 | 1,890 ± 40 | −5.7
August 27, 2009 | September 30, 2009 (bottle)^b^ | 125 | 114 ± 12 | −8.5
August 27, 2009 | September 30, 2009 (bottle)^b^ | 250 | 240 ± 7 | −4.0
August 27, 2009 | September 30, 2009 (bottle)^b^ | 500 | 486 ± 4 | −2.9
August 27, 2009 | September 30, 2009 (bottle)^b^ | 1,000 | 1,010 ± 10 | 1.3
August 27, 2009 | September 30, 2009 (bottle)^b^ | 2,000 | 2,050 ± 20 | 2.3
August 27, 2009 | September 30, 2009 (carboy)^c^ | 125 | 126 ± 3 | 1.1
August 27, 2009 | September 30, 2009 (carboy)^c^ | 250 | 263 ± 1 | 5.1
August 27, 2009 | September 30, 2009 (carboy)^c^ | 500 | 522 ± 10 | 4.3
August 27, 2009 | September 30, 2009 (carboy)^c^ | 1,000 | 1,020 ± 50 | 2.2
August 27, 2009 | September 30, 2009 (carboy)^c^ | 2,000 | 1,780 ± 240 | −10.8

NA = not applicable.

^a^ Average of triplicate analysis.

^b^ Animal room sample from the formulation remaining in the drinking water bottle.

^c^ Animal room sample from the formulation collected from the carboy.

^d^ Duplicate sample analyzed with a precision of duplicates value of 0.96.

^e^ Duplicate sample analyzed with a precision of duplicates value of 1.0.

Table A-4 Results of Analyses of Dose Formulations Administered to Mice in the Three-month Study of Sodium Tungstate Dihydrate

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration (mg/L)^a^ | Difference from Target (%)
May 11, 2009 | May 12, 2009 | 125 | 118 ± 9 | −5.6
May 11, 2009 | May 12, 2009 | 250 | 257 ± 2 | 2.7
May 11, 2009 | May 12, 2009 | 500 | 511 ± 12 | 2.2
May 11, 2009 | May 12, 2009 | 1,000 | 1,070 ± 20 | 6.7
May 11, 2009 | May 12, 2009 | 2,000 | 2,200 ± 10 | 10.0
May 11, 2009 | June 25, 2009 (bottle)^b^ | 125 | 123 ± 2 | −1.9
May 11, 2009 | June 25, 2009 (bottle)^b^ | 250 | 263 ± 3 | 5.1
May 11, 2009 | June 25, 2009 (bottle)^b^ | 500 | 508 ± 3 | 1.7
May 11, 2009 | June 25, 2009 (bottle)^b^ | 1,000 | 1,050 ± 10 | 4.7
May 11, 2009 | June 25, 2009 (bottle)^b^ | 2,000 | 2,140 ± 30 | 7.0
May 11, 2009 | June 25, 2009 (carboy)^c^ | 125 | 128 ± 9 | 2.7
May 11, 2009 | June 25, 2009 (carboy)^c^ | 250 | 269 ± 5 | 7.7
May 11, 2009 | June 25, 2009 (carboy)^c^ | 500 | 530 ± 5 | 6.0
May 11, 2009 | June 25, 2009 (carboy)^c^ | 1,000 | 1,090 ± 20 | 9.3
May 11, 2009 | June 25, 2009 (carboy)^c^ | 2,000 | 2,190 ± 50 | 9.3
June 5, 2009 | June 16, 2009 | 125 | 123 ± 3 | −1.6
June 5, 2009 | June 16, 2009 | 250 | 243 ± 4 | −2.7
June 5, 2009 | June 16, 2009 | 500 | 494 ± 4 | −1.2
June 5, 2009 | June 16, 2009 | 1,000 | 1,000 ± NA^d^ | 0.0
June 5, 2009 | June 16, 2009 | 2,000 | 1,940 ± 40 | −3.2
June 5, 2009 | July 24, 2009 (bottle)^b^ | 125 | 127 ± 4 | 1.9
June 5, 2009 | July 24, 2009 (bottle)^b^ | 250 | 257 ± 1 | 2.9
June 5, 2009 | July 24, 2009 (bottle)^b^ | 500 | 513 ± 18 | 2.6
June 5, 2009 | July 24, 2009 (bottle)^b^ | 1,000 | 1,060 ± 0 | 6.0
June 5, 2009 | July 24, 2009 (bottle)^b^ | 2,000 | 2,100 ± 10 | 5.0
June 5, 2009 | July 24, 2009 (carboy)^c^ | 125 | 128 ± 4 | 2.1
June 5, 2009 | July 24, 2009 (carboy)^c^ | 250 | 265 ± 7 | 5.9
June 5, 2009 | July 24, 2009 (carboy)^c^ | 500 | 537 ± 12 | 7.3
June 5, 2009 | July 24, 2009 (carboy)^c^ | 1,000 | 1,100 ± 20 | 9.7
June 5, 2009 | July 24, 2009 (carboy)^c^ | 2,000 | 2,110 ± 30 | 5.5
July 31, 2009 | August 3, 2009 | 125 | 118 ± 7 | −5.6
July 31, 2009 | August 3, 2009 | 250 | 254 ± 4 | 1.6
July 31, 2009 | August 3, 2009 | 500 | 510 ± 13 | 2.0
July 31, 2009 | August 3, 2009 | 1,000 | 1,010 ± 80 | 1.3
July 31, 2009 | August 3, 2009 | 2,000 | 1,950 ± 170 | −2.5
July 31, 2009 | September 1, 2009 (bottles, males)^b^ | 125 | 115 ± 6 | −8.0
July 31, 2009 | September 1, 2009 (bottles, males)^b^ | 250 | 239 ± 5 | −4.3
July 31, 2009 | September 1, 2009 (bottles, males)^b^ | 500 | 486 ± 8 | −2.7
July 31, 2009 | September 1, 2009 (bottles, males)^b^ | 1,000 | 981 ± 17 | −1.9
July 31, 2009 | September 1, 2009 (bottles, males)^b^ | 2,000 | 1,850 ± 80 | −7.7
July 31, 2009 | September 1, 2009 (bottles, females)^b^ | 125 | 109 ± 7 | −12.8
July 31, 2009 | September 1, 2009 (bottles, females)^b^ | 250 | 220 ± 5 | −12.0
July 31, 2009 | September 1, 2009 (bottles, females)^b^ | 500 | 456 ± 17 | −8.8
July 31, 2009 | September 1, 2009 (bottles, females)^b^ | 1,000 | 901 ± 6 | −9.9
July 31, 2009 | September 1, 2009 (bottles, females)^b^ | 2,000 | 1,770 ± 30 | −11.3
July 31, 2009 | September 1, 2009 (carboy)^c^ | 125 | 112 ± 3 | −10.1
July 31, 2009 | September 1, 2009 (carboy)^c^ | 250 | 241 ± 2 | −3.7
July 31, 2009 | September 1, 2009 (carboy)^c^ | 500 | 494 ± 5 | −1.3
July 31, 2009 | September 1, 2009 (carboy)^c^ | 1,000 | 1,000 ± 10 | 0.4
July 31, 2009 | September 1, 2009 (carboy)^c^ | 2,000 | 1,920 ± 60 | −4.0

^a^ Average of triplicate analysis.

^b^ Animal room sample from the formulation remaining in the drinking water bottle.

^c^ Animal room sample from the formulation collected from the carboy.

^d^ Duplicate sample analyzed with a precision of duplicates value of 0.96.

Table A-5 Results of Analyses of Dose Formulations Administered to Rats in the Perinatal and Two-year Study of Sodium Tungstate Dihydrate

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration (mg/L)^a^ | Difference from Target (%)
December 12, 2011 | December 15, 2011 | 250 | 246 ± 6 / 247 ± 2 | −1.7 / −1.1
December 12, 2011 | December 15, 2011 | 500 | 495 ± 3 / 483 ± 13 | −0.9 / −3.3
December 12, 2011 | December 15, 2011 | 1,000 | 963 ± 10 / 945 ± 17 | −3.7 / −5.5
December 12, 2011 | January 19, 2012^b^ (bottle) | 250 | 236 ± 6 | −5.7
December 12, 2011 | January 19, 2012^b^ (bottle) | 500 | 486 ± 2 | −2.8
December 12, 2011 | January 19, 2012^b^ (bottle) | 1,000 | 998 ± 13 | −0.2
December 12, 2011 | January 19, 2012^c^ (carboy) | 250 | 239 ± 7 | −4.3
December 12, 2011 | January 19, 2012^c^ (carboy) | 500 | 485 ± 3 | −3.1
December 12, 2011 | January 19, 2012^c^ (carboy) | 1,000 | 967 ± 6 | −3.3
January 5, 2012 | January 6, 2012 | 250 | 238 ± 10 / 243 ± 5 | −4.8 / −2.7
January 5, 2012 | January 6, 2012 | 500 | 473 ± 28 / 471 ± 24 | −5.3 / −5.7
January 5, 2012 | January 6, 2012 | 1,000 | 918 ± 57 / 960 ± 32 | −8.2 / −4.0
March 29, 2012 | March 29, 2012 | 250 | 245 ± 1 / 238 ± 3 | −2.0 / −4.7
March 29, 2012 | March 29, 2012 | 500 | 480 ± 3 / 479 ± 1 | −4.1 / −4.1
March 29, 2012 | March 29, 2012 | 1,000 | 957 ± 3 / 962 ± 3 | −4.3 / −3.8
May 22, 2012 | May 22, 2012 | 250 | 242 ± 4 / 242 ± 1 | −3.1 / −3.2
May 22, 2012 | May 22, 2012 | 500 | 490 ± 9 / 477 ± 7 | −2.0 / −4.6
May 22, 2012 | May 22, 2012 | 1,000 | 958 ± 3 / 957 ± 16 | −4.2 / −4.3
August 15, 2012 | August 20, 2012 | 250 | 236 ± 11 / 249 ± 1 | −5.6 / −0.4
August 15, 2012 | August 20, 2012 | 500 | 508 ± 0 / 504 ± 8 | 1.6 / 0.9
August 15, 2012 | August 20, 2012 | 1,000 | 997 ± 13 / 1,000 ± 10 | −0.3 / 0.0
August 15, 2012 | September 25, 2012^b^ (bottle) | 250 | 233 ± 7 | −6.7
August 15, 2012 | September 25, 2012^b^ (bottle) | 500 | 480 ± 8 | −4.1
August 15, 2012 | September 25, 2012^b^ (bottle) | 1,000 | 1,000 ± 20 | 0.0
August 15, 2012 | September 25, 2012^c^ (carboy) | 250 | 240 ± 8 | −4.1
August 15, 2012 | September 25, 2012^c^ (carboy) | 500 | 498 ± 0 | −0.4
August 15, 2012 | September 25, 2012^c^ (carboy) | 1,000 | 1,010 ± 10 | 0.7
October 11, 2012 | October 14, 2012 | 250 | 237 ± 15 / 256 ± 6 | −5.1 / 2.4
October 11, 2012 | October 14, 2012 | 500 | 490 ± 5 / 499 ± 4 | −1.9 / −0.3
October 11, 2012 | October 14, 2012 | 1,000 | 998 ± 3 / 1,050 ± 20 | −0.2 / 5.3
December 4, 2012 | December 6, 2012 | 250 | 240 ± 10 / 253 ± 3 | −4.0 / 1.1
December 4, 2012 | December 6, 2012 | 500 | 515 ± 8 / 538 ± 6 | 3.1 / 7.5
December 4, 2012 | December 6, 2012 | 1,000 | 1,050 ± 20 / 1,060 ± 10 | 5.0 / 5.7
February 26, 2013 | February 27, 2013 | 250 | 231 ± 8 / 238 ± 3 | −7.6 / −4.9
February 26, 2013 | February 27, 2013 | 500 | 478 ± 3 / 476 ± 7 | −4.5 / 4.8
February 26, 2013 | February 27, 2013 | 1,000 | 970 ± 22 / 950 ± 17 | −3.0 / −5.0
February 26, 2013 | April 9, 2013^b^ (bottle) | 250 | 233 ± 1 | −6.7
February 26, 2013 | April 9, 2013^b^ (bottle) | 500 | 482 ± 3 | −3.7
February 26, 2013 | April 9, 2013^b^ (bottle) | 1,000 | 953 ± 18 | −4.7
February 26, 2013 | April 9, 2013^c^ (carboy) | 250 | 241 ± 1 | −3.6
February 26, 2013 | April 9, 2013^c^ (carboy) | 500 | 468 ± 3 | −6.5
February 26, 2013 | April 9, 2013^c^ (carboy) | 1,000 | 945 ± 18 | −5.5
April 25, 2013 | April 26, 2013 | 250 | 240 ± 5 / 250 ± 7 | −4.1 / −0.1
April 25, 2013 | April 26, 2013 | 500 | 527 ± 23 / 494 ± 17 | 5.4 / −1.3
April 25, 2013 | April 26, 2013 | 1,000 | 995 ± 9 / 988 ± 6 | −0.5 / −1.2
July 16, 2013 | July 18. 2013 | 250 | 258 ± 10 / 240 ± 14 | 3.1 / −4.0
July 16, 2013 | July 18. 2013 | 500 | 479 ± 17 / 509 ± 21 | −4.1 / 1.7
July 16, 2013 | July 18. 2013 | 1,000 | 955 ± 71 / 970 ± 10 | −4.5 / −3.0
September 10, 2013 | September 14, 2013 | 250 | 228 ± 5 / 227 ± 6 | −8.9 / −9.1
September 10, 2013 | September 14, 2013 | 500 | 454 ± 8 / 501 ± 23 | −9.1 / 0.3
September 10, 2013 | September 14, 2013 | 1,000 | 1,090 ± 20 / 1,080 ± 0 | 8.7 / 8.0
September 10, 2013 | October 23, 2013^b^ (bottle) | 250 | 228 ± 12 | −8.8
September 10, 2013 | October 23, 2013^b^ (bottle) | 500 | 491 ± 5 | −1.8
September 10, 2013 | October 23, 2013^b^ (bottle) | 1,000 | 1,070 ± 10 | 6.7
September 10, 2013 | October 23, 2013^c^ (carboy) | 250 | 246 ± 4 | −1.7
September 10, 2013 | October 23, 2013^c^ (carboy) | 500 | 485 ± 16 | −2.9
September 10, 2013 | October 23, 2013^c^ (carboy) | 1,000 | 1,060 ± 30 | 6.0
December 4, 2013 | December 6, 2013 | 250 | 232 ± 9 / 256 ± 12 | −7.3 / 2.5
December 4, 2013 | December 6, 2013 | 500 | 495 ± 8 / 480 ± 21 | −1.1 / −4.1
December 4, 2013 | December 6, 2013 | 1,000 | 973 ± 13 / 900 ± 69 | −2.7 / −10.0

Values on either side of the / represent multiple formulations of the same dose prepared on that date.

^a^ Average of triplicate analysis.

^b^ Animal room sample from the formulation remaining in the drinking water bottle.

^c^ Animal room sample from the formulation collected from the carboy.

Table A-6 Results of Analyses of Dose Formulations Administered to Mice in the Two-year Study of Sodium Tungstate Dihydrate

Date Prepared | Date Analyzed | Target Concentration (mg/L) | Determined Concentration (mg/L)^a^ | Difference from Target (%)
January 5, 2012 | January 6, 2012 | 500 | 473 ± 28 / 471 ± 24 | −5.3 / −5.7
January 5, 2012 | January 6, 2012 | 1,000 | 918 ± 57 / 960 ± 32 | −8.2 / −4.0
January 5, 2012 | January 6, 2012 | 2,000 | 1,840 ± 60 | −8.2
January 5, 2012 | February 16, 2012^b^ (bottle) | 500 | 476 ± 26 | −4.7
January 5, 2012 | February 16, 2012^b^ (bottle) | 1,000 | 938 ± 57 | −6.2
January 5, 2012 | February 16, 2012^b^ (bottle) | 2,000 | 2,020 ± 30 | 1.0
January 5, 2012 | February 16, 2012^c^ (carboy) | 500 | 456 ± 30 | −8.8
January 5, 2012 | February 16, 2012^c^ (carboy) | 1,000 | 987 ± 32 | −1.3
January 5, 2012 | February 16, 2012^c^ (carboy) | 2,000 | 2,030 ± 90 | 1.7
March 29, 2012 | March 29, 2012 | 500 | 480 ± 3 / 479 ± 1 | −4.1 / −4.1
March 29, 2012 | March 29, 2012 | 1,000 | 957 ± 3 / 962 ± 3 | −4.3 / −3.8
March 29, 2012 | March 29, 2012 | 2,000 | 1,830 ± 40 | −8.7
May 22, 2012 | May 22, 2012 | 500 | 490 ± 9 / 477 ± 7 | −2.0 / −4.6
May 22, 2012 | May 22, 2012 | 1,000 | 958 ± 3 / 957 ± 16 | −4.2 / −4.3
May 22, 2012 | May 22, 2012 | 2,000 | 1,940 ± 10 | −3.0
August 15, 2012 | August 20, 2012 | 500 | 508 ± 0 / 504 ± 8 | 1.6 / 0.9
August 15, 2012 | August 20, 2012 | 1,000 | 997 ± 13 / 1,000 ± 10 | −0.3 / 0.0
August 15, 2012 | August 20, 2012 | 2,000 | 1,980 ± 10 | −0.8
August 15, 2012 | September 25, 2012^b^ (bottle) | 500 | 494 ± 22 | −1.3
August 15, 2012 | September 25, 2012^b^ (bottle) | 1,000 | 1,020 ± 10 | 2.0
August 15, 2012 | September 25, 2012^b^ (bottle) | 2,000 | 2,070 ± 20 | 3.7
August 15, 2012 | September 25, 2012^c^ (carboy) | 500 | 529 ± 4 | 5.9
August 15, 2012 | September 25, 2012^c^ (carboy) | 1,000 | NA^d^ | NA^d^
August 15, 2012 | September 25, 2012^c^ (carboy) | 2,000 | 2,090 ± 30 | 4.7
October 11, 2012 | October 14, 2012 | 500 | 490 ± 5 / 499 ± 4 | −1.9 / −0.3
October 11, 2012 | October 14, 2012 | 1,000 | 998 ± 3 / 1,050 ± 20 | −0.2 / 5.3
October 11, 2012 | October 14, 2012 | 2,000 | 2,110 ± 30 | 5.7
December 4, 2012 | December 6, 2012 | 500 | 515 ± 8 / 538 ± 6 | 3.1 / 7.5
December 4, 2012 | December 6, 2012 | 1,000 | 1,050 ± 20 / 1,060 ± 10 | 5.0 / 5.7
December 4, 2012 | December 6, 2012 | 2,000 | 2,060 ± 30 | 3.2
February 26, 2013 | February 27, 2013 | 500 | 478 ± 3 / 476 ± 7 | −4.5 / −4.8
February 26, 2013 | February 27, 2013 | 1,000 | 970 ± 22 / 950 ± 17 | −3.0 / −5.0
February 26, 2013 | February 27, 2013 | 2,000 | 1,890 ± 10 | −5.3
February 26, 2013 | April 9, 2013^b^ (bottle) | 500 | 453 ± 16 | −9.5
February 26, 2013 | April 9, 2013^b^ (bottle) | 1,000 | 915 ± 13 | −8.5
February 26, 2013 | April 9, 2013^b^ (bottle) | 2,000 | 1,900 ± 20 | −5.0
February 26, 2013 | April 9, 2013^c^ (carboy) | 500 | 468 ± 3 | −6.5
February 26, 2013 | April 9, 2013^c^ (carboy) | 1,000 | 937 ± 10 | −6.3
February 26, 2013 | April 9, 2013^c^ (carboy) | 2,000 | 1,880 ± 20 | −5.8
April 25, 2013 | April 26, 2013 | 500 | 527 ± 23 / 494 ± 17 | 5.4 / −1.3
April 25, 2013 | April 26, 2013 | 1,000 | 995 ± 9 / 988 ± 6 | −0.5 / −1.2
April 25, 2013 | April 26, 2013 | 2,000 | 1,900 ± 10 | −5.2
July 16, 2013 | July 18, 2013 | 500 | 479 ± 17 / 509 ± 21 | −4.1 / 1.7
July 16, 2013 | July 18, 2013 | 1,000 | 955 ± 71 / 970 ± 10 | −4.5 / −3.0
July 16, 2013 | July 18, 2013 | 2,000 | 2,000 ± 70 | 0.2
September 10, 2013 | September 14, 2013 | 500 | 454 ± 8 / 501 ± 23 | −9.1 / 0.3
September 10, 2013 | September 14, 2013 | 1,000 | 1,090 ± 20 / 1,080 ± 0 | 8.7 / 8.0
September 10, 2013 | September 14, 2013 | 2,000 | 2,150 ± 100 | 7.5
September 10, 2013 | October 23, 2013^b^ (bottle) | 500 | 503 ± 7 | 0.5
September 10, 2013 | October 23, 2013^b^ (bottle) | 1,000 | 1,040 ± 10 | 3.7
September 10, 2013 | October 23, 2013^b^ (bottle) | 2,000 | 2,090 ± 10 | 4.5
September 10, 2013 | October 23, 2013^c^ (carboy) | 500 | 485 ± 16 | −2.9
September 10, 2013 | October 23, 2013^c^ (carboy) | 1,000 | 1,060 ± 30 | 6.0
September 10, 2013 | October 23, 2013^c^ (carboy) | 2,000 | 1,980 ± 30 | −0.8
December 4, 2013 | December 6, 2013 | 500 | 495 ± 8 / 480 ± 21 | −1.1 / −4.1
December 4, 2013 | December 6, 2013 | 1,000 | 973 ± 13 / 900 ± 69 | −2.7 / −10.0
December 4, 2013 | December 6, 2013 | 2,000 | 1,910 ± 30 | −4.5

Values on either side of the / represent multiple formulations of the same dose prepared on that date.

NA = not analyzed.

^a^ Average of triplicate analysis.

^b^ Animal room sample from the formulation remaining in the drinking water bottle.

^c^ Animal room sample from the formulation collected from the carboy.

^d^ Sample not collected from carboy.

Figure A-1

Infrared Absorption Spectrum of Sodium Tungstate Dihydrate