# Revision Notice

Errors were identified in the NTP Technical Report on the Toxicology and Carcinogenesis Studies of Perfluorooctanoic Acid (CASRN 335-67-1) Administered in Feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats (Technical Report 598). For the uterine findings, changes were made to the number of animals in the 0/1,000 ppm group with a neoplasm (overall rates) and the number of litters with animals with a neoplasm (litter rates). One animal with a squamous cell carcinoma in the 0/1,000 ppm group was inadvertently combined in the adenocarcinoma analysis of the extended evaluation. The number of animals examined during the standard, extended, and standard or extended (combined) evaluations was also corrected in the 0/300, 0/1,000, and 300/1,000 ppm groups. Due to these corrections in the incidence data, statistical analysis was rerun, and the Rao-Scott-adjusted Poly-3 test p values were updated for all exposure groups. As a result, the trend tests for uterine adenocarcinoma are no longer statistically significant (p > 0.05) for the extended and the standard or extended (combined) evaluations. In addition, the pairwise comparisons of adenocarcinoma incidence between the control and the 0/1,000 ppm groups are now p = 0.05 for the extended and the standard or extended (combined) evaluations. The original conclusion that the higher incidence of uterine adenocarcinoma may have been related to PFOA exposure (equivocal evidence) is not changed. These corrections are described in detail in Appendix F. [February 1, 2023]