# Overview

The per/polyfluorinated alkyl substances (PFAS) class was nominated to the National Toxicology Program (NTP) by the U.S. Environmental Protection Agency for a variety of in vitro and in vivo toxicity assessments. These included evaluation of the toxicokinetics of seven PFAS chemicals after a single dose in rats; toxicity comparisons of seven PFAS chemicals in 28-day rat studies; and in vitro class evaluations of potential neurotoxicity, mitochondrial toxicity, and immunotoxicity, with a follow-up in vivo immunotoxicity study on perfluorodecanoic acid.

In addition to the above studies, an assessment of perinatal (gestational and lactational) perfluorooctanoic acid exposure on chronic toxicity and carcinogenicity was evaluated in rats. These studies are presented in this Technical Report.

As the PFAS class continues to expand with new uses and replacements, NTP continues to assess the potential toxicity of these chemicals through a variety of methods, including in silico, in vitro, and in vivo studies.