# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8925

DOI: https://doi.org/10.22427/NTP-TR-598

Report Series: NTP Technical Report Series

Report Series Number: 598

Official citation: National Toxicology Program (NTP). 2023. NTP technical report on the toxicology and carcinogenesis studies of perfluorooctanoic acid (CASRN 335-67-1) administered in feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats (revised). Research Triangle Park, NC: National Toxicology Program. Technical Report 598.