# Peer Review

The members of the Peer Review Panel who evaluated the draft NTP Technical Report on the Toxicology and Carcinogenesis Studies of Perfluorooctanoic Acid (CASRN 335-67-1) Administered in Feed to Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats on December 12, 2019, are listed below. Panel members served as independent scientists, not as representatives of any institution, company, or governmental agency. A summary of the Peer Review Panel’s comments is provided in Appendix D.

In this capacity, panel members had five major responsibilities in reviewing the NTP studies:

- to ascertain that all relevant literature data have been adequately cited and interpreted,
- to determine if the design and conditions of the NTP studies were appropriate,
- to ensure that the Technical Report presents the experimental results and conclusions fully and clearly,
- to judge the significance of the experimental results by scientific criteria, and
- to assess the evaluation of the evidence of carcinogenic activity and other observed toxic responses.

## Peer Reviewers

- Russell Cattley, V.M.D., Ph.D., Chairperson
  Auburn University
  Auburn, Alabama, USA
- Michael R. Elwell, D.V.M., Ph.D.
  APEX TOXPATH, LLC
  Apex, North Carolina, USA
- Wendy Halpern, D.V.M., Ph.D.
  Genentech, Inc.
  San Francisco, California, USA
- Gabriele Ludewig, Ph.D.
  University of Iowa
  Iowa City, Iowa, USA
- Kristini Miles, Ph.D.
  Venture Chemical Consulting LLC
  Atlanta, Georgia, USA