# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  C.R. Blystone, Ph.D., Study Scientist
  R.A. Herbert, D.V.M., Ph.D., Co-Study Pathologist
  M.C. Cora, D.V.M.
  H.C. Cunny, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  G.K. Roberts, Ph.D.
  V.G. Robinson, M.S.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  A. Watson, Ph.D.
  K.L. Witt, M.S.
- Provided oversight for data management
  J.M. Fostel, Ph.D.
- Integrated Laboratory Systems, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  K.S. Janardhan, Ph.D., Co-Study Pathologist
- Coordinated NTP Pathology Peer Review for hearts from control Harlan Sprague Dawley rats (April 14, 2016)
  M. Jokinen, D.V.M.
- Coordinated NTP Pathology Working Group for 21-week and 2-year rats (June 14, 2017)
  E.T. Adams, D.V.M., Ph.D.
- Battelle, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  D.A. Contos, M.S.
  D.K. Gerken, D.V.M., Ph.D.
  M.J. Ryan, D.V.M., Ph.D.
  D.Y. Vasconcelos, D.V.M., Ph.D.
- Conducted prestart chemistry activities, dose formulations, and biological sample chemistry analyses
  S.W. Graves, B.S., Principal Investigator
  B.L. Burback, Ph.D.
  D.A. Contos, M.S.
  T.A. Cristy, B.A.
  J. Pierfelice, B.S.
  E.M. Snyder, Ph.D.
  N.L. South, B.S.
- Pathology Associates International, Charles River Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review
  J. Hoane, D.V.M.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review
  A.E. Brix, D.V.M., Ph.D.
  T.A. Crabbs, D.V.M.
- Social & Scientific Systems, Inc., Research Triangle Park, North Carolina, USA
  Provided statistical analyses
  S. McBride, Ph.D., Principal Investigator
  C. Co, M.S.
  J. Krause, Ph.D.
  Y.I. Lu, M.S.