# References

1 United States Environmental Protection Agency (USEPA). Technical fact sheet – Perfluorooctane sulfonate (PFOS) and perfluorooctanoic acid (PFOA). Washington, DC: U.S. EPA, Office of Land and Emergency Management; 2017. EPA/505/F-17/001. https://www.epa.gov/sites/production/files/2017-12/documents/ffrrofactsheet_contaminants_pfos_pfoa_11-20-17_508_0.pdf
2 PubChem. PubChem Compound Database Summary: Perfluorooctanoic acid. Bethesda, MD: National Library of Medicine, National Center for Biotechnology Information; 2019. https://pubchem.ncbi.nlm.nih.gov/compound/9554 [Accessed: March 16, 2019]
3 Begley TH White K Honigfort P Twaroski ML Neches R Walker RA Perfluorochemicals: potential sources of and migration from food packaging. Food Addit Contam. 2005; 22(10):1023–1031. 10.1080/02652030500183474 16227186
4 Butt CM Muir DC Mabury SA Biotransformation pathways of fluorotelomer-based polyfluoroalkyl substances: A review. Environ Toxicol Chem. 2014; 33(2):243–267. 10.1002/etc.2407 24114778
5 National Health and Nutrition Examination Survey (NHANES). Fourth national report on human exposure to environmental chemicals. Volume 1. Atlanta, GA: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention; 2019. https://www.cdc.gov/exposurereport/pdf/FourthReport_UpdatedTables_Volume1_Jan2019-508.pdf
6 Steenland K Tinker S Frisbee S Ducatman A Vaccarino V Association of perfluorooctanoic acid and perfluorooctane sulfonate with serum lipids among adults living near a chemical plant. Am J Epidemiol. 2009; 170(10):1268–1278. 10.1093/aje/kwp279 19846564
7 Olsen GW Burris JM Burlew MM Mandel JH Epidemiologic assessment of worker serum perfluorooctanesulfonate (PFOS) and perfluorooctanoate (PFOA) concentrations and medical surveillance examinations. J Occup Environ Med. 2003; 45(3):260–270. 10.1097/01.jom.0000052958.59271.10 12661183
8 United States Environmental Protection Agency (USEPA). Drinking water health advisory for perfluorooctanoic acid (PFOA). Washington, DC: U.S. EPA, Office of Water; 2016. EPA/822/R-16/005. https://www.epa.gov/sites/production/files/2016-05/documents/pfoa_health_advisory_final_508.pdf
9 Lau C Thibodeaux JR Hanson RG Narotsky MG Rogers JM Lindstrom AB Strynar MJ Effects of perfluorooctanoic acid exposure during pregnancy in the mouse. Toxicol Sci. 2006; 90(2):510–518. 10.1093/toxsci/kfj105 16415327
10 Agency for Toxic Substances and Disease Registry (ATSDR). ATSDR’s Minimal Risk Levels (MRLs) and Environmental Media Evaluation Guides (EMEGs) for PFAS. Atlanta, GA: Centers for Disease Control and Prevention; 2018. https://www.atsdr.cdc.gov/pfas/mrl_pfas.html
11 Onishchenko N Fischer C Wan Ibrahim WN Negri S Spulber S Cottica D Ceccatelli S Prenatal exposure to PFOS or PFOA alters motor function in mice in a sex-related manner. Neurotox Res. 2011; 19(3):452–461. 10.1007/s12640-010-9200-4 20512442
12 Koskela A Finnila MA Korkalainen M Spulber S Koponen J Hakansson H Tuukkanen J Viluksela M Effects of developmental exposure to perfluorooctanoic acid (PFOA) on long bone morphology and bone cell differentiation. Toxicol Appl Pharmacol. 2016; 301:14–21. 10.1016/j.taap.2016.04.002 27068293
13 Minnesota Department of Health (MNDP). Toxicological summary for perfluorooctanoate. Health Risk Assessment Unit, Environmental Health Division; 2018. https://www.health.state.mn.us/communities/environment/risk/docs/guidance/gw/pfoa.pdf
14 New Jersey Department of Environmental Protection (NJDEP). Contaminants of emerging concern: Per- and polyfluoroalkyl substances. Trenton, NJ: Site Remediation Program; 2018. https://www.nj.gov/dep/srp/emerging-contaminants/
15 European Food Safety Authority (EFSA). Risk to human health related to the presence of perfluorooctane sulfonic acid and perfluorooctanoic acid in food. EFSA J. 2018; 16(12):e05194.10.2903/j.efsa.2018.5194 32625773
16 Kudo N Kawashima Y Toxicity and toxicokinetics of perfluorooctanoic acid in humans and animals. J Toxicol Sci. 2003; 28(2):49–57. 10.2131/jts.28.49 12820537
17 Dzierlenga A Robinson V Waidyanatha S DeVito M Eifrid M Gibbs S Granville C Blystone C Toxicokinetics of perfluorohexanoic acid (PFHxA), perfluorooctanoic acid (PFOA), and perfluorodecanoic acid (PFDA) in male and female Hsd:Sprague Dawley SD rats following intravenous or gavage administration. Toxicol Rep. 2019. Forthcoming. 10.1080/00498254.2019.1683776 31680603
18 Benskin JP De Silva AO Martin LJ Arsenault G McCrindle R Riddell N Mabury SA Martin JW Disposition of perfluorinated acid isomers in Sprague-Dawley rats; part 1: single dose. Environ Toxicol Chem. 2009; 28(3):542–554. 10.1897/08-239.1 18939892
19 Johnson J Gibson S Ober R Extent and route of excretion and tissue distribution of total carbon-14 in rats after a single IV dose of FC-95-^14^C. U.S. EPA docket AR-226-0006. Washington (DC): U.S. Environmental Protection Agency; 1979.
20 Kemper R Perfluorooctanoic acid: Toxicokinetics in the rat. Laboratory Project ID: Dupont-7473. U.S. EPA docket AR-226-1350. Washington (DC): U.S. Environmental Protection Agency; 2003.
21 Kim SJ Heo SH Lee DS Hwang IG Lee YB Cho HY Gender differences in pharmacokinetics and tissue distribution of 3 perfluoroalkyl and polyfluoroalkyl substances in rats. Food Chem Toxicol. 2016; 97:243–255. 10.1016/j.fct.2016.09.017 27637925
22 Ohmori K Kudo N Katayama K Kawashima Y Comparison of the toxicokinetics between perfluorocarboxylic acids with different carbon chain length. Toxicology. 2003; 184(2-3):135–140. 10.1016/S0300-483X(02)00573-5 12499116
23 Vanden Heuvel JP Kuslikis BI Shrago E Peterson RE Inhibition of long-chain acyl-CoA synthetase by the peroxisome proliferator perfluorodecanoic acid in rat hepatocytes. Biochem Pharmacol. 1991; 42(2):295–302. 10.1016/0006-2952(91)90716-I 1859447
24 Lou I Wambaugh JF Lau C Hanson RG Lindstrom AB Strynar MJ Zehr RD Setzer RW Barton HA Modeling single and repeated dose pharmacokinetics of PFOA in mice. Toxicol Sci. 2009; 107(2):331–341. 10.1093/toxsci/kfn234 19005225
25 Butenhoff JL Kennedy GL Jr Hinderliter PM Lieder PH Jung R Hansen KJ Gorman GS Noker PE Thomford PJ Pharmacokinetics of perfluorooctanoate in cynomolgus monkeys. Toxicol Sci. 2004; 82(2):394–406. 10.1093/toxsci/kfh302 15470233
26 Kudo N Katakura M Sato Y Kawashima Y Sex hormone-regulated renal transport of perfluorooctanoic acid. Chem Biol Interact. 2002; 139(3):301–316. 10.1016/S0009-2797(02)00006-6 11879818
27 Andersen ME Clewell HJ 3rd Tan YM Butenhoff JL Olsen GW Pharmacokinetic modeling of saturable, renal resorption of perfluoroalkylacids in monkeys—probing the determinants of long plasma half-lives. Toxicology. 2006; 227(1-2):156–164. 10.1016/j.tox.2006.08.004 16978759
28 Loccisano AE Campbell JL Jr Andersen ME Clewell HJ 3rd Evaluation and prediction of pharmacokinetics of PFOA and PFOS in the monkey and human using a PBPK model. Regul Toxicol Pharmacol. 2011; 59(1):157–175. 10.1016/j.yrtph.2010.12.004 21168463
29 Loccisano AE Campbell JL Jr Butenhoff JL Andersen ME Clewell HJ 3rd Comparison and evaluation of pharmacokinetics of PFOA and PFOS in the adult rat using a physiologically based pharmacokinetic model. Reprod Toxicol. 2012; 33(4):452–467. 10.1016/j.reprotox.2011.04.006 21565266
30 Loccisano AE Campbell JL Jr Butenhoff JL Andersen ME Clewell HJ 3rd Evaluation of placental and lactational pharmacokinetics of PFOA and PFOS in the pregnant, lactating, fetal and neonatal rat using a physiologically based pharmacokinetic model. Reprod Toxicol. 2012; 33(4):468–490. 10.1016/j.reprotox.2011.07.003 21872655
31 Loccisano AE Longnecker MP Campbell JL Jr Andersen ME Clewell HJ 3rd Development of PBPK models for PFOA and PFOS for human pregnancy and lactation life stages. J Toxicol Environ Health A. 2013; 76(1):25–57. 10.1080/15287394.2012.722523 23151209
32 Olsen GW Burris JM Ehresman DJ Froehlich JW Seacat AM Butenhoff JL Zobel LR Half-life of serum elimination of perfluorooctanesulfonate, perfluorohexanesulfonate, and perfluorooctanoate in retired fluorochemical production workers. Environ Health Perspect. 2007; 115(9):1298–1305. 10.1289/ehp.10009 17805419
33 Li Y Fletcher T Mucs D Scott K Lindh CH Tallving P Jakobsson K Half-lives of PFOS, PFHxS and PFOA after end of exposure to contaminated drinking water. Occup Environ Med. 2018; 75(1):46–51. 10.1136/oemed-2017-104651 29133598
34 Gomis MI Vestergren R Nilsson H Cousins IT Contribution of direct and indirect exposure to human serum concentrations of perfluorooctanoic acid in an occupationally exposed group of ski waxers. Environ Sci Technol. 2016; 50(13):7037–7046. 10.1021/acs.est.6b01477 27304840
35 Kudo N Suzuki-Nakajima E Mitsumoto A Kawashima Y Responses of the liver to perfluorinated fatty acids with different carbon chain length in male and female mice: in relation to induction of hepatomegaly, peroxisomal beta-oxidation and microsomal 1-acylglycerophosphocholine acyltransferase. Biol Pharm Bull. 2006; 29(9):1952–1957. 10.1248/bpb.29.1952 16946516
36 Kudo N Yamazaki T Sakamoto T Sunaga K Tsuda T Mitsumoto A Kawashima Y Effects of perfluorinated fatty acids with different carbon chain length on fatty acid profiles of hepatic lipids in mice. Biol Pharm Bull. 2011; 34(6):856–864. 10.1248/bpb.34.856 21628884
37 Permadi H Lundgren B Andersson K DePierre JW Effects of perfluoro fatty acids on xenobiotic-metabolizing enzymes, enzymes which detoxify reactive forms of oxygen and lipid peroxidation in mouse liver. Biochem Pharmacol. 1992; 44(6):1183–1191. 10.1016/0006-2952(92)90383-T 1417940
38 Vanden Heuvel JP Kuslikis BI Van Rafelghem MJ Peterson RE Tissue distribution, metabolism, and elimination of perfluorooctanoic acid in male and female rats. J Biochem Toxicol. 1991; 6(2):83–92. 10.1002/jbt.2570060202 1941903
39 Vanden Heuvel JP Thompson JT Frame SR Gillies PJ Differential activation of nuclear receptors by perfluorinated fatty acid analogs and natural fatty acids: A comparison of human, mouse, and rat peroxisome proliferator-activated receptor-α, -β, and –γ, liver X receptor-β, and retinoid X receptor-α. Toxicol Sci. 2006; 92(2):476–489. 10.1093/toxsci/kfl014 16731579
40 Wolf CJ Takacs ML Schmid JE Lau C Abbott BD Activation of mouse and human peroxisome proliferator-activated receptor alpha by perfluoroalkyl acids of different functional groups and chain lengths. Toxicol Sci. 2008; 106(1):162–171. 10.1093/toxsci/kfn166 18713766
41 Cheng X Klaassen CD Perfluorocarboxylic acids induce cytochrome P450 enzymes in mouse liver through activation of PPAR-alpha and CAR transcription factors. Toxicol Sci. 2008; 106(1):29–36. 10.1093/toxsci/kfn147 18648086
42 Rosen MB Lee JS Ren H Vallanat B Liu J Waalkes MP Abbott BD Lau C Corton JC Toxicogenomic dissection of the perfluorooctanoic acid transcript profile in mouse liver: evidence for the involvement of nuclear receptors PPAR alpha and CAR. Toxicol Sci. 2008; 103(1):46–56. 10.1093/toxsci/kfn025 18281256
43 Elcombe CR Elcombe BM Foster JR Farrar DG Jung R Chang SC Kennedy GL Butenhoff JL Hepatocellular hypertrophy and cell proliferation in Sprague-Dawley rats following dietary exposure to ammonium perfluorooctanoate occurs through increased activation of the xenosensor nuclear receptors PPARalpha and CAR/PXR. Arch Toxicol. 2010; 84(10):787–798. 10.1007/s00204-010-0572-2 20614104
44 Perkins RG Butenhoff JL Kennedy GL Jr Palazzolo MJ 13-week dietary toxicity study of ammonium perfluorooctanoate (APFO) in male rats. Drug Chem Toxicol. 2004; 27(4):361–378. 10.1081/DCT-200039773 15573472
45 Butenhoff J Costa G Elcombe C Farrar D Hansen K Iwai H Jung R Kennedy G Jr Lieder P Olsen G Toxicity of ammonium perfluorooctanoate in male cynomolgus monkeys after oral dosing for 6 months. Toxicol Sci. 2002; 69(1):244–257. 10.1093/toxsci/69.1.244 12215680
46 C8 Science Panel. C8 probable link reports: 2011-2012. 2012. http://www.c8sciencepanel.org/prob_link.html
47 Agency for Toxic Substances and Disease Registry (ATSDR). Toxicological profile for perfluoroalkyls: Draft for public comment. Atlanta, GA: Centers for Disease Control and Prevention; 2018. https://www.atsdr.cdc.gov/toxprofiles/TP.asp?id=1117&tid=237
48 Fenton SE Reiner JL Nakayama SF Delinsky AD Stanko JP Hines EP White SS Lindstrom AB Strynar MJ Petropoulou SE Analysis of PFOA in dosed CD-1 mice. Part 2. Disposition of PFOA in tissues and fluids from pregnant and lactating mice and their pups. Reprod Toxicol. 2009; 27(3-4):365–372. 10.1016/j.reprotox.2009.02.012 19429407
49 Butenhoff JL Kennedy GL Jr Frame SR O’Connor JC York RG The reproductive toxicology of ammonium perfluorooctanoate (APFO) in the rat. Toxicology. 2004; 196(1-2):95–116. 10.1016/j.tox.2003.11.005 15036760
50 Johnson PI Sutton P Atchley DS Koustas E Lam J Sen S Robinson KA Axelrad DA Woodruff TJ The Navigation Guide—Evidence-based medicine meets environmental health: systematic review of human evidence for PFOA effects on fetal growth. Environ Health Perspect. 2014; 122(10):1028–1039. 10.1289/ehp.1307893 24968388
51 Negri E Metruccio F Guercio V Tosti L Benfenati E Bonzi R La Vecchia C Moretto A Exposure to PFOA and PFOS and fetal growth: A critical merging of toxicological and epidemiological data. Crit Rev Toxicol. 2017; 47(6):482–508. 10.1080/10408444.2016.1271972 28617200
52 Verner M-A Loccisano AE Morken N-H Yoon M Wu H McDougall R Maisonet M Marcus M Kishi R Miyashita C Associations of Perfluoroalkyl Substances (PFAS) with lower birth weight: an evaluation of potential confounding by glomerular filtration rate using a Physiologically Based Pharmacokinetic Model (PBPK). Environ Health Perspect. 2015; 123(12):1317–1324. 10.1289/ehp.1408837 26008903
53 Steenland K Barry V Savitz D Serum perfluorooctanoic acid and birthweight: an updated meta-analysis with bias analysis. Epidemiology. 2018; 29(6):765–776. 10.1097/EDE.0000000000000903 30063543
54 Rappazzo KM Coffman E Hines EP Exposure to perfluorinated alkyl substances and health outcomes in children: A systematic review of the epidemiologic literature. Int J Environ Res Public Health. 2017; 14(7). 10.3390/ijerph14070691 28654008
55 Loveless SE Hoban D Sykes G Frame SR Everds NE Evaluation of the immune system in rats and mice administered linear ammonium perfluorooctanoate. Toxicol Sci. 2008; 105(1):86–96. 10.1093/toxsci/kfn113 18559402
56 Yang Q Abedi-Valugerdi M Xie Y Zhao XY Moller G Nelson BD DePierre JW Potent suppression of the adaptive immune response in mice upon dietary exposure to the potent peroxisome proliferator, perfluorooctanoic acid. Int Immunopharmacol. 2002; 2(2-3):389–397. 10.1016/S1567-5769(01)00164-3 11811941
57 Yang Q Xie Y Alexson SE Nelson BD DePierre JW Involvement of the peroxisome proliferator-activated receptor alpha in the immunomodulation caused by peroxisome proliferators in mice. Biochem Pharmacol. 2002; 63(10):1893–1900. 10.1016/S0006-2952(02)00923-1 12034374
58 Yang Q Xie Y Depierre JW Effects of peroxisome proliferators on the thymus and spleen of mice. Clin Exp Immunol. 2000; 122(2):219–226. 10.1046/j.1365-2249.2000.01367.x 11091278
59 Dewitt JC Copeland CB Strynar MJ Luebke RW Perfluorooctanoic acid-induced immunomodulation in adult C57BL/6J or C57BL/6N female mice. Environ Health Perspect. 2008; 116(5):644–650. 10.1289/ehp.10896 18470313
60 DeWitt JC Williams WC Creech NJ Luebke RW Suppression of antigen-specific antibody responses in mice exposed to perfluorooctanoic acid: Role of PPARalpha and T- and B-cell targeting. J Immunotoxicol. 2016; 13(1):38–45. 10.3109/1547691X.2014.996682 25594567
61 Fairley KJ Purdy R Kearns S Anderson SE Meade B Exposure to the immunosuppressant, perfluorooctanoic acid, enhances the murine IgE and airway hyperreactivity response to ovalbumin. Toxicol Sci. 2007; 97(2):375–383. 10.1093/toxsci/kfm053 17369199
62 Ryu MH Jha A Ojo OO Mahood TH Basu S Detillieux KA Nikoobakht N Wong CS Loewen M Becker AB Chronic exposure to perfluorinated compounds: impact on airway hyperresponsiveness and inflammation. Am J Physiol. 2014; 307(10):L765–L774. 10.1152/ajplung.00100.2014 25217661
63 Grandjean P Andersen EW Budtz-Jørgensen E Nielsen F Mølbak K Weihe P Heilmann C Serum vaccine antibody concentrations in children exposed to perfluorinated compounds. JAMA. 2012; 307(4):391–397. 10.1001/jama.2011.2034 22274686
64 Grandjean P Heilmann C Weihe P Nielsen F Mogensen UB Timmermann A Budtz-Jørgensen E Estimated exposures to perfluorinated compounds in infancy predict attenuated vaccine antibody concentrations at age 5-years. J Immunotoxicol. 2017; 14(1):188–195. 10.1080/1547691X.2017.1360968 28805477
65 Grandjean P Heilmann C Weihe P Nielsen F Mogensen Ulla B Budtz-Jørgensen E Serum vaccine antibody concentrations in adolescents exposed to perfluorinated compounds. Environ Health Perspect. 2017; 125(7):077018. 10.1289/EHP275 28749778
66 Granum B Haug LS Namork E Stolevik SB Thomsen C Aaberge IS van Loveren H Lovik M Nygaard UC Pre-natal exposure to perfluoroalkyl substances may be associated with altered vaccine antibody levels and immune-related health outcomes in early childhood. J Immunotoxicol. 2013; 10(4):373–379. 10.3109/1547691X.2012.755580 23350954
67 Kielsen K Shamim Z Ryder LP Nielsen F Grandjean P Budtz-Jørgensen E Heilmann C Antibody response to booster vaccination with tetanus and diphtheria in adults exposed to perfluorinated alkylates. J Immunotoxicol. 2016; 13(2):270–273. 10.3109/1547691X.2015.1067259 26181512
68 Mogensen UB Grandjean P Heilmann C Nielsen F Weihe P Budtz-Jorgensen E Structural equation modeling of immunotoxicity associated with exposure to perfluorinated alkylates. Environ Health. 2015; 14:47. 10.1186/s12940-015-0032-9 26041029
69 Stein CR McGovern KJ Pajak AM Maglione PJ Wolff MS Perfluoroalkyl and polyfluoroalkyl substances and indicators of immune function in children aged 12-19 y: National Health and Nutrition Examination Survey. Pediatr Res. 2016; 79(2):348–357. 10.1038/pr.2015.213 26492286
70 Looker C Luster MI Calafat AM Johnson VJ Burleson GR Burleson FG Fletcher T Influenza vaccine response in adults exposed to perfluorooctanoate and perfluorooctanesulfonate. Toxicol Sci. 2014; 138(1):76–88. 10.1093/toxsci/kft269 24284791
71 National Toxicology Program (NTP). Monograph on immunotoxicity associated with exposure to perfluorooctanoic acid (PFOA) and perfluorooctane sulfonate (PFOS). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, Office of Health Assessment and Translation; 2016. https://ntp.niehs.nih.gov/ntp/ohat/pfoa_pfos/pfoa_pfosmonograph_508.pdf
72 Butenhoff JL Kennedy GL Jr Chang SC Olsen GW Chronic dietary toxicity and carcinogenicity study with ammonium perfluorooctanoate in Sprague-Dawley rats. Toxicology. 2012; 298(1-3):1–13. 10.1016/j.tox.2012.04.001 22531602
73 Hardisty JF Willson GA Brown WR McConnell EE Frame SR Gaylor DW Kennedy GL Butenhoff JL Pathology Working Group review and evaluation of proliferative lesions of mammary gland tissues in female rats fed ammonium perfluorooctanoate (APFO) in the diet for 2 years. Drug Chem Toxicol. 2010; 33(2):131–137. 10.3109/01480541003667610 20307141
74 Biegel LB Hurtt ME Frame SR O’Connor JC Cook JC Mechanisms of extrahepatic tumor induction by peroxisome proliferators in male CD rats. Toxicol Sci. 2001; 60(1):44–55. 10.1093/toxsci/60.1.44 11222872
75 Caverly Rae JM Frame SR Kennedy GL Butenhoff JL Chang S-C Pathology review of proliferative lesions of the exocrine pancreas in two chronic feeding studies in rats with ammonium perfluorooctanoate. Toxicol Rep. 2014; 1:85–91. 10.1016/j.toxrep.2014.04.005 28962229
76 Tilton SC Orner GA Benninghoff AD Carpenter HM Hendricks JD Pereira CB Williams DE Genomic profiling reveals an alternate mechanism for hepatic tumor promotion by perfluorooctanoic acid in rainbow trout. Environ Health Perspect. 2008; 116(8):1047–1055. 10.1289/ehp.11190 18709148
77 International Agency for Research on Cancer (IARC). IARC monographs on the evaluation of carcinogenic risks to humans. Some chemicals used as solvents and in polymer manufacture. Lyon, France: International Agency for Research on Cancer; 2017. https://monographs.iarc.fr/wp-content/uploads/2018/06/mono110.pdf
78 Takagi A Sai K Umemura T Hasegawa R Kurokawa Y Short-term exposure to the peroxisome proliferators, perfluorooctanoic acid and perfluorodecanoic acid, causes significant increase of 8-hydroxydeoxyguanosine in liver DNA of rats. Cancer Lett. 1991; 57(1):55–60. 10.1016/0304-3835(91)90063-N 2025879
79 Buhrke T Kibellus A Lampen A In vitro toxicological characterization of perfluorinated carboxylic acids with different carbon chain lengths. Toxicol Lett. 2013; 218(2):97–104. 10.1016/j.toxlet.2013.01.025 23391484
80 Fernandez Freire P Perez Martin JM Herrero O Peropadre A de la Pena E Hazen MJ In vitro assessment of the cytotoxic and mutagenic potential of perfluorooctanoic acid. Toxicol In Vitro. 2008; 22(5):1228–1233. 10.1016/j.tiv.2008.04.004 18499391
81 Yahia D Haruka I Kagashi Y Tsuda S 8-Hydroxy-2′-deoxyguanosine as a biomarker of oxidative DNA damage induced by perfluorinated compounds in TK6 cells. Environ Toxicol. 2016; 31(2):192–200. 10.1002/tox.22034 25113910
82 Yao X Zhong L Genotoxic risk and oxidative DNA damage in HepG2 cells exposed to perfluorooctanoic acid. Mutat Res. 2005; 587(1-2):38–44. 10.1016/j.mrgentox.2005.07.010 16219484
83 Wielsoe M Long M Ghisari M Bonefeld-Jorgensen EC Perfluoroalkylated substances (PFAS) affect oxidative stress biomarkers in vitro. Chemosphere. 2015; 129:239–245. 10.1016/j.chemosphere.2014.10.014 25455676
84 Florentin A Deblonde T Diguio N Hautemaniere A Hartemann P Impacts of two perfluorinated compounds (PFOS and PFOA) on human hepatoma cells: cytotoxicity but no genotoxicity? Int J Hyg Environ Health. 2011; 214(6):493–499. 10.1016/j.ijheh.2011.05.010 21676652
85 Jacquet N Maire MA Rast C Bonnard M Vasseur P Perfluorooctanoic acid (PFOA) acts as a tumor promoter on Syrian hamster embryo (SHE) cells. Environ Sci Pollut Res Int. 2011; 19(7):2537–2549. 10.1007/s11356-012-0968-z 22828883
86 Lindeman B Maass C Duale N Gutzkow KB Brunborg G Andreassen A Effects of per- and polyfluorinated compounds on adult rat testicular cells following in vitro exposure. Reprod Toxicol. 2012; 33(4):531–537. 10.1016/j.reprotox.2011.04.001 21530637
87 Butenhoff JL Kennedy GL Jung R Chang SC Evaluation of perfluorooctanoate for potential genotoxicity. Toxicol Rep. 2014; 1:252–270. 10.1016/j.toxrep.2014.05.012 28962243
88 National Toxicology Program (NTP). Toxicity studies of perfluorinated carboxylic acids (perfluorohexanoic acid, perfluorooctanoic acid, perfluorononanoic acid, and perfluorodecanoic acid) administered by gavage to Sprague Dawley (Hsd:Sprague Dawley SD) rats. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Institutes of Health; 2019. Toxicity Study Report No. 97 (in preparation).
89 Chhabra RS Bucher JR Haseman JK Elwell MR Kurtz PJ Carlton BD Comparative carcinogenicity of 5,5-diphenylhydantoin with or without perinatal exposure in rats and mice. Fundam Appl Toxicol. 1993; 21(2):174–186. 10.1006/faat.1993.1087 8405780
90 Chhabra RS Bucher JR Haseman JK Elwell MR Kurtz PJ Carlton BD Comparative carcinogenicity of polybrominated biphenyls with or without perinatal exposure in rats and mice. Fundam Appl Toxicol. 1993; 21(4):451–460. 10.1006/faat.1993.1121 8253298
91 Chhabra RS Eustis S Haseman JK Kurtz PJ Carlton BD Comparative carcinogenicity of ethylene thiourea with or without perinatal exposure in rats and mice. Fundam Appl Toxicol. 1992; 18(3):405–417. 10.1016/0272-0590(92)90139-9 1597265
92 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
93 Boorman G Montgomery C Jr Eustis S Wolfe M McConnell E Hardisty J Quality assurance in pathology for rodent carcinogenicity studies. In: Milman H Weisburger Eeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
94 McConnell EE Solleveld HA Swenberg JA Boorman GA Guidelines for combining neoplasms for evaluation of rodent carcinogenesis studies. J Natl Cancer Inst. 1986; 76(2):283–289. 3456066
95 Kaplan EL Meier P Nonparametric estimation from incomplete observations. J Am Stat Assoc. 1958; 53(282):457–481. 10.1080/01621459.1958.10501452
96 Cox DR Regression models and life‐tables. J R Stat Soc B. 1972; 34(2):187–202.
97 Bailer AJ Portier CJ Effects of treatment-induced mortality and tumor-induced mortality on tests for carcinogenicity in small samples. Biometrics. 1988; 44(2):417–431. 10.2307/2531856 3390507
98 Piegorsch W, Bailer A. Statistics for environmental biology and toxicology: Section 6.3.2. London, UK: Chapman and Hall; 1997.
99 Portier CJ Bailer AJ Testing for increased carcinogenicity using a survival-adjusted quantal response test. Fundam Appl Toxicol. 1989; 12(4):731–737. 10.1016/0272-0590(89)90004-3 2744275
100 Portier CJ Hedges JC Hoel DG Age-specific models of mortality and tumor onset for historical control animals in the National Toxicology Program’s carcinogenicity experiments. Cancer Res. 1986; 46(9):4372–4378. 3731095
101 Bieler GS Williams RL Ratio estimates, the delta method, and quantal response tests for increased carcinogenicity. Biometrics. 1993; 49(3):793–801. 10.2307/2532200 8241374
102 Nam JM A simple approximation for calculating sample sizes for detecting linear trend in proportions. Biometrics. 1987; 43(3):701–705. 10.2307/2532006 3663825
103 Rao JN Scott AJ A simple method for the analysis of clustered binary data. Biometrics. 1992; 48(2):577–585. 10.2307/2532311 1637980
104 Fung KY Krewski D Rao JN Scott AJ Tests for trend in developmental toxicity experiments with correlated binary data. Risk Anal. 1994; 14(4):639–648. 10.1111/j.1539-6924.1994.tb00277.x 7972964
105 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
106 Dixon W Massey FJJ Introduction to statistical analysis. New York: McGraw Hill Book Company, Inc.; 1957. 10.2307/2332898
107 Tukey J Exploratory Data Analysis. Reading (MA): Addison-Wesley; 1977. Easy summaries – numerical and graphical; p. 43–44.
108 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
109 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. 10.2307/2528930 5547548
110 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. 10.2307/2556164 5037867
111 Hommel G A stagewise rejective multiple test procedure based on a modified Bonferroni test. Biometrika. 1988; 75(2):383–386. 10.1093/biomet/75.2.383
112 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. 10.2307/2529789 884197
113 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. 10.2307/2531254 3719054
114 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
115 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145. 10.2307/2333011
116 Hsu JC The factor analytic approach to simultaneous inference in the general linear model. J Comput Graph Stat. 1992; 1(2):151–168.
117 Haseman JK Value of historical controls in the interpretation of rodent tumor data. Drug Inf J. 1992; 26(2):191–200. 10.1177/009286159202600210
118 Haseman JK Data analysis: statistical analysis and use of historical control data. Regul Toxicol Pharmacol. 1995; 21(1):52–59, discussion 81–56. 10.1006/rtph.1995.1009 7784636
119 Haseman JK Rao GN Effects of corn oil, time-related changes, and inter-laboratory variability on tumor occurrence in control Fischer 344 (F344/N) rats. Toxicol Pathol. 1992; 20(1):52–60. 10.1177/019262339202000107 1411131
120 Code of Federal Regulations (CFR). 21:Part 58.
121 Suttie A Masson R Schutten M Chapter 10, Endocrine pancreas. In: Suttie Aeditor. Boorman’s Pathology of the Rat. 2nd ed. Boston (MA): Academic Press; 2018. p. 107–122. 10.1016/B978-0-12-391448-4.00010-1
122 Weaver YM Ehresman DJ Butenhoff JL Hagenbuch B Roles of rat renal organic anion transporters in transporting perfluorinated carboxylates with different chain lengths. Toxicol Sci. 2010; 113(2):305–314. 10.1093/toxsci/kfp275 19915082
123 Ehresman DJ Froehlich JW Olsen GW Chang S-C Butenhoff JL Comparison of human whole blood, plasma, and serum matrices for the determination of perfluorooctanesulfonate (PFOS), perfluorooctanoate (PFOA), and other fluorochemicals. Environ Res. 2007; 103(2):176–184. 10.1016/j.envres.2006.06.008 16893538
124 Lilienthal H Dieter HH Holzer J Wilhelm M Recent experimental results of effects of perfluoroalkyl substances in laboratory animals - Relation to current regulations and guidance values. Int J Hyg Environ Health. 2017; 220(4):766–775. 10.1016/j.ijheh.2017.03.001 28286084
125 Post GB Cohn PD Cooper KR Perfluorooctanoic acid (PFOA), an emerging drinking water contaminant: A critical review of recent literature. Environ Res. 2012; 116:93–117. 10.1016/j.envres.2012.03.007 22560884
126 Rosen MB Das KP Rooney J Abbott B Lau C Corton JC PPARalpha-independent transcriptional targets of perfluoroalkyl acids revealed by transcript profiling. Toxicology. 2017; 387:95–107. 10.1016/j.tox.2017.05.013 28558994
127 Seacat AM Thomford PJ Hansen KJ Olsen GW Case MT Butenhoff JL Subchronic toxicity studies on perfluorooctanesulfonate potassium salt in cynomolgus monkeys. Toxicol Sci. 2002; 68(1):249–264. 10.1093/toxsci/68.1.249 12075127
128 Ennulat D Magid-Slav M Rehm S Tatsuoka KS Diagnostic performance of traditional hepatobiliary biomarkers of drug-induced liver injury in the rat. Toxicol Sci. 2010; 116(2):397–412. 10.1093/toxsci/kfq144 20466777
129 Thompson MB Bile acids in the assessment of hepatocellular function. Toxicol Pathol. 1996; 24(1):62–71. 10.1177/019262339602400109 8839282
130 Ennulat D Walker D Clemo F Magid-Slav M Ledieu D Graham M Botts S Boone L Effects of hepatic drug-metabolizing enzyme induction on clinical pathology parameters in animals and man. Toxicol Pathol. 2010; 38(5):810–828. 10.1177/0192623310374332 20585144
131 Hall A Elcombe C Foster J Harada T Kaufmann W Knippel A Küttler K Malarkey D Maronpot R Nishikawa A Liver hypertrophy: A review of adaptive (adverse and non-adverse) changes— Conclusions from the 3rd International ESTP Expert Workshop. Toxicol Pathol. 2012; 40(7):971–994. 10.1177/0192623312448935 22723046
132 Chen X Matthews J Zhou L Pelton P Liang Y Xu J Yang M Cryan E Rybczynski P Demarest K Improvement of dyslipidemia, insulin sensitivity, and energy balance by a peroxisome proliferator-activated receptor alpha agonist. Metabolism. 2008; 57(11):1516–1525. 10.1016/j.metabol.2008.06.005 18940388
133 Konig B Koch A Spielmann J Hilgenfeld C Stangl GI Eder K Activation of PPARalpha lowers synthesis and concentration of cholesterol by reduction of nuclear SREBP-2. Biochem Pharmacol. 2007; 73(4):574–585. 10.1016/j.bcp.2006.10.027 17126302
134 Walker D Tomlinson L Lipids. In: Kurtz DM Travlos GSeditors. The Clinical Chemistry of Laboratory Animals. Boca Raton (FL): CRC Press; 2018. p. 777–871.
135 Yan J Chen B Lu J Xie W Deciphering the roles of the constitutive androstane receptor in energy metabolism. Acta Pharmacol Sin. 2015; 36(1):62–70. 10.1038/aps.2014.102 25500869
136 Corton JC Peters JM Klaunig JE The PPARα-dependent rodent liver tumor response is not relevant to humans: addressing misconceptions. Arch Toxicol. 2018; 92(1):83–119. 10.1007/s00204-017-2094-7 29197930
137 Felter SP Foreman JE Boobis A Corton JC Doi AM Flowers L Goodman J Haber LT Jacobs A Klaunig JE Human relevance of rodent liver tumors: key insights from a Toxicology Forum workshop on nongenotoxic modes of action. Regul Toxicol Pharmacol. 2018; 92:1–7. 10.1016/j.yrtph.2017.11.003 29113941
138 National Toxicology Program (NTP). NTP historical controls report: All routes and vehicles - F344/N rats. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2013. https://ntp.niehs.nih.gov/ntp/historical_controls/ntp2000_2013/histcont2013_ratsf344_allroutes_508.pdf
139 National Toxicology Program (NTP). NTP historical controls report: All routes and vehicles - Wistar-Han rats. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2016. https://ntp.niehs.nih.gov/ntp/historical_controls/ntp2000_2016/aug-2016-hc-report-wh-rats-all-routes.pdf
140 Charles River Laboratories. Compilation of spontaneous neoplastic lesions and survival in Crl:CD (SD) rats from control groups. Wilmington, MA: Charles River Laboratories; 2013. https://www.criver.com/sites/default/files/Technical%20Resources/Compilation%20of%20Spontaneous%20Neoplastic%20Lesions%20and%20Survival%20in%20Crl-CD_SD_%20Rats%20From%20Control%20Groups%20-%20March%202013.pdf
141 Giménez-Bastida JA Surma M Zieliński H In vitro evaluation of the cytotoxicity and modulation of mechanisms associated with inflammation induced by perfluorooctanesulfonate and perfluorooctanoic acid in human colon myofibroblasts CCD-18Co. Toxicol In Vitro. 2015; 29(7):1683–1691. 10.1016/j.tiv.2015.07.001 26142696
142 Shankar A Xiao J Ducatman A Perfluoroalkyl chemicals and chronic kidney disease in US adults. Am J Epidemiol. 2011; 174(8):893–900. 10.1093/aje/kwr171 21873601
143 Dhingra R Winquist A Darrow LA Klein M Steenland K A study of reverse causation: examining the associations of perfluorooctanoic acid serum levels with two outcomes. Environ Health Perspect. 2017; 125(3):416–421. 10.1289/EHP273 27529882
144 Anderson LM Predictive values of traditional animal bioassay studies for human perinatal carcinogenesis risk determination. Toxicol Appl Pharmacol. 2004; 199(2):162–174. 10.1016/j.taap.2004.02.008 15313588