# Conclusions

Under the conditions of these 2-year feed studies, there was clear evidence of carcinogenic activity^b^ of PFOA in male Hsd:Sprague Dawley^®^ SD^®^ rats based on the increased incidence of hepatocellular neoplasms (predominately hepatocellular adenomas) and increased incidence of acinar cell neoplasms (predominately acinar cell adenomas) of the pancreas. The additional effect of perinatal exposure in combination with postnatal exposure was uncertain and limited to the observation of hepatocellular carcinomas.

b See Explanation of Levels of Evidence of Carcinogenic Activity.

There was some evidence of carcinogenic activity of PFOA in female Hsd:Sprague Dawley^®^ SD^®^ rats based on the increased incidences of pancreatic acinar cell adenoma or adenocarcinoma (combined) neoplasms. The higher incidence of hepatocellular carcinomas and adenocarcinomas of the uterus may have been related to exposure. The combined perinatal and postweaning exposure was not observed to change the neoplastic or nonneoplastic response compared to the postweaning exposure alone in female rats.

Exposure to PFOA resulted in increased incidences of nonneoplastic lesions in the liver and pancreas of male rats and the liver, kidney, forestomach, and thyroid gland of female rats.