# Discussion

Perfluorooctanoic acid (PFOA) is a widespread contaminant and the second most prevalent per/polyfluoroalkyl substance (PFAS) measured in human plasma to date; second only to perfluorooctane sulfonic acid (PFOS). Its stability in the environment and long half-life in humans have led to decades of exposure, which is declining, but is still present despite removal from use. Exposure likely occurs throughout development, starting in utero. Previous studies in rats have identified the carcinogenic activity of PFOA, but in these studies exposures were started in young adult animals after critical periods of development.^72,74^ Due to the concern of widespread exposure occurring through multiple life stages, the National Toxicology Program (NTP) tested the hypothesis that additional exposure during the perinatal period (in utero and during lactation up to weaning) would increase the incidence of neoplasms or lead to the appearance of different neoplasm types. To test the hypothesis, groups of rats exposed during the perinatal period and after weaning were compared to groups with postweaning exposure only. Because female rats are known to have higher PFOA elimination rates than male rats, higher postweaning feed exposures of up to 1,000 ppm were provided to females. Exposure groups were analyzed by pairwise comparison to assess potential differences

In the current studies, exposure during the perinatal period was up to 300 ppm, which led to plasma concentrations of 74–75 μM in the dam on gestation day (GD) 18 and postnatal day (PND) 4. The concentrations were similar at different time periods (GD 18 versus PND 4), although feed consumption was higher during lactation compared to gestation. This could be due, in part, to lactational transfer from dams to pups. At 19 weeks of age, plasma concentrations were approximately 50 μM in the F_1_ females at a similar exposure concentration (i.e., 300 ppm). The lower concentrations are likely due to the differences in F_0_ feed consumption during gestation and lactation versus F_1_ nonpregnant females.

F_1_ exposure evaluations occurred on GD 18, PND 4, and at 19 weeks of age, and showed maternal transfer early in development and continued exposure at the later time periods. Fetuses pooled by litter had concentrations about a third of maternal plasma concentrations on GD 18, indicating some maternal transfer. Pooled whole pups had consistent concentrations between male and female pups indicating lactational transfer to the offspring early during postnatal development. No apparent sex differences were observed in the pups, which is consistent with previous reports that sex differences arise during puberty with increases in testosterone.^26^ At 19 weeks of age, male and female adult plasma and liver concentrations were consistent between groups that were and were not perinatally exposed. As expected, plasma concentrations were about 12-fold lower in females compared to males with a similar exposure (0/300 ppm). Exposure-adjusted (mg/kg/day) plasma concentrations decreased in males as exposure increased from 20 ppm up to 300 ppm. This is consistent with the hypothesized saturation of a kidney reabsorption pathway.^26,122^ Exposure-adjusted plasma concentrations in females at 19 weeks of age did not appear to change with exposure concentration.

In general, the rat plasma PFOA concentrations were considerably higher than those attained in the general human population, for which 2015–2016 NHANES data yield a geometric mean of 4 nM (95th percentile = 10 nM) in human sera.^5^ Human sera:plasma and sera:whole blood ratios are estimated to be 1:1 and 2:1, respectively.^123^ The rat plasma concentrations were marginally higher than concentrations measured in the NTP 28-day toxicity studies (57 μM) with administered doses of 100 mg/kg/day via gavage route of exposure.^88^

In the current studies, exposure during gestation and lactation up to 300 ppm (approximately 22 and approximately 46 mg/kg/day, respectively) resulted in minimal to no changes in body weight of the F_0_ dams and no effect on litter size or survival. Pup weights were at most 8% lower compared to the 0/0 ppm control group. These data are consistent with published feed studies in SD rats, which observed effects at 30 mg/kg/day in rats.^49^ However, with continued exposure, body weights of exposed groups were significantly lower compared to the 0/0 ppm control group.

At the interim evaluation, liver toxicity was observed in the PFOA-exposed male rats with no difference between groups with and without perinatal exposure; similar liver effects were observed in the PFOA-exposed female rats, but to a much lesser degree. In males, liver weights were increased and hepatocyte pigment (most likely lipofuscin), hepatocyte cytoplasmic alteration, hepatocyte hypertrophy, and hepatocyte necrosis were observed in the PFOA-exposed animals. The male portion of Study 1 was stopped because of reduced body weight and liver necrosis in males exposed to 150 or 300 ppm PFOA either perinatally and postweaning or postweaning alone. In female rats, liver weights were also increased, but the incidences of hepatocyte necrosis and hepatocyte hypertrophy were much lower compared to the males. These sex differences are likely in part due to the lower plasma concentrations in females compared to males.

In the NTP 28-day toxicity studies, PFOA activated PPARα and constitutive androstane receptor (CAR) in this animal model (Hsd:Sprague Dawley^®^ SD^®^ rats) as evident by increased expression of associated genes.^88^ At the 16-week interim necropsy in this 2-year study, liver acyl-CoA oxidase enzyme activities were elevated in male and female rats. The hepatocellular hypertrophy and cytoplasmic alteration are likely due to peroxisome proliferation, but may also be mediated through CAR activation or possibly other mechanisms.^45,124-127^ Mild increases (less than twofold) in the biomarkers of hepatocellular injury, ALT and SDH activity, correlated with the liver histopathology (necrosis and single cell death). In male rats, bile acid concentrations were increased in the higher dosed groups with a greater than twofold increase compared to the 0/0 ppm control group. Greater than twofold increases in bile acid concentrations are consistent with cholestasis, the causes of which include physical disruption of bile flow through the biliary system or perturbation of bile acid formation and excretion at the cellular level.^128,129^ ALP was mildly increased (less than twofold) in male and female rats. These increases may be due to cholestasis; however, mild increases in ALP activity (and ALT activity) are also associated with the administration of hepatic microsomal enzyme inducer compounds, including PPARα agonist, when the only histological finding is centrilobular hypertrophy.^128,130,131^ Additionally, these effects corresponded with large increases in the acyl-CoA oxidase activity in males compared to females. Similar to the observed liver toxicity, there were no differences in acyl-CoA oxidase activity between animals exposed perinatally and postweaning versus those only exposed after weaning.

Liver aromatase activity was not affected by PFOA exposure in females and males of Study 1, but there was a consistent twofold increase across postweaning exposure groups (20, 40, and 80 ppm) in males exposed to the lower concentrations in Study 2. This occurred in animals with and without perinatal exposure, with no obvious explanation for why this occurred in males of Study 2 and not in Study 1. Aromatase activity was measured to potentially understand the mechanism of Leydig cell neoplasms of the testis and other potentially endocrine-related effects; however, there was no increase in the incidence of Leydig cell neoplasms observed in this study. This may be due to differences in exposure concentrations among studies, as Leydig cell neoplasms were observed at a higher exposure of 300 ppm,^72,74^ or due to differences among rat stocks (Crl:COBS CD(SD)BR/Crl:CD BR (CD) versus Hsd:Sprague Dawley^®^ SD^®^).

Other clinical chemistry changes included increases in total protein (female only) and albumin concentrations, and decreases in total protein (male only), globulin, cholesterol (male only), and triglyceride concentrations. In general, these clinical chemistry changes were similar with and without perinatal exposure, but in females were of lesser magnitude or absent compared to the male rats. Albumin concentrations may have been elevated due to decreased water intake (supported by the increases in blood urea nitrogen) or as an acute phase protein in response to (liver) inflammation. Globulins are produced by the liver or lymphocytes (immunoglobulins), and it is not clear if PFOA caused a perturbation of hepatic or lymphocytic production or metabolism of these proteins. The decreases in lipid concentrations (cholesterol, triglycerides) are consistent with the known effects of PPARα activation on lipid metabolism, which includes increases in peroxisomal fatty acid β-oxidation and effects on lipid transport.^132-134^ CAR is also an important regulator of cholesterol homeostasis, and its activation may also be related to the observed lipid alterations.^135^ The various clinical chemistry changes at the 16-week interim are similar to those observed in the NTP 28-day PFOA study.^88^

In addition to the liver, increased incidences of thyroid gland hypertrophy were observed at the 16-week interim (male and female) and terminal evaluation (female) in the higher exposure groups compared to the control animals. This may be a compensatory effect related to decreased circulating total thyroxine and triiodothyronine hormone concentrations, which were observed in the NTP 28-day toxicity study.^88^ Increased submucosa inflammation of the glandular stomach was observed in the male postweaning exposure groups of 150 and 300 ppm at the 16-week interim, but not at lower exposure groups in the second study. This lesion was increased in the female 1,000 ppm postweaning exposure groups at the terminal evaluation, but an exposure-related increase was not observed at the 16-week interim.

The following discussion on carcinogenic activity is based on a weight of evidence of several factors described in the preface of this report and on the consistent findings in animals exposed either perinatally and postweaning or postweaning alone. A few differences between exposure paradigms are noted, but in general, the additional effect of including perinatal exposure on the chronic toxicity or carcinogenic response of PFOA appeared to be minimal.

At the end of the 2-year study, several neoplastic and nonneoplastic liver lesions were observed. In males, the incidences of hepatocellular adenomas were increased in the 40 and 80 ppm groups with and without perinatal exposure and exceeded the historical control range. In addition, hepatocellular carcinomas, a rare neoplasm (0/340 historical control), occurred in the 300/80 group. Increased incidences of liver necrosis were observed in all exposure groups with and without perinatal exposure, as were incidences of hepatocyte pigment, cytoplasmic alteration, and hypertrophy. Hepatocyte single cell death occurred in the mid- and high-postweaning exposure groups of 0/40, 300/40, and 0/80, 300/80 ppm. The increase in the incidences of hepatocellular adenomas or carcinomas (combined) was related to exposure. The incidence of hepatocellular carcinoma in animals exposed perinatally (300/80 ppm) was higher compared to those that were not (0/80 ppm). Although this increase was not statistically significant, it is uncertain if this was an effect of the additional perinatal exposure. The rarity of the lesion based on historical control data suggests this effect may be due to perinatal exposure; however, there were no other indications in the liver that demonstrated a difference between animals with the perinatal exposure versus animals without this exposure. The increase in incidence of hepatocellular neoplasms is similar to that seen in a previous PFOA rat study with 300 ppm exposure^74^ and could be related at least in part to the PPARα activity,^74^ which reviews of studies suggest that the human liver is not as sensitive to PPARα activity as rodents.^136,137^

In female rats, there were higher incidences of hepatocellular carcinomas, which are rare (1/340 historical control), in the 0/1,000 and 300/1,000 ppm groups, compared to the 0/0 ppm controls. Similar to males, this was accompanied by higher incidences of necrosis, pigment, cytoplasmic alteration, hypertrophy, increased mitosis, and hepatocyte single cell death. The magnitude of these findings was less than those in the males, which again might in part be due to the lower plasma concentrations of PFOA in females than in males. The marginally higher incidence of carcinomas compared to the controls may be related to exposure given the liver response in males, and that females had consistently lower incidences. No differences were observed between groups exposed perinatally and those that were not.

Increased incidences of pancreatic acinar cell adenomas and adenocarcinomas were observed in exposed males, as was the combined incidence of these neoplasms. Significantly increased incidences of adenomas in all postweaning exposed groups (36–64%) were higher than the historical control range for adenomas in males (45/340 historical control; range 0–28%) and the occurrence of rare adenocarcinomas (2/340 historical control; range 0–2%) were observed in all postweaning exposure groups (20, 40, and 80 ppm). The combined incidence of these neoplasms was statistically significant at all postweaning exposure concentrations with and without perinatal exposure. In addition, there was an increase in the incidence of pancreatic acinus hyperplasia with and without perinatal exposure. Taken together, the increase in the incidences of pancreatic acinar cell adenoma or adenocarcinoma (combined) neoplasms (predominately adenomas) was related to PFOA exposure. There was no difference in response between groups with combined perinatal and postweaning exposure compared to groups with postweaning exposure only. These findings are consistent with a previous PFOA chronic exposure study,^74^ and although not considered to be related to exposure in the earlier study,^72^ a reevaluation of tissue from the first PFOA chronic study indicated increased incidences of pancreatic acinar cell hyperplasia.^75^ The female pancreatic response was considered to be stronger than the liver response because pancreatic adenomas and adenocarcinomas were present, which were not observed in other studies (0/340 historical control), and because the exposure response was strengthened in both exposure paradigms when these two neoplasms were combined. This response differed from the observed response in the liver, where hepatocellular adenomas did not increase but there was a marginal increase in hepatocellular carcinomas.

There were higher incidences of pancreatic acinar cell neoplasms in the current study that also occurred at lower exposure concentrations compared to previous studies,^72,74^ for which several explanations are possible. In this study, the criterion used for diagnosis of pancreatic acinar cell neoplasms was larger than 3 mm at their widest diameter, whereas previous studies used a diameter of 5 mm for their criterion.^75^ Additionally, the Hsd:Sprague Dawley^®^ SD^®^ rat appears to have a higher background incidence of pancreatic acinar neoplasms, up to 28%, historically, in control animals; thus, they may be more sensitive to these neoplasms compared to the other rat stocks used previously. For example, NTP studies with the Wistar Han and F344/N rats appear to have a lower background incidence for pancreatic acinar cell neoplasms^138,139^ and Crl:CD (SD) Sprague Dawley rats are reported to have a background incidence of <1%.^140^

In females, low incidences of pancreatic acinar cell adenomas and adenocarcinomas were observed in the highest exposure groups of 0/1,000 and 300/1,000. These neoplasms are rare in females (adenomas = 0/340; carcinomas = 0/340 historical control). There were low occurrences of acinus hyperplasia in the exposed female groups, but these occurrences were not increased as they were in the male exposed groups. Although the occurrences of these neoplasms were low and not statistically significant, observations of increased incidences of pancreatic acinar cell neoplasms in males increased confidence that the occurrence of these rare neoplasms in PFOA-treated female animals also was due to exposure and hence was considered to be some evidence of carcinogenic activity. Perinatal and postweaning exposure groups did not differ from the postweaning-only exposure groups. These neoplasms were not observed in females in the first PFOA chronic study,^72^ which may be due to a lower exposure level compared to this study (300 versus 1,000 ppm) or other study design differences noted previously.

Within the uterus, there was a higher incidence of adenocarcinomas in PFOA-exposed females. This occurred in groups that had perinatal and postweaning or postweaning-only exposure, although the increase in most of the groups was not statistically significant. Historical control data for adenocarcinomas for similarly sectioned uterine tissue is very limited, with the concurrent control having a 2% incidence and two other studies having a 10% background incidence, suggesting that this is not a rare neoplasm. The incidences of nonneoplastic lesions of the uterus (e.g., atypical hyperplasia of the endometrium) were not increased in response to exposure. The increase in the incidence of adenocarcinomas of the uterus may have been related to exposure, as incidences in exposed females were higher than those in the 0/0 ppm control group, but the strength of the response was marginal and there was a low concurrent control incidence that lowered confidence in the response.

Treatment-related increased incidences of hyperplasia of the urothelium that lines the renal papilla, renal papilla necrosis, and renal tubule mineralization occurred in the female rats. Renal tubule mineralization and hyperplasia of the urothelium were present at the 16-week interim and terminal 2-year evaluation, whereas renal papilla necrosis was only observed at the 2-year evaluation and likely arose due to continued exposure. These lesions primarily occurred in the 1,000 ppm postweaning exposure groups. Organic anion transporters play a major role in predominant excretion of PFOA in urine, and the excretion is significantly faster in females than males.^26^ As a result, female rats have higher PFOA concentrations in the urine compared to males.^26^ Although the mechanisms of injury were not explored, direct cytotoxicity from the high concentration of PFOA in the urine is a possibility.^141^ A positive association between higher serum concentrations of perfluoroalkyl chemical and chronic kidney disease has been reported in humans^142^; however, it is not clear if the disease was due to increased PFAS exposure or if the disease itself increased PFAS exposure due to poor kidney function.^143^

The lack of differences between exposure paradigms is consistent with the similar plasma concentrations measured at the interim evaluation between PFOA-exposed animals with and without perinatal exposure. A review of perinatal carcinogenic risks suggests that non-genotoxic chemicals or chemicals that require activation generally are less potent perinatal carcinogens during this time of development compared to genotoxic chemicals or direct-acting chemicals, which can lead to new neoplasm types and/or a greater response.^144^ Previous NTP studies examined the contribution of perinatal exposure to carcinogenic activity and found some differences between groups with and without perinatal exposure.^89-91^ These differences were marginal in some cases and it was unclear if the length of exposure, and not developmental exposure per se, contributed to these differences. There was a general consistency in response between male and female rats in this study, but it varied in degree. Female rats generally had a lower response compared to males, which is consistent with the lower internal dose measured in females than in males at 16 weeks and supports the hypothesis that female response differences are due to pharmacokinetic differences.