# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: [underlined: https://doi.org/10.22427/NTP-DATA-TR598].^a^

a National Toxicology Program (NTP). TR-598: Pathology tables, survival and growth curves from NTP long-term, general study information, long-term, genetic toxicology studies. Research Triangle Park, NC. 2020. https://doi.org/10.22427/NTP-DATA-TR598

## Study 1: Two-year Study in Females and 16-week Interim Evaluation in Males and Females

### Perinatal Exposure

No exposure-related effects were observed on the pregnancy status, maternal survival, or number of dams that littered (Table 4). Maternal body weights and body weight gains of exposed dams during gestation were comparable to those of the control group (Table 5). During lactation, there were no consistent effects on maternal weight or maternal body weight gain across time points among exposed groups of dams (Table 6). Feed consumption (g/animal/day) during gestation was marginally (3% to 4%) lower in the 150 and 300 ppm groups compared to the control groups at select intervals during gestation (Table 7). Feed consumption was marginally lower (up to 4%) in the 300 ppm group from lactation days (LDs) 1 to 14, during which primarily the dam, and not the offspring, was consuming the feed (Table 7). Chemical consumption was 10.9 mg PFOA/kg body weight/day and 21.7 mg/kg/day for the 150 and 300 ppm groups during gestation, respectively. Chemical consumption was 23.3 and 45.2 mg/kg/day for the 150 and 300 ppm groups from LD 1–14, respectively; chemical consumption from LD 14–21 was not calculated due to the entire litter eating feed and an accurate assessment could not be made.

Table 4 Summary of Disposition during Perinatal Exposure and F_1_ Allocation in the Two-year Perinatal and Postweaning Study of Perfluorooctanoic Acid (Study 1)

| 0 ppm | 150 ppm | 300 ppm
Time-mated Females | 103 | 36 | 36
Nonpregnant Females | 12 | 5 | 4
Pregnant Females Delivering | 91 | 31 | 32
Pregnant Dams Not Delivering | 0 | 0 | 0
Littered/Pregnant on GD 21 | 91/91 (100%) | 31/31 (100%) | 32/32 (100%)
Litters Removed (PND 4)^a^ | 5 | 1 | 0
Litters Poststandardization (PND 4) | 86 | 30 | 32
Weaned Males/Females | 180/180 | 60/60 | 60/60

^a^ Removed due to insufficient size.

Table 5 Mean Body Weights and Body Weight Gains of F_0_ Females during Gestation in the Two-year Perinatal and Postweaning Study of Perfluorooctanoic Acid (Study 1)^a^

Gestation Day | 0 ppm | 150 ppm | 300 ppm
Body Weight (g)
6 | 240.02 ± 1.41 (91) | 241.40 ± 1.83 (31) | 240.10 ± 1.96 (32)
9 | 256.33 ± 1.37 (91) | 255.53 ± 2.04 (31) | 254.66 ± 1.98 (32)
12 | 271.57 ± 1.38 (91) | 268.85 ± 1.96 (31) | 269.44 ± 2.02 (32)
15 | 291.06 ± 1.53 (91) | 288.32 ± 2.28 (31) | 287.63 ± 2.26 (32)
18 | 331.58 ± 2.00 (91) | 329.09 ± 2.81 (31) | 328.88 ± 2.72 (32)
21 | 379.39 ± 2.92 (91) | 375.53 ± 3.86 (31) | 374.91 ± 3.33 (30)
Body Weight Change (g)
6 to 9 | 16.32 ± 0.57* (91) | 14.13 ± 0.73 (31) | 14.56 ± 0.91 (32)
9 to 12 | 15.24 ± 0.44 (91) | 13.31 ± 0.84* (31) | 14.78 ± 0.59 (32)
12 to 15 | 19.49 ± 0.51* (91) | 19.47 ± 0.95 (31) | 18.19 ± 0.53 (32)
15 to 18 | 40.52 ± 0.80 (91) | 40.77 ± 1.27 (31) | 41.25 ± 1.01 (32)
18 to 21 | 47.81 ± 1.13* (91) | 46.44 ± 1.39 (31) | 44.83 ± 1.20 (30)
6 to 21 | 139.37 ± 2.48* (91) | 134.13 ± 3.32 (31) | 133.39 ± 2.79 (30)

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05.

^a^ Mean ± standard error (number of dams). Each exposed group was compared to the control group using Williams’ test when a significant trend (p ≤ 0.01) was present by Jonckheere’s test or with Dunnett’s test when no significant trend was present.

Table 6 Mean Body Weights and Body Weight Gains of F_0_ Females during Lactation in the Two-year Perinatal and Postweaning Study of Perfluorooctanoic Acid (Study 1)^a^

Lactation Day | 0 ppm | 150 ppm | 300 ppm
Body Weight (g)
1 | 281.59 ± 1.60 (91) | 279.45 ± 2.04 (31) | 277.89 ± 2.47 (32)
4 | 298.08 ± 1.51* (86) | 295.41 ± 2.13 (30) | 289.97 ± 3.18* (32)
7 | 304.13 ± 1.48* (86) | 298.58 ± 2.32 (30) | 299.36 ± 2.53 (32)
14 | 321.16 ± 1.65 (86) | 316.43 ± 2.21 (30) | 316.98 ± 2.22 (32)
21 | 306.22 ± 1.52 (86) | 306.24 ± 1.84 (30) | 305.80 ± 2.69 (32)
Body Weight Change (g)
1 to 4 | 15.75 ± 0.81 (86) | 16.06 ± 1.20 (30) | 12.07 ± 2.30 (32)
4 to 7 | 6.05 ± 0.84 (86) | 3.17 ± 1.41 (30) | 9.39 ± 1.90 (32)
7 to 14 | 17.03 ± 0.95 (86) | 17.85 ± 1.24 (30) | 17.63 ± 1.47 (32)
14 to 21 | −14.94 ± 1.19* (86) | −10.19 ± 1.22* (30) | −11.18 ± 1.60 (32)
1 to 21 | 23.89 ± 1.14** (86) | 26.89 ± 1.74 (30) | 27.91 ± 2.07 (32)

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Mean ± standard error (number of dams). Each exposed group was compared to the control using Williams’ test when a significant (p ≤ 0.01) trend was present by Jonckheere’s test or with Dunnett’s test when no significant trend was present.

Table 7 Feed Consumption by F_0_ Females during Gestation and Lactation in the Two-year Perinatal and Postweaning Study of Perfluorooctanoic Acid (Study 1)^a^

Days | 0 ppm | 150 ppm | 300 ppm
Gestation (g/animal/day)
6 to 9 | 19.60 ± 0.18* (91) | 19.25 ± 0.29 (31) | 19.11 ± 0.26 (32)
9 to 12 | 20.14 ± 0.15* (91) | 19.42 ± 0.30* (31) | 19.55 ± 0.25 (32)
12 to 15 | 20.54 ± 0.14** (91) | 19.93 ± 0.30** (31) | 19.62 ± 0.27** (32)
15 to 18 | 22.11 ± 0.17 (91) | 22.14 ± 0.28 (31) | 22.22 ± 0.30 (32)
18 to 21 | 23.89 ± 0.20 (91) | 23.68 ± 0.33 (31) | 23.56 ± 0.34 (32)
6 to 21 | 21.26 ± 0.13* (91) | 20.88 ± 0.25 (31) | 20.81 ± 0.24 (32)
Lactation (g/animal/day)
1 to 4 | 38.17 ± 0.60** (84) | 38.47 ± 1.74 (29) | 36.53 ± 1.86** (32)
4 to 7 | 40.94 ± 0.78** (85) | 40.18 ± 0.77 (29) | 36.92 ± 0.65** (32)
7 to 10 | 49.48 ± 0.67** (85) | 45.97 ± 1.70* (30) | 46.67 ± 0.64** (32)
10 to 14 | 58.71 ± 0.48 (86) | 58.70 ± 0.82 (30) | 57.80 ± 0.81 (32)
14 to 17 | 61.97 ± 0.72* (86) | 58.53 ± 0.82** (30) | 61.83 ± 1.23 (32)
17 to 21 | 70.10 ± 0.93 (86) | 69.24 ± 1.41 (30) | 69.29 ± 1.42 (32)
1 to 14 | 47.59 ± 0.35** (82) | 47.10 ± 0.80 (28) | 45.51 ± 0.77** (32)

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Mean ± standard error in grams/animal/day (number of dams). Each exposed group was compared to the control group using Shirley’s test when a significant (p ≤ 0.01) trend was present by Jonckheere’s test or with Dunn’s test when no significant trend was present.

Total and live litter sizes and survival of the F_1_ rats during lactation were not affected by exposure (Table 8). Male and female pup body weights on postnatal day (PND) 1 were 5% lower in the 300 ppm groups compared to the 0/0 ppm control group and 5% to 8% lower at PND 7, 14, and 21 (Table 9).

Table 8 Mean Litter Size and Survival Ratio of F_1_ Rats during Lactation in the Two-year Perinatal and Postweaning Study of Perfluorooctanoic Acid (Study 1)^a^

Postnatal Day | 0 ppm | 150 ppm | 300 ppm
Total Litter Size
1 | 13.68 ± 0.34 (91) | 13.26 ± 0.42 (31) | 13.19 ± 0.42 (32)
Live Litter Size
1 | 13.60 ± 0.34 (91) | 13.26 ± 0.42 (31) | 13.16 ± 0.42 (32)
4 | 13.42 ± 0.37 (91) | 13.16 ± 0.42 (31) | 13.13 ± 0.41 (32)
4 (Poststandardization) | 8.00 ± 0.00 (86) | 8.00 ± 0.00 (30) | 8.00 ± 0.00 (32)
21 | 7.87 ± 0.06 (86) | 7.83 ± 0.08 (30) | 7.97 ± 0.03 (32)
Survival Ratio
1 to 4^b^ | 0.985 ± 0.011 (90) | 0.993 ± 0.004 (31) | 0.998 ± 0.002 (32)
4 to 21^c^ | 0.984 ± 0.007 (86) | 0.979 ± 0.011 (30) | 0.996 ± 0.004 (32)

^a^ Mean ± standard error (number of dams). Each exposed group was compared to the control group using Shirley’s test when a significant (p ≤ 0.01) trend was present by Jonckheere’s test or with Dunn’s test when no significant trend was present.

^b^ Number of live pups on PND 4/number of live pups on PND 1.

^c^ Number of live pups on PND 21/number of live pups on PND 4 poststandardization.

Table 9 Mean Body Weight of F_1_ Rats during Lactation in the Two-year Perinatal and Postweaning Study of Perfluorooctanoic Acid (Study 1)

Postnatal Day | 0 ppm | 150 ppm | 300 ppm
Male (g)
1^a^ | 7.17 ± 0.07** (89) | 7.10 ± 0.11 (31) | 6.79 ± 0.11** (32)
4^b,c^ | 10.02 ± 0.11 (337/86) | 10.13 ± 0.16 (120/30) | 9.73 ± 0.19 (131/32)
7^c^ | 15.38 ± 0.18** (335/86) | 15.42 ± 0.23 (119/30) | 14.09 ± 0.34** (131/32)
14^c^ | 32.49 ± 0.28** (330/86) | 32.11 ± 0.40 (119/30) | 30.27 ± 0.51** (130/32)
21^c^ | 51.65 ± 0.52** (330/86) | 50.61 ± 0.72 (119/30) | 48.68 ± 0.95** (130/32)
Female (g)
1^a^ | 6.87 ± 0.07** (90) | 6.75 ± 0.10 (31) | 6.51 ± 0.13** (32)
4^b,c^ | 9.56 ± 0.11 (351/86) | 9.70 ± 0.17 (120/30) | 9.45 ± 0.20 (125/32)
7^c^ | 14.66 ± 0.19** (351/86) | 14.58 ± 0.26 (118/30) | 13.66 ± 0.33** (125/32)
14^c^ | 31.12 ± 0.29** (348/86) | 30.52 ± 0.42 (117/30) | 29.40 ± 0.51** (125/32)
21^c^ | 48.68 ± 0.49** (347/86) | 47.85 ± 0.76 (116/30) | 46.22 ± 0.92* (125/32)
All Pups (g)
1^a^ | 7.02 ± 0.06** (90) | 6.91 ± 0.10 (31) | 6.63 ± 0.11** (32)
4^b,c^ | 9.79 ± 0.10 (688/86) | 9.91 ± 0.15 (240/30) | 9.59 ± 0.19 (256/32)
7^c^ | 15.02 ± 0.17** (686/86) | 15.00 ± 0.24 (237/30) | 13.89 ± 0.33** (256/32)
14^c^ | 31.81 ± 0.26** (678/86) | 31.32 ± 0.39 (236/30) | 29.84 ± 0.49** (255/32)
21^c^ | 50.15 ± 0.47** (677/86) | 49.27 ± 0.71 (235/30) | 47.49 ± 0.91** (255/32)

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group. Statistical significance for the control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Mean ± standard error (number of dams). Each exposed group was compared to the control group using Williams’ test when a significant (p ≤ 0.01) trend was present by Jonckheere’s test or with Dunnett’s test when no significant trend was present.

^b^ PND 4 poststandardization.

^c^ Mean ± standard error (number of pups/number of dams). Individual pup weights first adjusted for litter size on PND 4 poststandardization. Each exposed group was compared to the control group using a mixed model with a Dunnett-Hsu adjustment.

### Sixteen-week Interim Evaluation in Males and Females (Study 1)

No early deaths occurred among rats designated for interim evaluation at 16 weeks (19 weeks of age). Due to the concern of overt toxicity in males, the male portion of the 2-year study was terminated at 21 weeks (24 weeks of age). The overt toxicity in the male rats presented low body weights and the presence of liver necrosis. There were no exposure-related clinical observations (Appendix E). No other evaluation was performed on the males removed from study at 21 weeks.

Group mean feed (g/animal/day) and compound consumption (mg/kg/day) for male rats through 21 weeks are available in Appendix E. Compared to the 0/0 ppm control group, mean feed consumption by exposed males was lower through week 13 of the study. Mean feed consumption (g/animal/day) by 0/150, 150/150, 0/300, and 300/300 ppm groups was 13%, 11%, 23%, and 19% less than the 0/0 ppm control group, respectively, at 13 weeks. This reduction in feed consumption may be due in part to the smaller size of the animals (described below) compared to the 0/0 ppm control group. This difference would be captured in feed consumption expressed in g/kg body weight/day, but these values were not calculated. Compound consumption for the 0/150 and 150/150 ppm groups through week 13 averaged 15.6 and 15.8 mg/kg/day, respectively, and for the 0/300 and 300/300 ppm groups, 31.7 and 32.1 mg/kg/day, respectively.

Mean feed consumption (g/animal/day) for F_1_ females is available in Appendix E. Feed consumption for females in the 0/300 and 150/300 ppm groups was within 10% of the 0/0 ppm control group throughout the study. Mean feed consumption for the 0/1,000 and 300/1,000 ppm female groups was reduced through the first 4 weeks postweaning. However, by the fifth week, mean feed consumption for these two groups was within 10% of the 0/0 ppm control group and remained so through the end of the study. Compound consumption averaged 29.6 mg/kg/day for the 0/300 and 150/300 ppm groups and 98.6 and 104.4 mg/kg/day for the 0/1,000 and 300/1,000 ppm groups, respectively.

Plasma PFOA concentrations in males were consistent between groups with and without exposure during the perinatal period and were within 10% of each other between the 0/150 and 150/150 ppm groups and between the 0/300 and 300/300 ppm groups (Table 10). Liver concentrations showed a similar pattern. Plasma concentrations in females showed a similar pattern to the males (e.g., minor differences between perinatal exposures and liver patterns); however, PFOA concentrations were much lower compared to males even though female exposure (mg/kg/day) was 2 to 3 times higher compared to males (Table 11). Plasma concentrations were approximately 12-fold lower in the 0/300 ppm female group compared to the 0/300 ppm male group.

Table 10 Summary of Plasma and Liver Concentration Data for Male Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)^a,b^

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 150 ppm | 300 ppm
n | | 10 | 10 | 10
Plasma Concentration (ng/mL) | 0 ppm | BD^c^ | 193,000 ± 11,325 | 242,500 ± 12,731
| 150 ppm | – | 175,390 ± 14,956 | –
| 300 ppm | – | – | 223,400 ± 8,422
Plasma Concentration (μM) | 0 ppm | BD^c^ | 466.1 ± 27.4 | 585.7 ± 30.7
| 150 ppm | – | 423.6 ± 36.1 | –
| 300 ppm | – | – | 539.5 ± 20.3
Liver Concentration (ng/g) | 0 ppm | BD | 157,400 ± 5,418 | 171,000 ± 7,578
| 150 ppm | – | 144,300 ± 5,752 | –
| 300 ppm | – | – | 193,800 ± 9,704
Liver Concentration (μM) | 0 ppm | BD | 380.1 ± 13.1 | 413.0 ± 18.3
| 150 ppm | – | 348.5 ± 13.9 | –
| 300 ppm | – | – | 468.0 ± 23.4
Liver/Plasma Ratio | 0 ppm | BD | 0.84 ± 0.05 | 0.73 ± 0.06
| 150 ppm | – | 0.86 ± 0.06 | –
| 300 ppm | – | – | 0.88 ± 0.05

Pairwise comparisons across perinatal exposures (0/150 vs. 150/150 ppm and 0/300 vs. 300/300 ppm) did not show any statistically significant differences.

Values adjusted for molar concentration were calculated by dividing by the molecular weight of 414.06.

BD = below detection; group did not have over 20% of its values above the limit of quantification. In these cases, no statistical analyses were performed.

^a^ Data presented as mean ± SEM.

^b^ Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests (unless otherwise noted).

^c^ N = 9; decrease in N in the 0/0 ppm control group is due to the exclusion of an implausible plasma concentration value.

Table 11 Summary of Plasma and Liver Concentration Data for Female Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)^a,b^

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 300 ppm | 1,000 ppm
n | | 10 | 10 | 10
Plasma Concentration (ng/mL) | 0 ppm | BD | 20,420 ± 1,212 | 72,250 ± 4,351
| 150 ppm | – | 20,800 ± 1,043 | –
| 300 ppm | – | – | 70,160 ± 6,895
Plasma Concentration (μM) | 0 ppm | BD | 49.3 ± 2.9 | 174.5 ± 10.5
| 150 ppm | – | 50.2 ± 2.5 | –
| 300 ppm | – | – | 169.4 ± 16.7
Liver Concentration (ng/g) | 0 ppm | BD | 16,420 ± 787 | 69,040 ± 3,942
| 150 ppm | – | 16,660 ± 750 | –
| 300 ppm | – | – | 67,840 ± 5,681
Liver Concentration (μM) | 0 ppm | BD | 39.7 ± 1.9 | 166.7 ± 9.5
| 150 ppm | – | 40.2 ± 1.8 | –
| 300 ppm | – | – | 163.8 ± 13.7
Liver/Plasma Ratio | 0 ppm | BD | 0.82 ± 0.03 | 0.96 ± 0.04
| 150 ppm | – | 0.81 ± 0.03 | –
| 300 ppm | – | – | 0.99 ± 0.05

Pairwise comparisons across perinatal exposures (0/300 vs. 150/300 ppm and 0/1,000 vs. 300/1,000 ppm) did not show any statistically significant differences.

Values adjusted for molar concentration were calculated by dividing by the molecular weight of 414.06.

BD = below detection; group did not have over 20% of its values above the limit of quantification. In these cases, no statistical analyses were performed.

^a^ Data presented as mean ± SEM.

^b^ Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests (unless otherwise noted).

Males in all exposure groups gained weight through the interim study evaluation at week 16 (Figure 2, Figure 3; Appendix E). However, exposed males did not gain weight at the same rate as the 0/0 ppm control group; this reduced weight gain was related to exposure. Body weights of males in the 0/150 and 150/150 ppm groups evaluated at 16 weeks were 79% and 76% of the 0/0 ppm control group weight, respectively, and body weights of males in the 0/300 and 300/300 ppm groups were 55% of the 0/0 ppm control group weight.

Figure 2

Growth Curves for Male Rats with Postweaning-only Exposure to 0/0, 0/150, or 0/300 ppm Perfluorooctanoic Acid in Feed for 21 Weeks

Figure 3

Growth Curves for Male Rats with Perinatal and Postweaning Exposure to 0/0, 150/150, or 300/300 ppm Perfluorooctanoic Acid in Feed for 21 Weeks

Group mean body weights of females are reported in Appendix E. Mean body weights for females in the 0/300 and 150/300 ppm groups were within 10% of the 0/0 ppm control group. Mean body weights for the 0/1,000 and 300/1,000 ppm female groups were approximately 10–15% less than the 0/0 ppm control group throughout most of the postweaning period. For the females evaluated at 16 weeks, mean body weights for the 0/1,000 and 300/1,000 ppm groups were 12% less than that of the 0/0 ppm control group.

The group mean absolute and relative liver weights of all exposed groups of males and of 0/1,000 and 300/1,000 ppm female groups were significantly greater than those of the 0/0 ppm control group (Table 12, Table 13). Absolute liver weights were increased up to 42% (males) and 36% (females) of the 0/0 ppm control group. Histological correlates (hepatocyte hypertrophy, cytoplasmic alteration, and pigment) were present in all groups that had liver weight changes (Table 12, Table 13). Groups with both perinatal and postweaning exposure did not differ from groups with postweaning-only exposure.

Table 12 Summary of Hepatic Findings for Male Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 150 ppm | 300 ppm
n | | 10 | 10 | 10
Necropsy Body Weight (g)^a,b^ | 0 ppm | 425.9 ± 10.4**^##^ | 336.7 ± 9.1** | 234.4 ± 20.4**
| 150 ppm | – | 325.3 ± 13.8** | –
| 300 ppm | – | – | 234.3 ± 16.2**
Liver Weight^a,b^
Absolute (g) | 0 ppm | 16.52 ± 0.59 | 23.41 ± 0.51** | 19.57 ± 0.98*
| 150 ppm | – | 21.44 ± 0.75** | –
| 300 ppm | – | – | 18.69 ± 0.59*
Relative (mg/g) | 0 ppm | 38.72 ± 0.62**^##^ | 69.90 ± 2.13** | 87.37 ± 5.54**
| 150 ppm | – | 66.55 ± 2.62** | –
| 300 ppm | – | – | 82.07 ± 3.95**
Histological Findings^c^
Liver^d^ | | 10 | 10 | 10
Hepatocyte, Cytoplasmic Alteration^e^ | 0 ppm | 0**^##^ | 10** (2.2)^f^ | 10** (2.6)
| 150 ppm | – | 10** (2.1) | –
| 300 ppm | – | – | 10** (2.8)
Hepatocyte, Hypertrophy | 0 ppm | 0**^##^ | 10** (2.1) | 6** (2.5)
| 150 ppm | – | 10** (1.9) | –
| 300 ppm | – | – | 10**^ (1.6)
Hepatocyte, Single Cell Death | 0 ppm | 0**^##^ | 10** (1.3) | 10** (1.0)
| 150 ppm | – | 9** (1.1) | –
| 300 ppm | – | – | 10** (1.0)
Necrosis | 0 ppm | 0^#^ | 6** (1.2) | 2 (1.0)
| 150 ppm | – | 2 (1.5) | –
| 300 ppm | – | – | 4* (1.8)
Pigment | 0 ppm | 0**^##^ | 8** (1.1) | 10** (2.0)
| 150 ppm | – | 9** (1.2) | –
| 300 ppm | – | – | 10** (1.9)
n | | 5 | 5 | 5
Acyl-CoA Oxidase Activity (nmol/min/mg)^a,b^ | 0 ppm | 2.212 ± 0.100**^##^ | 21.160 ± 1.741** | 24.360 ± 0.698**
| 150 ppm | – | 21.360 ± 2.133** | –
| 300 ppm | – | – | 25.340 ± 1.810**
Aromatase Activity (pmol/mg/min)^a,b^ | 0 ppm | 6.972 ± 1.212 | 14.292 ± 2.424 | 5.588 ± 2.135
| 150 ppm | – | 11.602 ± 2.118 | –
| 300 ppm | – | – | 11.896 ± 2.696

Statistical significance for a treatment group indicates a significant pairwise test compared to the 0/0 ppm control group. Statistical significance for the 0/0 ppm control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^#^ Statistically significant trend at p ≤ 0.05 when comparing across the 0/0, 150/150, and 300/300 ppm groups; ^##^p ≤ 0.01.

^ Statistically significant at p ≤ 0.05 when comparing 0/300 vs. 300/300 ppm.

^a^ Data presented as mean ± SEM.

^b^ Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests.

^c^ Statistical analysis performed by the Poly-3 test.

^d^ Number of animals examined microscopically.

^e^ Number of animals with lesion.

^f^ Average severity grade of lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Table 13 Summary of Hepatic Findings for Female Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 300 ppm | 1,000 ppm
n | | 10 | 10 | 10
Necropsy Body Weight (g)^a,b^ | 0 ppm | 255.2 ± 4.5**^##^ | 248.9 ± 8.5 | 223.7 ± 3.9**
| 150 ppm | – | 242.3 ± 7.1 | –
| 300 ppm | – | – | 223.4 ± 8.4**
Liver Weight^a,b^
Absolute (g) | 0 ppm | 9.35 ± 0.40**^##^ | 9.78 ± 0.32 | 12.70 ± 0.36**
| 150 ppm | – | 9.36 ± 0.23 | –
| 300 ppm | – | – | 12.71 ± 0.56**
Relative (mg/g) | 0 ppm | 36.55 ± 1.08**^##^ | 39.34 ± 0.61 | 56.78 ± 1.33**
| 150 ppm | – | 38.70 ± 0.70 | –
| 300 ppm | – | – | 56.86 ± 1.19**
Histological Findings^c^
Liver^d^ | | 10 | 10 | 10
Hepatocyte, Cytoplasmic Alteration^e^ | 0 ppm | 0**^##^ | 0 | 10** (1.3)^f^
| 150 ppm | – | 0 | –
| 300 ppm | – | – | 10** (2.0)
Hepatocyte, Hypertrophy | 0 ppm | 0**^##^ | 0 | 10** (1.4)
| 150 ppm | – | 0 | –
| 300 ppm | – | – | 10** (2.0)
Hepatocyte, Single Cell Death | 0 ppm | 0 | 0 | 1 (1.0)
| 150 ppm | – | 0 | –
| 300 ppm | – | – | 0
Necrosis | 0 ppm | 0 | 0 | 2 (2.5)
| 150 ppm | – | 0 | –
| 300 ppm | – | – | 0
Pigment | 0 ppm | 0^##^ | 0 | 2 (1.0)
| 150 ppm | – | 0 | –
| 300 ppm | – | – | 6** (1.0)
n | | 5 | 5 | 5
Acyl-CoA Oxidase Activity (nmol/min/mg)^a,b^ | 0 ppm | 2.366 ± 0.106**^##^ | 3.402 ± 0.300** | 15.360 ± 0.375**
| 150 ppm | – | 3.300 ± 0.213** | –
| 300 ppm | – | – | 12.980 ± 0.712**
Aromatase Activity (pmol/mg/min)^a,b^ | 0 ppm | 1.590 ± 0.404 | 1.762 ± 0.302 | 1.710 ± 0.433
| 150 ppm | – | 2.672 ± 0.881 | –
| 300 ppm | – | – | 2.616 ± 0.572

Statistical significance for a treatment group indicates a significant pairwise test compared to the 0/0 ppm control group. Statistical significance for the 0/0 ppm control group indicates a significant trend test.

Pairwise comparisons across perinatal exposures (0/300 vs. 150/300 ppm and 0/1,000 vs. 300/1,000 ppm) did not show any statistically significant differences.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^#^ Statistically significant trend at p ≤ 0.05 when comparing across the 0/0, 150/300, and 300/1,000 ppm groups; ^##^p ≤ 0.01.

^a^ Data presented as mean ± SEM.

^b^ Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests.

^c^ Statistical analysis performed by the Poly-3 test.

^d^ Number of animals examined microscopically.

^e^ Number of animals with lesion.

^f^ Average severity grade of lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Acyl-CoA oxidase enzyme activity, a marker of PPARα activity, was increased in all male and female PFOA-exposed groups. Activity increased in males in the 0/150 and 150/150 ppm groups by 10-fold and increased in the 0/300 and 300/300 ppm groups by 11- to 12-fold compared to the 0/0 ppm control group. The magnitude of the effect was smaller in females with a 1.4-fold increase in the mid-doses of 0/300 and 150/300 ppm groups and a 5.5- and 6.5-fold increase in the 300/1,000 and 0/1,000 ppm groups, respectively, compared to the 0/0 ppm control group. No changes were observed in liver aromatase activity in males or females (Table 12, Table 13).

The mean absolute and relative spleen and absolute thymus weights of all exposed male groups were significantly less than those of the 0/0 ppm control group (Table 14; Appendix E). The decrease in absolute spleen and thymus weights was up to 54% and 49%, respectively, in the 0/300 ppm group compared to the 0/0 ppm control group; however, there were no correlated histological findings.

Table 14 Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)^a,b^

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 150 ppm | 300 ppm
n | | 10 | 10 | 10
Necropsy Body Weight (g) | 0 ppm | 425.9 ± 10.4**^##^ | 336.7 ± 9.1** | 234.4 ± 20.4**
| 150 ppm | – | 325.3 ± 13.8** | –
| 300 ppm | – | – | 234.3 ± 16.2**
Spleen Weight
Absolute (g) | 0 ppm | 0.805 ± 0.031**^##^ | 0.551 ± 0.022** | 0.373 ± 0.038**
| 150 ppm | – | 0.543 ± 0.036** | –
| 300 ppm | – | – | 0.395 ± 0.038**
Relative (mg/g) | 0 ppm | 1.89 ± 0.05**^#^ | 1.63 ± 0.03** | 1.58 ± 0.06**
| 150 ppm | – | 1.66 ± 0.07* | –
| 300 ppm | – | – | 1.66 ± 0.07*
Thymus Weight
Absolute (g) | 0 ppm | 0.369 ± 0.015**^##^ | 0.277 ± 0.017** | 0.187 ± 0.027**
| 150 ppm | – | 0.284 ± 0.014** | –
| 300 ppm | – | – | 0.208 ± 0.026**
Relative (mg/g) | 0 ppm | 0.87 ± 0.04 | 0.83 ± 0.05 | 0.77 ± 0.06
| 150 ppm | – | 0.88 ± 0.04 | –
| 300 ppm | – | – | 0.86 ± 0.07

Statistical significance for a treatment group indicates a significant pairwise test compared to the 0/0 ppm control group. Statistical significance for the 0/0 ppm control group indicates a significant trend test.

Pairwise comparisons across perinatal exposures (0/150 vs. 150/150 ppm and 0/300 vs. 300/300 ppm) did not show any statistically significant differences.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^#^ Statistically significant trend at p ≤ 0.05 when comparing across the 0/0, 150/150, and 300/300 ppm groups; ^##^p ≤ 0.01.

^a^ Data presented as mean ± SEM.

^b^ Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests (unless otherwise noted).

Statistically significant differences between exposed and 0/0 ppm control group males in absolute and relative heart, lung, right kidney, testis, thyroid gland, pituitary gland, and adrenal gland mean weights were considered related to the significantly decreased body weights, and there were no correlated histological findings (Appendix E).

Significantly decreased mean absolute right kidney and lung weights of the 0/1,000 and 300/1,000 ppm female groups, mean absolute heart weight of the 0/1,000 ppm female group, and mean absolute pituitary gland weight of the 300/1,000 ppm female group were also considered related to reduced body weights.

Select clinical chemistry data are presented in Table 15 (males) and Table 16 (females). Urea nitrogen concentrations were significantly increased in all exposed male groups; this was most likely due to a decrease in water consumption (i.e., mild dehydration), which is supported by the observed decreases in feed consumption. Triglyceride concentrations were significantly decreased in all exposed male groups.

Table 15 Select Clinical Chemistry Data for Male Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)^a,b^

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 150 ppm | 300 ppm
n | | 10 | 10 | 10
Urea Nitrogen (mg/dL) | 0 ppm | 15.3 ± 0.6**^##^ | 21.2 ± 0.7** | 21.3 ± 0.8**
| 150 ppm | – | 20.6 ± 1.0** | –
| 300 ppm | – | – | 24.1 ± 1.0**
Total Protein (g/dL) | 0 ppm | 6.59 ± 0.07**^##^ | 6.17 ± 0.09** | 5.18 ± 0.15**
| 150 ppm | – | 5.87 ± 0.13** | –
| 300 ppm | – | – | 5.35 ± 0.22**
Albumin (g/dL) | 0 ppm | 4.13 ± 0.04 | 4.69 ± 0.07** | 4.00 ± 0.14
| 150 ppm | – | 4.48 ± 0.09* | –
| 300 ppm | – | – | 4.09 ± 0.16
Globulin (g/dL) | 0 ppm | 2.46 ± 0.06**^##^ | 1.48 ± 0.07** | 1.18 ± 0.03**
| 150 ppm | – | 1.39 ± 0.06** | –
| 300 ppm | – | – | 1.26 ± 0.08**
A/G Ratio | 0 ppm | 1.69 ± 0.05**^##^ | 3.24 ± 0.18** | 3.40 ± 0.12**
| 150 ppm | – | 3.27 ± 0.15** | –
| 300 ppm | – | – | 3.31 ± 0.16**
Triglycerides (mg/dL) | 0 ppm | 115.1 ± 6.2**^##^ | 61.5 ± 6.5** | 52.4 ± 6.4**
| 150 ppm | – | 58.4 ± 3.6** | –
| 300 ppm | – | – | 52.3 ± 2.0**
Alanine Aminotransferase (IU/L) | 0 ppm | 50.70 ± 1.80*^##^ | 71.20 ± 4.05** | 66.70 ± 6.71*
| 150 ppm | – | 70.20 ± 3.09** | –
| 300 ppm | – | – | 65.10 ± 4.49**
Alkaline Phosphatase (IU/L) | 0 ppm | 174.1 ± 9.3**^##^ | 412.6 ± 38.1** | 399.1 ± 27.0**
| 150 ppm | – | 398.7 ± 25.0** | –
| 300 ppm | – | – | 410.8 ± 33.1**
Sorbitol Dehydrogenase (IU/L) | 0 ppm | 8.2 ± 0.7**^##^ | 16.7 ± 1.8** | 20.6 ± 7.7 **
| 150 ppm | – | 15.9 ± 1.3** | –
| 300 ppm | – | – | 16.3 ± 1.8**
Bile salt/acids (μmol/L) | 0 ppm | 25.4 ± 1.6**^##^ | 45.7 ± 3.6** | 127.0 ± 26.5**
| 150 ppm | – | 46.2 ± 6.4** | –
| 300 ppm | – | – | 69.8 ± 15.2**

Statistical significance for a treatment group indicates a significant pairwise test compared to the 0/0 ppm control group. Statistical significance for the 0/0 ppm control group indicates a significant trend test.

Pairwise comparisons across perinatal exposures (0/150 vs. 150/150 ppm and 0/300 vs. 300/300 ppm) did not show any statistically significant differences.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^#^ Statistically significant trend at p ≤ 0.05 when comparing across the 0/0, 150/150, and 300/300 ppm groups; ^##^p ≤ 0.01.

^a^ Data presented as mean ± SEM.

^b^ Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests (unless otherwise noted).

Table 16 Select Clinical Chemistry Data for Female Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)^a,b^

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 300 ppm | 1,000 ppm
n | | 10 | 10 | 10
Total Protein (g/dL) | 0 ppm | 6.87 ± 0.04^#^ | 6.80 ± 0.10 | 7.09 ± 0.11
| 150 ppm | – | 6.70 ± 0.08 | –
| 300 ppm | – | – | 7.19 ± 0.08*
Albumin (g/dL) | 0 ppm | 4.65 ± 0.05**^##^ | 4.85 ± 0.08 | 5.25 ± 0.09**
| 150 ppm | – | 4.74 ± 0.04 | –
| 300 ppm | – | – | 5.33 ± 0.07**
Globulin (g/dL) | 0 ppm | 2.22 ± 0.04**^##^ | 1.95 ± 0.04** | 1.84 ± 0.04**
| 150 ppm | – | 1.96 ± 0.07** | –
| 300 ppm | – | – | 1.86 ± 0.05**
A/G Ratio | 0 ppm | 2.10 ± 0.05**^##^ | 2.49 ± 0.06** | 2.86 ± 0.05**
| 150 ppm | – | 2.44 ± 0.09** | –
| 300 ppm | – | – | 2.88 ± 0.08**
Alanine Aminotransferase (IU/L) | 0 ppm | 43.70 ± 2.18**^##^ | 50.50 ± 3.08 | 56.00 ± 3.06**
| 150 ppm | – | 51.00 ± 2.75 | –
| 300 ppm | – | – | 54.90 ± 2.07**
Alkaline Phosphatase (IU/L) | 0 ppm | 129.8 ± 9.0* | 122.4 ± 7.8 | 166.3 ± 6.9*
| 150 ppm | – | 154.8 ± 11.3 | –
| 300 ppm | – | – | 144.5 ± 11.6
Sorbitol Dehydrogenase (IU/L) | 0 ppm | 8.1 ± 0.6^#^ | 9.2 ± 0.9 | 10.3 ± 1.1
| 150 ppm | – | 9.8 ± 0.9 | –
| 300 ppm | – | – | 10.9 ± 0.7*

Statistical significance for a treatment group indicates a significant pairwise test compared to the 0/0 ppm control group. Statistical significance for the 0/0 ppm control group indicates a significant trend test.

Pairwise comparisons across perinatal exposures (0/300 vs. 150/300 ppm and 0/1,000 vs. 300/1,000) did not show any statistically significant differences.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^#^ Statistically significant trend at p ≤ 0.05 when comparing across the 0/0, 150/300, and 300/1,000 ppm groups; ^##^p ≤ 0.01.

^a^ Data presented as mean ± SEM.

^b^ Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests (unless otherwise noted).

Globulin concentrations were significantly decreased in all exposed groups of males and females. In exposed male groups, the degree of decrease in the globulin concentration resulted in a significant decrease in total protein concentration. Albumin concentrations were significantly increased in the 0/150 and 150/150 ppm male groups and in the 0/1,000, and 300/1,000 ppm female groups compared to the 0/0 ppm control group. The combination of these protein changes resulted in significant increases in the albumin:globulin ratios in all exposed groups.

With and without perinatal exposure, alanine aminotransferase (ALT), alkaline phosphatase (ALP), and sorbitol dehydrogenase (SDH) enzyme activities were significantly increased in all exposed male groups. In females, ALT activity was significantly increased in the 0/1,000 and 300/1,000 ppm groups, whereas SDH activity was increased in the 300/1,000 ppm group and ALP activity increased in the 0/1,000 ppm group compared to the 0/0 ppm control group. Additionally, bile acid concentrations were significantly increased in all exposed male groups with and without perinatal exposure.

Data for nonneoplastic lesions in male and female rats at the 16-week interim evaluation are presented in Appendix E.

The histopathological descriptions of the nonneoplastic and neoplastic data for the 16-week interim and 2-year studies in males and females discussed in this section are presented in the Histopathological Descriptions section following the presentation of the 2-year study in males.

Liver: Compared to the 0/0 ppm control group, the incidences of hepatocyte hypertrophy, hepatocyte cytoplasmic alteration, hepatocyte single cell death, and pigment were significantly increased in all exposed male groups (Table 12). The incidences of hepatocyte necrosis were significantly increased in the 0/150 and 300/300 ppm groups; two incidences of necrosis also occurred in the 0/300 and 150/150 ppm groups. No differences between groups with perinatal and without perinatal exposures were observed.

In females, the incidences of hepatocyte hypertrophy and hepatocyte cytoplasmic alteration were significantly increased in the 0/1,000 and 300/1,000 ppm groups compared to the 0/0 ppm control group (Table 13). The incidence of pigment was significantly increased in the 300/1,000 ppm group relative to the 0/0 ppm control group.

Thyroid Gland: In males, the incidence of follicular cell hypertrophy was significantly increased in the 0/300 ppm group compared to the 00/0 ppm control group (Table 17). In females, the incidence of follicular cell hypertrophy was significantly increased in the 300/1,000 ppm group compared to the 0/0 ppm control (Table 18). No differences between groups with perinatal and without perinatal exposures were observed.

Table 17 Incidences of Select Nonneoplastic Lesions of the Thyroid Gland, Kidney, and Glandular Stomach in Male Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)^a^

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 150 ppm | 300 ppm
n | | 10^b^ | 10 | 10
Thyroid Gland
Follicular Cell, Hypertrophy^c^ | 0 ppm | 0** | 2 (1.0)^d^ | 6** (1.0)
| 150 ppm | – | 0 | –
| 300 ppm | – | – | 2 (1.0)
Kidney
Renal Tubule, Mineral | 0 ppm | 0**^##^ | 4* (1.0) | 5** (1.0)
| 150 ppm | – | 1 (1.0) | –
| 300 ppm | – | – | 6** (1.0)
Glandular Stomach
Submucosa, Inflammation, Chronic Active | 0 ppm | 0** | 2 (1.0) | 5** (1.0)
| 150 ppm | – | 2 (1.0) | –
| 300 ppm | – | – | 2 (1.0)

Statistical significance for a treatment group indicates a significant pairwise test compared to the 0/0 ppm control group. Statistical significance for the 0/0 ppm control group indicates a significant trend test.

Pairwise comparisons across perinatal exposures (0/150 vs. 150/150 ppm and 0/300 vs. 300/300 ppm) did not show any statistically significant differences.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^##^ Statistically significant trend at p ≤ 0.01 when comparing across the 0/0, 150/150, and 300/300 ppm groups.

^a^ Statistical analysis performed by the Poly-3 test.

^b^ Number of animals examined microscopically.

^c^ Number of animals with lesion.

^d^ Average severity grade of lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Table 18 Incidences of Select Nonneoplastic Lesions of the Thyroid Gland and Kidney in Female Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)^a^

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 300 ppm | 1,000 ppm
n | | 10^b^ | 10 | 10
Thyroid Gland
Follicular Cell, Hypertrophy^c^ | 0 ppm | 0^##^ | 0 | 1 (1.0)^d^
| 150 ppm | – | 0 | –
| 300 ppm | – | – | 4* (1.3)
Kidney
Renal Tubule, Mineral | 0 ppm | 2** (1.0) | 1 (1.0) | 7* (1.0)
| 150 ppm | – | 2 (1.0) | –
| 300 ppm | – | – | 5 (1.2)
Papilla, Urothelium, Hyperplasia | 0 ppm | 0**^##^ | 0 | 4* (1.3)
| 150 ppm | – | 0 | –
| 300 ppm | – | – | 4* (1.0)

Statistical significance for a treatment group indicates a significant pairwise test compared to the 0/0 ppm control group. Statistical significance for the 0/0 ppm control group indicates a significant trend test.

Pairwise comparisons across perinatal exposures (0/300 vs. 150/300 ppm and 0/1,000 vs. 300/1,000 ppm) did not show any statistically significant differences.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^##^ Statistically significant trend at p ≤ 0.01 when comparing across the 0/0, 150/300, and 300/1,000 ppm groups.

^a^ Statistical analysis performed by the Poly-3 test.

^b^ Number of animals examined microscopically.

^c^ Number of animals with lesion.

^d^ Average severity grade of lesion in affected animals: 1 = minimal; 2 = mild; 3 = moderate; 4 = marked.

Kidney: In males, the incidences of renal tubule mineral were significantly increased in the 0/150, 0/300, and 300/300 ppm groups compared to the 0/0 ppm control group (Table 17).

In females, the incidences of papilla urothelium hyperplasia were significantly increased in the 0/1,000 and 300/1,000 ppm groups compared to the 0/0 ppm control (Table 18). The incidence of renal tubule mineral in the 0/1,000 ppm group was significantly greater than that of the 0/0 ppm control group. No differences between groups with perinatal and without perinatal exposures were observed.

Glandular Stomach: The incidences of chronic active inflammation of the submucosa were increased in all exposed male groups compared to the 0/0 ppm control group, but the increases were statistically significant only in the 0/300 ppm group (Table 17). No differences between groups with perinatal and without perinatal exposures were observed.

### Two-year Study in Females (Study 1)

Survival of exposed groups of females was similar to that of the 0/0 ppm control group (Table 19, Table 20; Figure 4). There were no exposure-related clinical observations (Appendix E).

Table 19 Survival of Female Rats Following Postweaning-only Exposure in the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)

| 0/0 ppm | 0/300 ppm | 0/1,000 ppm
Animals Initially in Study | 50 | 50 | 50
Moribund | 15 | 16 | 20
Natural Deaths | 12 | 6 | 7
Animals Surviving to Study Termination | 23 | 28^a^ | 23
Percent Probability of Survival at End of Study^b^ | 46.0 | 56.0 | 46.0
Mean Survival (days)^c^ | 646.6 | 695.3 | 626.1
Survival Analysis^d^ | p = 0.901 | p = 0.126N | p = 0.777N

^a^ Includes two animals that died naturally during the last week of the study.

^b^ Kaplan-Meier determinations.

^c^ Mean of litter means of all deaths (uncensored, censored, and study termination).

^d^ The result of the trend test is in the 0/0 ppm column, and the results of the pairwise comparisons with the 0/0 ppm control group are in the exposed group columns. Negative trends are indicated by N. Analyses were performed using a Cox Proportional Hazards Model with dam ID as a random effect.

Table 20 Survival of Female Rats Following Perinatal and Postweaning Exposure in the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)

| 0/0 ppm | 150/300 ppm | 300/1,000 ppm
Animals Initially in Study | 50 | 50 | 50
Moribund | 15 | 11 | 17
Natural Deaths | 12 | 7 | 10
Animals Surviving to Study Termination | 23 | 32 | 23^a^
Percent Probability of Survival at End of Study^b^ | 46.0 | 64.0 | 46.0
Mean Survival (days)^c^ | 646.6 | 681.1 | 660.0
Survival Analysis^d^ | p = 0.831 | p = 0.080N | p = 0.831N

^a^ Includes one animal that died naturally during the last week of the study.

^b^ Kaplan-Meier determinations.

^c^ Mean of litter means of all deaths (uncensored, censored, and study termination).

^d^ The result of the trend test is in the 0/0 ppm column, and the results of the pairwise comparisons with the 0/0 ppm control group are in the exposed group columns. Negative trends are indicated by N. Analyses were performed using a Cox Proportional Hazards Model with dam ID as a random effect.

Figure 4

Kaplan-Meier Survival Curves for Female Rats Exposed to Perfluorooctanoic Acid in Feed for Two Years

Exposure-related decreases in group mean body weights were observed for exposed females throughout the study (Table 21, Table 22; Figure 5; Figure 6). At study termination, group mean body weights for the 0/1,000 and 300/1,000 ppm groups were lower (19% and 27%, respectively) than those of the 0/0 ppm control group.

Table 21 Mean Body Weights and Survival of Female Rats Following Postweaning-only Exposure in the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)

Day | 0/0 ppm | | 0/300 ppm | | | 0/1,000 ppm
Day | Av. Wt. (g) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 55.4 | 32 | 53.3 | 96.2 | 29 | 53.3 | 96.3 | 31
8 | 82.3 | 32 | 77.7 | 94.4 | 29 | 67.8 | 82.4 | 31
15 | 111.6 | 32 | 109.3 | 97.9 | 29 | 89.4 | 80.1 | 31
22 | 146.3 | 32 | 143.7 | 98.3 | 29 | 118.0 | 80.7 | 31
29 | 168.8 | 32 | 167.9 | 99.4 | 29 | 141.5 | 83.8 | 31
36 | 188.5 | 32 | 185.4 | 98.3 | 29 | 159.1 | 84.4 | 31
43 | 202.2 | 32 | 201.3 | 99.5 | 29 | 174.4 | 86.2 | 31
50 | 213.2 | 32 | 209.3 | 98.2 | 29 | 185.9 | 87.2 | 31
57 | 224.4 | 32 | 219.7 | 97.9 | 29 | 194.9 | 86.9 | 31
64 | 231.4 | 32 | 226.1 | 97.7 | 29 | 201.0 | 86.8 | 31
71 | 236.8 | 32 | 231.4 | 97.7 | 29 | 208.7 | 88.1 | 31
78 | 241.2 | 32 | 237.3 | 98.3 | 29 | 213.6 | 88.5 | 31
85 | 245.7 | 32 | 241.8 | 98.4 | 29 | 216.0 | 87.9 | 31
120 | 256.6 | 32 | 255.2 | 99.4 | 29 | 227.3 | 88.6 | 31
141 | 269.1 | 32 | 263.2 | 97.8 | 29 | 238.4 | 88.6 | 31
169 | 279.3 | 32 | 273.2 | 97.8 | 29 | 243.5 | 87.2 | 31
197 | 287.1 | 32 | 279.8 | 97.4 | 29 | 249.2 | 86.8 | 31
225 | 291.9 | 32 | 285.1 | 97.7 | 29 | 255.2 | 87.4 | 30
253 | 299.6 | 32 | 291.0 | 97.1 | 29 | 261.3 | 87.2 | 29
281 | 302.9 | 32 | 296.3 | 97.8 | 29 | 261.1 | 86.2 | 29
309 | 313.0 | 32 | 302.0 | 96.5 | 29 | 268.5 | 85.8 | 28
337 | 317.3 | 31 | 305.6 | 96.3 | 29 | 268.5 | 84.6 | 28
365 | 324.2 | 31 | 313.2 | 96.6 | 29 | 275.1 | 84.9 | 28
393 | 331.2 | 30 | 320.2 | 96.7 | 29 | 276.0 | 83.3 | 28
421 | 339.7 | 29 | 329.0 | 96.9 | 29 | 279.6 | 82.3 | 28
449 | 339.8 | 29 | 332.9 | 98.0 | 29 | 276.6 | 81.4 | 28
477 | 346.4 | 29 | 336.7 | 97.2 | 29 | 286.8 | 82.8 | 28
505 | 356.3 | 29 | 342.2 | 96.0 | 29 | 291.1 | 81.7 | 28
533 | 364.0 | 28 | 347.3 | 95.4 | 29 | 300.6 | 82.6 | 28
561 | 366.0 | 27 | 353.5 | 96.6 | 29 | 296.0 | 80.9 | 27
589 | 369.8 | 26 | 351.5 | 95.1 | 27 | 301.1 | 81.4 | 27
617 | 372.9 | 26 | 351.9 | 94.4 | 27 | 300.6 | 80.6 | 27
645 | 376.8 | 24 | 356.7 | 94.7 | 27 | 300.1 | 79.7 | 26
673 | 383.1 | 23 | 359.9 | 94.0 | 27 | 300.2 | 78.4 | 25
701 | 378.2 | 21 | 375.6 | 99.3 | 23 | 305.1 | 80.7 | 23
729 | 383.9 | 19 | 369.3 | 96.2 | 21 | 303.5 | 79.0 | 20
EOS | 387.0 | 19 | 369.7 | 95.5 | 19 | 314.6 | 81.3 | 18

EOS = end of study.

Table 22 Mean Body Weights and Survival of Female Rats Following Perinatal and Postweaning Exposure in the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)

Day | 0/0 ppm | | 150/300 ppm | | | 300/1,000 ppm
Day | Av. Wt. (g) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 55.4 | 32 | 54.9 | 99.0 | 29 | 51.6 | 93.1 | 30
8 | 82.3 | 32 | 79.2 | 96.3 | 29 | 62.9 | 76.5 | 30
15 | 111.6 | 32 | 106.4 | 95.3 | 29 | 82.6 | 74.0 | 30
22 | 146.3 | 32 | 143.8 | 98.3 | 29 | 109.7 | 75.0 | 30
29 | 168.8 | 32 | 166.7 | 98.7 | 29 | 133.3 | 79.0 | 30
36 | 188.5 | 32 | 183.3 | 97.2 | 29 | 152.7 | 81.0 | 30
43 | 202.2 | 32 | 197.6 | 97.7 | 29 | 166.3 | 82.2 | 30
50 | 213.2 | 32 | 208.6 | 97.8 | 29 | 179.9 | 84.4 | 30
57 | 224.4 | 32 | 217.7 | 97.0 | 29 | 189.1 | 84.3 | 30
64 | 231.4 | 32 | 223.2 | 96.4 | 29 | 196.6 | 84.9 | 30
71 | 236.8 | 32 | 228.7 | 96.6 | 29 | 202.5 | 85.5 | 30
78 | 241.2 | 32 | 234.4 | 97.2 | 29 | 206.8 | 85.7 | 30
85 | 245.7 | 32 | 237.6 | 96.7 | 29 | 210.9 | 85.8 | 30
120 | 256.6 | 32 | 254.0 | 99.0 | 29 | 221.0 | 86.1 | 30
141 | 269.1 | 32 | 260.5 | 96.8 | 29 | 229.4 | 85.3 | 30
169 | 279.3 | 32 | 269.9 | 96.6 | 29 | 237.4 | 85.0 | 30
197 | 287.1 | 32 | 277.8 | 96.8 | 29 | 243.0 | 84.6 | 30
225 | 291.9 | 32 | 282.1 | 96.7 | 29 | 247.9 | 84.9 | 30
253 | 299.6 | 32 | 287.0 | 95.8 | 29 | 253.8 | 84.7 | 30
281 | 302.9 | 32 | 294.2 | 97.1 | 29 | 250.8 | 82.8 | 30
309 | 313.0 | 32 | 298.2 | 95.2 | 29 | 257.2 | 82.2 | 30
337 | 317.3 | 31 | 302.8 | 95.4 | 29 | 261.0 | 82.3 | 30
365 | 324.2 | 31 | 310.4 | 95.8 | 29 | 264.0 | 81.4 | 30
393 | 331.2 | 30 | 305.3 | 92.2 | 28 | 266.0 | 80.3 | 30
421 | 339.7 | 29 | 311.6 | 91.7 | 28 | 268.4 | 79.0 | 30
449 | 339.8 | 29 | 317.6 | 93.5 | 28 | 267.4 | 78.7 | 30
477 | 346.4 | 29 | 322.1 | 93.0 | 28 | 272.3 | 78.6 | 29
505 | 356.3 | 29 | 327.3 | 91.8 | 28 | 279.0 | 78.3 | 29
533 | 364.0 | 28 | 333.7 | 91.7 | 28 | 285.3 | 78.4 | 28
561 | 366.0 | 27 | 335.8 | 91.7 | 28 | 287.2 | 78.5 | 28
589 | 369.8 | 26 | 339.0 | 91.7 | 27 | 291.1 | 78.7 | 27
617 | 372.9 | 26 | 339.0 | 90.9 | 27 | 291.2 | 78.1 | 27
645 | 376.8 | 24 | 340.0 | 90.2 | 24 | 291.3 | 77.3 | 25
673 | 383.1 | 23 | 338.2 | 88.3 | 24 | 294.2 | 76.8 | 23
701 | 378.2 | 21 | 344.4 | 91.1 | 24 | 286.6 | 75.8 | 20
729 | 383.9 | 19 | 342.2 | 89.1 | 22 | 289.0 | 75.3 | 20
EOS | 387.0 | 19 | 346.5 | 89.5 | 22 | 283.7 | 73.3 | 19

EOS = end of study.

Figure 5

Growth Curves for Female Rats with Postweaning-only Exposure to 0/0, 0/300, or 0/1,000 ppm Perfluorooctanoic Acid in Feed for Two Years (Study 1)

Figure 6

Growth Curves for Female Rats with Perinatal and Postweaning Exposure to 0/0, 150/300, or 300/1,000 ppm Perfluorooctanoic Acid in Feed for Two Years (Study 1)

Group mean feed consumption over the course of the study averaged 93%, 99%, 96%, and 88% of the 0/0 ppm control group for the 0/300, 150/300, 0/1,000, and 300/1,000 ppm groups, respectively (Appendix E). After weaning, compound consumption for females in the 0/300 and 150/300 ppm groups averaged 18.2 and 18.4 mg/kg/day, respectively. Compound consumption averaged 63.4 and 63.5 mg/kg/day for the 0/1,000 and 300/1,000 ppm groups, respectively.

#### Pathology and Statistical Analyses

The morphologic features of the lesions discussed in this section are presented in the Histopathological Descriptions section following the Study 2 results.

Liver: Chronic exposure with and without perinatal exposure resulted in slight increases in the incidences of hepatocellular carcinoma in the 0/1,000 and 300/1,000 ppm groups, respectively; however, the increases were not significantly different from the incidence in the 0/0 ppm control group (Table 23). The occurrences of hepatocellular adenomas did not differ among the groups. The combined incidence of adenomas and carcinomas was marginally higher in the 1,000 ppm postweaning groups, which was primarily due to the higher incidence of carcinomas in these groups (Table 23). The one hepatocellular carcinoma present in the historical control is from this study. No differences between groups with perinatal and without perinatal exposures were observed.

Table 23 Incidences of Neoplastic and Nonneoplastic Liver Lesions in Female Rats in the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 300 ppm | 1,000 ppm
n | | 50^a^ | 50 | 50^b^
Hepatocyte, Cytoplasmic Alteration^c^ | 0 ppm | 0**^##^ | 9** (1.4)^d^ | 49** (2.3)
| 150 ppm | – | 17** (1.1) | –
| 300 ppm | – | – | 49** (2.2)
Hepatocyte, Hypertrophy | 0 ppm | 0**^##^ | 11** (1.7) | 48** (2.4)
| 150 ppm | – | 16** (1.6) | –
| 300 ppm | – | – | 49** (2.4)
Hepatocyte, Single Cell Death | 0 ppm | 0**^##^ | 4 (1.0) | 29** (1.3)
| 150 ppm | – | 5* (1.0) | –
| 300 ppm | – | – | 32** (1.2)
Necrosis | 0 ppm | 0** | 1 (1.0) | 8* (1.5)
| 150 ppm | – | 4 (1.3) | –
| 300 ppm | – | – | 5 (2.4)
Pigment | 0 ppm | 3**^##^ (1.3) | 5 (1.4) | 43** (1.7)
| 150 ppm | – | 10* (1.1) | –
| 300 ppm | – | – | 40** (1.8)
Bile Duct, Hyperplasia | 0 ppm | 16^#^ (1.3) | 25 (1.2) | 22 (1.2)
| 150 ppm | – | 27 (1.1) | –
| 300 ppm | – | – | 27* (1.3)
Hepatocyte, Increased Mitoses | 0 ppm | 2^#^ (1.0) | 3 (1.0) | 4 (1.5)
| 150 ppm | – | 5 (1.6) | –
| 300 ppm | – | – | 10* (1.3)
Hepatocellular Adenoma^e^
Overall Rate^f^ Litters Rate^g^ Rao-Scott Adjusted Poly-3 Test^h,i^ | 0 ppm | 2/50 (4%) 2/32 (6%) p = 0.543N/0.322 | 0/50 (0%) 0/29 (0%) p = 0.262N | 1/49 (2%) 1/31 (3%) p = 0.506N
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 0/50 (0%) 0/29 (0%) p = 0.251N | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 3/50 (6%) 3/30 (10%) p = 0.508
Hepatocellular Carcinoma^j^
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 1/50 (2%) 1/32 (3%) p = 0.211/0.089 | 1/50 (2%) 1/29 (3%) p = 0.709N | 3/49 (6%) 3/31 (10%) p = 0.318
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 0/50 (0%) 0/29 (0%) p = 0.524N | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 4/50 (8%) 4/30 (13%) p = 0.233
Hepatocellular Adenoma or Carcinoma, (Combined)^k^
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 3/50 (6%) 3/32 (9%) p = 0.332/0.093 | 1/50 (2%) 1/29 (3%) p = 0.275N | 4/49 (8%) 4/31 (13%) p = 0.491
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 0/50 (0%) 0/29 (0%) p = 0.126N | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 6/50 (12%) 6/30 (20%) p = 0.269

Statistical significance for a treatment group indicates a significant pairwise test compared to the 0/0 ppm control group. Statistical significance for the 0/0 ppm control group indicates a significant trend test.

Pairwise comparisons across perinatal exposures (0/300 vs. 150/300 ppm and 0/1,000 vs. 300/1,000 ppm) did not show any statistically significant differences.

* Significantly different (p ≤ 0.05) from the 0/0 ppm control group by the Rao-Scott test.; **p ≤ 0.01.

^#^ Statistically significant trend at p ≤ 0.05 when comparing across the 0/0, 150/300, and 300/1,000 ppm groups; ^##^p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ N = 49 for the 0/1,000 ppm group.

^c^ Number of animals with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^e^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 14/340 (3.63% ± 2.59%); range: 0% to 8%.

^f^ Number of animals with neoplasm per number of animals necropsied.

^g^ Number of litters with animals with neoplasm per number of litters necropsied.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidences are the p values corresponding to pairwise comparisons between the respective control and that exposed group. The Rao-Scott test adjusts the Poly-3 test for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^i^ Rao-Scott trend values presented as: p value (postweaning-only exposure groups)/p value (perinatal and postweaning exposure groups).

^j^ Historical control incidence: 1/340 (0.33% ± 0.82%); range: 0% to 2%.

^k^ Historical control incidence: 15/340 (3.96% ± 2.77%); range: 0% to 8%.

Chronic exposure with and without perinatal exposure resulted in exposure concentration-related increases in the incidences of a spectrum of nonneoplastic hepatocellular lesions (Table 23; Appendix E). Compared to the incidences in the 0/0 ppm control group, the incidences of hepatocyte cytoplasmic alteration and hepatocyte hypertrophy were significantly increased in all exposed female groups in the 2-year study. In general, the severity of these lesions tended to be minimal to moderate and were more severe in groups receiving the highest exposure concentrations. Hepatocyte hypertrophy and cytoplasmic alteration were generally colocalized hepatocellular changes.

The incidences of hepatocyte single cell death were significantly increased in the 150/300, 0/1,000, and 300/1,000 ppm groups compared to the 0/0 ppm control group (Table 23; Appendix E).

The incidences of necrosis were increased in all exposed groups; however, only the increase in the 0/1,000 ppm group reached statistical significance compared to the 0/0 ppm control group (Table 23; Appendix E).

The incidences of pigment were significantly increased in the 150/300, 0/1,000, and 300/1,000 ppm groups compared to the 0/0 ppm control group (Table 23; Appendix E).

The incidences of bile duct hyperplasia were increased in all exposed groups compared to the 0/0 ppm control group; the increase was significant only in the 300/1,000 ppm group (Table 23; Appendix E).

The incidences of hepatocyte mitoses were significantly increased in the 300/1,000 ppm group compared to the 0/0 ppm control group (Table 23; Appendix E).

Pancreas: In the 300/1,000 ppm group, slight increases were observed in the incidences of acinar cell adenoma, acinar cell adenocarcinoma and adenoma or adenocarcinoma combined that did not reach statistical significance compared to the 0/0 ppm control group (Table 24). One duct adenocarcinoma occurred in the 300/1,000 ppm group. (See 2-year study in males for description of the pancreatic lesions.) There were occurrences of hyperplasia, but they were not statistically significant. No differences between groups with perinatal and without perinatal exposures were observed.

Table 24 Incidences of Neoplastic and Nonneoplastic Pancreas Lesions in Female Rats in the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 300 ppm | 1,000 ppm
n | | 50^a^ | 50 | 50^b^
Acinus, Hyperplasia^c^ | 0 ppm | 0 | 1 (2.0)^d^ | 1 (2.0)
| 150 ppm | – | 0 | –
| 300 ppm | – | – | 1 (4.0)
Acinar Cell Adenoma^e^
Overall Rate^f^ Litters Rate^g^ Rao-Scott Adjusted Poly-3 Test^h^ | 0 ppm | 0/50 (0%) 0/32 (0%) p = 0.084^i^ | 0/50 0/29 _^j^ | 1/49 (2%) 1/31 (3%) (e)
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 0/50 (0%) 0/29 (0%) (e) | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 3/50 (6%) 3/30 (10%) p = 0.215
Acinar Cell Adenocarcinoma^k^
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 0/50 (0%) 0/32 (0%) p = 0.178^i^ | 0/50 0/29 _ | 1/49 (2%) 1/31 (3%) (e)
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 0/50 (0%) 0/29 (0%) (e) | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 2/50 (4%) 2/30 (7%) p = 0.340
Acinar Cell Adenoma or Adenocarcinoma, (Combined)^l^
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 0/50 (0%) 0/32 (0%) p = 0.174/0.018^m^ | 0/50 (0%) 0/29 (0%) (e) | 2/49 (4%) 2/31 (6%) p = 0.337
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 0/50 (0%) 0/29 (0%) (e) | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 5/50 (10%) 5/30 (17%) p = 0.086

Pairwise comparisons across perinatal exposures (0/300 vs. 150/300 ppm and 0/1,000 vs. 300/1,000 ppm) did not show any statistically significant differences.

(e) = value of statistic could not be computed.

^a^ Number of animals with tissue examined microscopically.

^b^ N = 49 for the 0/1,000 ppm group.

^c^ Number of animals with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^e^ Historical control incidence for all routes of 2-year studies: 0/340.

^f^ Number of animals with neoplasm per number of animals necropsied.

^g^ Number of litters with animals with neoplasm per number of litters necropsied.

^h^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidences are the p values corresponding to pairwise comparisons between the respective control and that exposed group. The Rao-Scott test adjusts the Poly-3 test for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^i^ P value represents the trend for the 0/0, 150/300, and 300/1,000 ppm groups.

^j^ Not applicable; no neoplasms in group.

^k^ Historical control incidence: 0/340.

^l^ Historical control incidence: 0/340.

^m^ Rao-Scott trend values presented as: p value (postweaning-only exposure groups)/p value (perinatal and postweaning exposure groups).

Uterus: In the standard evaluation of the perinatal and/or postweaning exposures, increased incidences of adenocarcinomas of the uterus, compared to the 0/0 ppm control group, occurred in the 0/300, 0/1,000, 150/300, and 300/1,000 ppm groups (Table 25).

In the extended evaluation, additional adenocarcinomas were diagnosed in the uteri of exposed groups (Table 25). The incidences of adenocarcinoma were increased in the 0/300 and 0/1,000 ppm groups; the increase in the 0/1,000 ppm group was significant.

In the combined standard and extended evaluations, the incidences of adenocarcinoma were increased in the 0/300, 0/1,000, 150/300, and 300/1,000 ppm groups; however, the increase was significant only in the 0/1,000 ppm group (Table 25). No differences between groups with perinatal and without perinatal exposures were observed.

Table 25 Incidences of Neoplastic and Nonneoplastic Lesions in the Standard and Extended Evaluations of the Uterus in the Two-year Feed Study of Perfluorooctanoic Acid in Female Rats (Study 1)

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 300 ppm | 1,000 ppm
Standard Evaluation
Hyperplasia, Atypical^a^ | 0 ppm | 0/50 | 0/49 | 0/49
| 150 ppm | – | 0/50 | –
| 300 ppm | – | – | 0/50
Adenoma^b^
Overall Rate^c^ Litters Rate^d^ Rao-Scott Adjusted Poly-3 Test^e^ | 0 ppm | 0/50 (0%) 0/32 (0%) p = 0.717N^f^ | 1/49 (2%) 1/29 (3%) p = 0.591 | 0/49 (0%) 0/31 (0%) (e)
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 0/50 0/29 _^g^ | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 0/50 0/30 _
Adenocarcinoma^h^
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 0/50 (0%) 0/32 (0%) p = 0.049/0.512^i^ | 1/49 (2%) 1/29 (3%) p = 0.548 | 4/49 (8%) 4/31 (13%) p = 0.102
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 2/50 (4%) 2/29 (7%) p = 0.285 | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 1/50 (2%) 1/30 (3%) p = 0.477
Adenoma or Adenocarcinoma, (Combined)^j^
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 0/50 (0%) 0/32 (0%) p = 0.068/0.512 | 2/49 (4%) 2/29 (7%) p = 0.285 | 4/49 (8%) 4/31 (13%) p = 0.086
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 2/50 (4%) 2/29 (7%) p = 0.285 | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 1/50 (2%) 1/30 (3%) p = 0.477
Extended Evaluation
Hyperplasia, Atypical | 0 ppm | 3/50 | 4/49 | 3/48
| 150 ppm | – | 7/50 | –
| 300 ppm | – | – | 3/48
Adenoma
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 1/50 (2%) 1/32 (3%) p = 0.521N/0.518N | 0/49 (0%) 0/29 (0%) p = 0.578N | 0/48 (0%) 0/30 (0%) p = 0.579N
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 0/50 (0%) 0/29 (0%) p = 0.574N | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 0/48 (0%) 0/30 (0%) p = 0.578N
Adenocarcinoma
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 1/50 (2%) 1/32 (3%) p = 0.055/0.089 | 5/49 (10%) 5/29 (17%) p = 0.159 | 7/48 (15%) 6/30 (20%) p = 0.050
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 3/50 (6%) 3/29 (10%) p = 0.346 | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 5/48 (10%) 5/30 (17%) p = 0.110
Adenoma or Adenocarcinoma, (Combined)
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 2/50 (4%) 2/32 (6%) p = 0.094/0.160 | 5/49 (10%) 5/29 (17%) p = 0.280 | 7/48 (15%) 6/30 (20%) p = 0.102
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 3/50 (6%) 3/29 (10%) p = 0.535 | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 5/48 (10%) 5/30 (17%) p = 0.212
Standard or Extended Evaluation (Combined)
Hyperplasia, Atypical | 0 ppm | 3/50 (2.0)^k^ | 4/49 (2.0) | 3/49 (2.7)
| 150 ppm | – | 7/50 (2.1) | –
| 300 ppm | – | – | 3/50 (4.0)
Adenoma
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 1/50 (2%) 1/32 (3%) p = 0.376N/0.513N | 1/49 (2%) 1/29 (3%) p = 0.717N | 0/49 (0%) 0/31 (0%) p = 0.489N
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 0/50 (0%) 0/29 (0%) p = 0.576N | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 0/50 (0%) 0/30 (0%) p = 0.573N
Adenocarcinoma
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 1/50 (2%) 1/32 (3%) p = 0.054/0.094 | 5/49 (10%) 5/29 (17%) p = 0.159 | 7/49 (14%) 6/31 (19%) p = 0.050
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 3/50 (6%) 3/29 (10%) p = 0.345 | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 5/50 (10%) 5/30 (17%) p = 0.115
Adenoma or Adenocarcinoma, (Combined)
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 2/50 (4%) 2/32 (6%) p = 0.094/0.169 | 5/49 (10%) 5/29 (17%) p = 0.280 | 7/49 (14%) 6/31 (19%) p = 0.101
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 150 ppm | – | 3/50 (6%) 3/29 (10%) p = 0.535 | –
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | – | – | 5/50 (10%) 5/30 (17%) p = 0.220

Pairwise comparisons across perinatal exposures (0/300 vs. 150/300 ppm and 0/1,000 vs. 300/1,000 ppm) did not show any statistically significant differences.

(e) = value of statistic could not be computed.

^a^ Number of animals with lesion/number of animals with tissue examined microscopically.

^b^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 1/150 (0.67% ± 1.15%); range: 0% to 2%.

^c^ Number of animals with neoplasm per number of animals necropsied.

^d^ Number of litters with animals with neoplasm per number of litters necropsied.

^e^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidences are the p values corresponding to pairwise comparisons between the respective control and that exposed group. The Rao-Scott test adjusts the Poly-3 test for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^f^ P value represents the trend for the 0/0, 0/300, and 0/1,000 ppm groups.

^g^ Not applicable; no neoplasms in group.

^h^ Historical control incidence: 11/150 (7.33% ± 4.62%); range: 2% to 10%.

^i^ Rao-Scott trend values presented as: p value (postweaning-only exposure groups)/p value (perinatal and postweaning exposure groups).

^j^ Historical control incidence: 12/150 (8% ± 3.46%); range: 4% to 10%.

^k^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Kidney: Compared to the 0/0 ppm control group, the incidences of hyperplasia of the renal papillary epithelium were significantly increased in the 0/300, 0/1,000, and 300/1,000 ppm groups (Table 26). The incidences of papilla necrosis were significantly increased in the 0/1,000 and 300/1,000 ppm groups. The incidence of renal tubule mineral was significantly increased in the 0/1,000 ppm group. In general, the incidences of these kidney lesions increased with increasing exposure concentration. There were some statistical differences observed in groups with and without perinatal exposure. The incidence of hyperplasia of the renal papillary epithelium in the 150/300 ppm group was significantly decreased compared to the 0/300 ppm group. It is not clear if this was related to perinatal exposure as this only occurred with the 150 ppm perinatal exposure and not the 300 ppm perinatal exposure. In addition, there was a decrease of renal tubule mineral in the 300/1,000 ppm group compared to the 0/1,000 ppm group. Similarly, it is unclear if this is related to perinatal exposure.

Table 26 Incidences of Select Nonneoplastic Lesions in the Kidney, Stomach, and Thyroid Gland of Female Rats in the Two-year Feed Study of Perfluorooctanoic Acid (Study 1)

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 300 ppm | 1,000 ppm
n | | 50^a^ | 50 | 50^b^
Kidney
Papilla, Urothelium, Hyperplasia^c^ | 0 ppm | 4**^##^ (1.0)^d^ | 21** (1.0) | 40** (1.9)
| 150 ppm | – | 8^^ (1.0) | –
| 300 ppm | – | – | 45** (1.8)
Papilla, Necrosis | 0 ppm | 0**^##^ | 0 | 12** (2.3)
| 150 ppm | – | 0 | –
| 300 ppm | – | – | 22** (2.1)
Renal Tubule, Mineral | 0 ppm | 5** (1.2) | 6 (1.3) | 16** (1.0)
| 150 ppm | – | 8 (1.0) | –
| 300 ppm | – | – | 8^ (1.5)
Forestomach
Ulcer | 0 ppm | 2**^##^ (1.5) | 2 (1.5) | 9* (1.6)
| 150 ppm | – | 1 (1.0) | –
| 300 ppm | – | – | 11* (2.1)
Epithelium, Hyperplasia | 0 ppm | 4**^##^ (2.3) | 5 (1.8) | 22** (2.8)
| 150 ppm | – | 3 (2.3) | –
| 300 ppm | – | – | 21** (2.5)
Submucosa, Inflammation, Chronic Active | 0 ppm | 3**^##^ (2.3) | 2 (2.5) | 16** (2.6)
| 150 ppm | – | 2 (2.0) | –
| 300 ppm | – | – | 18** (2.5)
Thyroid Gland
Follicular Cell, Hypertrophy | 0 ppm | 4**^##^ (2.3) | 8 (2.1) | 28** (2.0)
| 150 ppm | – | 9 (1.6) | –
| 300 ppm | – | – | 19** (1.7)

Statistical significance for a treatment group indicates a significant pairwise test compared to the 0/0 ppm control group. Statistical significance for the 0/0 ppm control group indicates a significant trend test.

* Significantly different (p ≤ 0.05) from the 0/0 ppm control by the Rao-Scott test; **p ≤ 0.01.

^##^ Statistically significant trend at p ≤ 0.01 when comparing across the 0/0, 150/300, and 300/1,000 ppm groups.

^ Statistically different (p ≤ 0.05) when comparing the 0/300 vs. 150/300 ppm groups or 0/1,000 vs. 300/1,000 groups; ^^p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ N = 49 for the 0/1,000 ppm group.

^c^ Number of animals with lesion.

^d^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Forestomach: The incidences of ulcer, epithelium hyperplasia, and chronic active inflammation of the submucosa in the 0/1,000 and 300/1,000 ppm groups were significantly greater than those in the 0/0 ppm control group (Table 26). Both exposed groups had a single case of a squamous cell papilloma (Appendix E).

Thyroid Gland: The incidences of follicular cell hypertrophy in the 0/1,000 and 300/1,000 ppm groups were significantly greater than those in the 0/0 ppm control group (Table 26). No differences between groups with perinatal and without perinatal exposures were observed.

## Study 2: Two-year Study in Males with 16-week Interim Evaluation

### Perinatal Exposure

No exposure-related effects were observed on the pregnancy status, maternal survival, or number of dams that littered (Table 27). PFOA fetal and lactational transfer was assessed at GD 18 and PND 4, respectively (Table 28). Maternal plasma concentrations of the 300 ppm group were 75.1 μM on GD 18 and 74.2 μM on PND 4. Concentrations of PFOA from fetuses pooled by litter on GD 18 were 23 μM, indicating some maternal transfer with maternal plasma concentrations at 75 μM. On PND 4, concentrations from whole male and female pups were comparable at 11 μM and 10 μM, respectively, indicating some lactational transfer (Table 28). Concentrations of PFOA were below detection in the control group.

Table 27 Summary of Disposition during Perinatal Exposure and F_1_ Allocation in the Two-year Perinatal and Postweaning Study of Perfluorooctanoic Acid (Study 2)

| 0 ppm | 300 ppm
Time-mated Females | 147 | 147
Pregnant Females | 129 | 123
Nonpregnant Females | 18 | 24
Biological Sample Analysis (GD 18) | 6^a^ | 5
Pregnant Dams Not Delivering | 4 | 6
Moribund (Dystocia) | 1 | 0
Littered/Pregnant on GD 21 | 119/123 (97%) | 112/118 (95%)
Litters Removed (PND 4)^b^ | 11 | 5
Litters Poststandardization (PND 4) | 108 | 107
Weaned Males | 240 | 240

^a^ Includes one dam that was not pregnant.

^b^ Removed due to insufficient size.

Table 28 Perfluorooctanoic Acid Concentrations in F_0_ and F_1_ Rats in the Two-year Perinatal and Postweaning Study of Perfluorooctanoic Acid (Study 2)^a^

| 0 ppm | 300 ppm
Gestation Day 18
F_0_ Plasma Concentration (ng/mL) | BD | 31,080 ± 1,227 (5)
F_0_ Plasma Concentration (μM) | BD | 75.1 ± 3.0 (5)
F_1_ Pooled Whole Fetus (ng/g) | BD | 9,374 ± 1,785 (5)
F_1_ Pooled Whole Fetus (μM) | BD | 23 ± 4 (5)
Postnatal Day 4
F_0_ Plasma Concentration (ng/mL) | BD | 30,725 ± 2,782 (4)
F_0_ Plasma Concentration (μM) | BD | 74.2 ± 6.74 (4)
F_1_ Pooled Whole Male Pup (ng/g) | BD | 4,539 ± 320 (4)
F_1_ Pooled Whole Male Pup (μM) | BD | 11 ± 1 (4)
F_1_ Pooled Whole Female Pup (ng/g) | BD | 4,132 ± 517 (3)
F_1_ Pooled Whole Female Pup (μM) | BD | 10 ± 1 (3)

BD = below detection.

^a^ Mean ± standard error (number of dams, fetuses, or pups). No statistical analysis was performed.

Maternal body weights of the 300 ppm group during gestation were similar to those of the control group (Table 29). A slight decrease in body weight gain was observed at the first interval of GD 6 to 9, but overall weight gain from GD 6 to 21 was not affected by exposure (Table 29). During lactation, there was a marginal decrease (2% to 3%) in maternal weight compared to the control group and a decrease in body weight gain over this time period (Table 30).

Table 29 Mean Body Weights and Body Weight Gains of F_0_ Females during Gestation in the Two-year Perinatal and Postweaning Study of Perfluorooctanoic Acid (Study 2)^a^

Gestation Day | 0 ppm | 300 ppm
Body Weight (g)
6 | 214.14 ± 1.11 (129) | 213.74 ± 1.18 (123)
9 | 229.97 ± 1.33 (129) | 227.52 ± 1.40 (123)
12 | 247.19 ± 1.20 (129) | 245.27 ± 1.21 (123)
15 | 264.53 ± 1.34 (129) | 262.78 ± 1.30 (123)
18 | 298.93 ± 1.97 (129) | 299.40 ± 1.83 (123)
21 | 341.68 ± 2.88 (124) | 341.25 ± 2.71 (118)
Body Weight Change (g)
6 to 9 | 15.83 ± 0.68 (129) | 13.77 ± 0.66* (123)
9 to 12 | 17.22 ± 0.57 (129) | 17.75 ± 0.70 (123)
12 to 15 | 17.34 ± 0.51 (129) | 17.51 ± 0.43 (123)
15 to 18 | 34.40 ± 0.89 (129) | 36.62 ± 0.90 (123)
18 to 21 | 43.04 ± 1.07 (124) | 42.24 ± 1.16 (118)
6 to 21 | 127.70 ± 2.49 (124) | 127.68 ± 2.46 (118)

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05.

^a^ Mean ± standard error (number of dams). The exposed group was compared to the control group using a t-test.

Table 30 Mean Body Weights and Body Weight Gains of F_0_ Females during Lactation in the Two-year Perinatal and Postweaning Study of Perfluorooctanoic Acid (Study 2)^a^

Lactation Day | 0 ppm | 300 ppm
Body Weight (g)
1 | 259.90 ± 1.35 (119) | 257.71 ± 1.35 (112)
4 | 271.11 ± 1.41 (119) | 267.13 ± 1.36* (112)
7 | 281.72 ± 1.37 (108) | 276.49 ± 1.36** (107)
14 | 296.06 ± 1.64 (107) | 290.23 ± 1.35** (107)
21 | 283.21 ± 1.60 (107) | 274.49 ± 1.40** (107)
Body Weight Change (g)
1 to 4 | 11.21 ± 0.60 (119) | 9.42 ± 0.52* (112)
4 to 7 | 9.63 ± 0.65 (108) | 9.72 ± 0.69 (107)
7 to 14 | 14.25 ± 1.09 (107) | 13.74 ± 0.73 (107)
14 to 21 | −12.85 ± 1.10 (107) | −15.74 ± 0.74* (107)
1 to 21 | 22.61 ± 1.10 (107) | 16.99 ± 0.91** (107)

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group.

^*^ Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Mean ± standard error (number of dams). The exposed group was compared to the control group using a t-test.

Feed consumption (g/animal/day) was marginally lower (≤ 3%) in the 300 ppm group compared to the control group at two intervals during gestation, but overall GD 6 to 21 feed consumption was unaffected (Table 31). Feed consumption by the 300 ppm female group during lactation was marginally less (approximately 5%) than that of the control group from LD 1 to 14 (Table 31). Chemical consumption was 21.8 mg/kg/day during gestation and 48.3 mg/kg/day during days 1 to 14 of the lactational period.

Table 31 Feed Consumption by F_0_ Females during Gestation and Lactation in the Two-year Perinatal and Postweaning Study of Perfluorooctanoic Acid (Study 2)^a^

Days | 0 ppm | 300 ppm
Gestation (g/animal/day)
6 to 9 | 17.03 ± 0.20 (129) | 16.52 ± 0.20** (123)
9 to 12 | 17.34 ± 0.13 (129) | 17.58 ± 0.11 (123)
12 to 15 | 18.77 ± 0.15 (129) | 18.27 ± 0.18** (123)
15 to 18 | 21.02 ± 0.21 (129) | 21.50 ± 0.29 123)
18 to 21 | 21.24 ± 0.22 (124) | 21.15 ± 0.26 (118)
6 to 21 | 19.11 ± 0.14 (124) | 18.99 ± 0.12 (118)
Lactation (g/animal/day)
1 to 4 | 41.24 ± 1.47 (115) | 38.18 ± 1.11** (112)
4 to 7 | 40.00 ± 0.37 (108) | 38.66 ± 0.30* (107)
7 to 10 | 47.89 ± 0.43 (107) | 45.14 ± 0.34** (107)
10 to 14 | 54.50 ± 0.41 (106) | 53.25 ± 0.39* (107)
14 to 17 | 57.58 ± 0.60 (107) | 55.66 ± 0.37** (107)
17 to 21 | 67.70 ± 0.81 (107) | 66.83 ± 0.59 (107)
1 to 14 | 46.81 ± 0.42 (102) | 44.62 ± 0.34** (107)

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

^a^ Mean ± standard error in grams/cage per day (number of dams). The exposed group was compared to the control group using the Wilcoxon rank-sum test.

Live litter sizes on PNDs 1 and 21 were not affected by exposure, and survival of F_1_ pups was not affected between PNDs 4 poststandardization and 21 (Table 32). The mean pup body weight of the 300 ppm group was 4% less than that of the controls on PND 1. F_1_ 300 ppm male weights were less than control group weights throughout lactation, ranging from 3% lower at PND 1 to 7% lower at PND 21.

Table 32 Mean Litter Size, Survival Ratio, and Mean Body Weights of F_1_ Rats during Lactation in the Two-year Perinatal and Postweaning Study of Perfluorooctanoic Acid (Study 2)

Postnatal Day | 0 ppm | 300 ppm
Live Litter Size^a^
1 | 11.72 ± 0.26 (118) | 11.52 ± 0.24 (112)
4 (Poststandardization) | 8.00 ± 0.00 (118) | 7.99 ± 0.01 (112)
21 | 7.81 ± 0.07 (118) | 7.89 ± 0.03 (112)
Survival Ratio^a,b^
4 to 21 | 0.98 ± 0.01 (118) | 0.99 ± 0.00 (112)
Body Weight
All Pups^a,c^
1^c^ | 7.37 ± 0.06 (118) | 7.07 ± 0.05** (112)
Male Pups
1^c^ | 7.50 ± 0.06 (116) | 7.26 ± 0.06** (111)
4^d^ | 10.57 ± 0.12 (436/108) | 10.14 ± 0.10** (435/107)
7^d^ | 15.90 ± 0.18 (435/108) | 15.03 ± 0.15** (435/107)
14^d^ | 31.64 ± 0.30 (427/107) | 30.19 ± 0.24** (431/107)
21^d^ | 52.35 ± 0.48 (421/106) | 48.84 ± 0.43** (428/107)

Statistical significance for a treatment group indicates a significant pairwise test compared to the vehicle control group.

** Statistically significant at p ≤ 0.01.

^a^ Mean ± standard error (number of dams). The exposed group was compared to the control group using the Wilcoxon rank-sum test.

^b^ Number of live pups on PND 21/number of live pups on PND 4 poststandardization.

^c^ Mean ± standard error (number of dams). The exposed group was compared to the control group using a t-test.

^d^ Mean ± standard error (number of pups/number of dams). Values were adjusted for live litter size at PND 4 poststandardization; a mixed-litter effects model was used to compare the exposed group to the control group.

### Sixteen-week Interim Evaluation in Males (Study 2)

All rats designated for interim evaluation survived until 16 weeks (Appendix E). There were no clinical observations in any of the exposed groups (Appendix E).

Group mean feed and compound consumption data are presented in Appendix E. Feed consumption (g/animal/day) in all groups remained within 10% of the 0/0 ppm control group throughout the study. PFOA consumption for the first 13 weeks postweaning averaged 1.9 mg/kg/day for the 0/20 and 300/20 ppm groups, 4.0 mg/kg/day for the 0/40 and 300/40 ppm groups, and 7.9 and 8.0 mg/k/day for the 0/80 and 300/80 ppm groups, respectively. In general, chemical consumption increased in proportion with exposure concentration (ppm).

Plasma concentrations of PFOA in males were consistent between groups that were exposed postweaning (300 ppm) or not exposed to PFOA (Table 33). The differences between groups (e.g., 0/20 and 300/20 ppm) were 12% or less. Liver concentrations followed a similar pattern as the plasma concentrations.

Table 33 Summary of Plasma and Liver Concentration Data for Male Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 2)^a,b^

| Perinatal Exposure | | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 20 ppm | 40 ppm | 80 ppm
n | | 10 | 10 | 10 | 10
Plasma Concentration (ng/mL) | 0 ppm | BD | 81,400 ± 2,715 | 130,780 ± 7,560 | 159,600 ± 8,303
| 300 ppm | 36 ± 12** | 78,030 ± 2,976** | 117,060 ± 4,189** | 144,100 ± 5,480**
Plasma Concentration (μM) | 0 ppm | BD | 196.6 ± 6.6 | 315.8 ± 18.3 | 385.5 ± 20.1
| 300 ppm | 0.1 ± 0.0** | 188.5 ± 7.2** | 282.7 ± 10.1** | 348.0 ± 13.2**
Liver Concentration (ng/g) | 0 ppm | BD | 83,550 ± 4,658 | 108,280 ± 5,412 | 147,400 ± 10,629
| 300 ppm | BD | 85,960 ± 3,635 | 109,210 ± 3,039 | 133,310 ± 4,625
Liver Concentration (μM) | 0 ppm | BD | 201.8 ± 11.2 | 261.5 ± 13.1 | 356.0 ± 25.7
| 300 ppm | BD | 207.6 ± 8.8 | 263.8 ± 7.3 | 322.0 ± 11.2
Liver/Plasma Ratio | 0 ppm | BD | 1.02 ± 0.03 | 0.84 ± 0.04 | 0.92 ± 0.03
| 300 ppm | BD | 1.11 ± 0.04 | 0.94 ± 0.03 | 0.94 ± 0.05

Statistical significance for a treatment group indicates a significant pairwise test compared to the respective control group (0/0 or 300/0 ppm). Statistical significance for the 0/0 ppm or 300/0 ppm control group indicates a significant trend test.

Pairwise comparisons across perinatal exposures (0/20 vs. 300/20, 0/40 vs. 300/40, and 0/80 vs. 300/80 ppm) did not show any statistically significant differences.

** Statistically significant at p ≤ 0.01.

Values adjusted for molar concentration were calculated by dividing by the molecular weight of 414.06.

BD = below detection; group did not have over 20% of its values above the limit of quantification. In these cases, no statistical analyses were performed.

^a^ Data presented as mean ± SEM.

^b^ Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests (unless otherwise noted).

Group mean body weights are provided in Appendix E. Group mean body weights for the 0/20, 300/0, and 300/20 ppm groups were within 10% of the 0/0 ppm control group until the interim evaluation. At 16 weeks, group mean body weights for the 0/40, 300/40, 0/80, and 300/80 ppm groups were 18%, 14%, 19%, and 21% less than that of the 0/0 ppm control group, respectively (Table 34).

Table 34 Summary of Hepatic Findings for Male Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 2)^a,b^

| Perinatal Exposure | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 20 ppm | 40 ppm | 80 ppm
n | | 10^c^ | 10 | 10 | 10
Necropsy Body Wt. (g) | 0 ppm | 429.8 ± 12.1** | 389.5 ± 7.9** | 351.8 ± 8.7** | 348.4 ± 10.2**
| 300 ppm | 414.6 ± 7.5** | 390.5 ± 7.7† | 367.5 ± 7.2**†† | 338.4 ± 13.7**††
Liver Weight
Absolute (g) | 0 ppm | 14.62 ± 0.43** | 17.99 ± 0.42** | 18.80 ± 0.76** | 19.74 ± 0.90**
| 300 ppm | 13.57 ± 0.30** | 17.33 ± 0.66**†† | 18.49 ± 0.47**†† | 18.64 ± 1.04**††
Relative (mg/g) | 0 ppm | 34.10 ± 0.81** | 46.24 ± 0.90** | 53.38 ± 1.49** | 56.56 ± 1.71**
| 300 ppm | 32.73 ± 0.43** | 44.27 ± 1.02**†† | 50.30 ± 0.76**†† | 55.07 ± 2.18**††
n | | 10 | 10 | 10 | 10
Acyl-CoA Oxidase Activity (nmol/min/mg) | 0 ppm | 2.636 ± 0.107** | 11.436 ± 0.660** | 19.360 ± 1.170** | 25.010 ± 1.973**
| 300 ppm | 2.754 ± 0.073** | 13.779 ± 1.484**†† | 18.420 ± 1.061**†† | 25.320 ± 2.438**††
Aromatase Activity (pmol/mg/min) | 0 ppm | 7.658 ± 0.718** | 15.910 ± 0.842** | 14.539 ± 1.075** | 16.630 ± 0.766**
| 300 ppm | 8.837 ± 0.782** | 15.951 ± 1.059**†† | 17.560 ± 1.477**†† | 16.640 ± 1.083**††

Statistical significance for a treatment group indicates a significant pairwise test compared to the respective control group (0/0 or 300/0 ppm). Statistical significance for the 0/0 ppm or 300/0 ppm control group indicates a significant trend test.

Pairwise comparisons across perinatal exposures (0/20 vs. 300/20, 0/40 vs. 300/40, and 0/80 vs. 300/80 ppm) did not show any statistically significant differences.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

† Statistically significant at p ≤ 0.05 for pairwise comparisons of 0/0 to 300/20 ppm, 0/0 to 300/40 ppm, and 0/0 to 300/80 ppm using a Wilcoxon rank-sum test with a Hommel adjustment (enzyme activity) or a t-test with a Hommel adjustment (body and organ weights); ††p ≤ 0.01.

^a^ Data presented as mean ± SEM.

^b^ Statistical analysis of body and organ weights performed using Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests. Statistical analysis of enzyme activity performed using Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests.

^c^ Number of animals examined.

With the exception of the 300/0 ppm group, the group mean absolute and relative liver weights of all exposed groups were significantly greater than those of the 0/0 ppm control group (Table 34). Histological correlates were present in all groups that had liver weight changes (Appendix E). No differences were observed between groups with and without perinatal exposures.

Acyl-CoA oxidase enzyme activity within the liver was increased in all postweaning exposed groups compared to the 0/0 ppm control group (Table 34). The magnitude of the increase was similar between groups that were perinatally exposed or not (e.g., 0/20 vs. 300/20 ppm). Aromatase activity within the liver was increased marginally in all postweaning exposed groups with roughly a doubling in activity compared to the 0/0 ppm control group (Table 34). Note that the 0/0 ppm control group and 300/0 ppm groups had similar acyl-CoA oxidase and aromatase activity. No differences were observed between groups with and without perinatal exposures.

With the exception of the relative weight of the 0/80 ppm group, the group mean absolute and relative spleen weights of all exposed groups were significantly less than those of the 0/0 ppm control group (Table 35; Appendix E). Absolute weights were decreased up to 29% compared to the 0/0 ppm control group without a histological correlate.

Table 35 Select Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 2)^a,b^

| Perinatal Exposure | | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 20 ppm | 40 ppm | 80 ppm
n | | 10^c^ | 10 | 10 | 10
Spleen Weight
Absolute (g) | 0 ppm | 0.793 ± 0.029** | 0.634 ± 0.025** | 0.564 ± 0.014** | 0.577 ± 0.031**
| 300 ppm | 0.648 ± 0.016**^##^ | 0.643 ± 0.025†† | 0.589 ± 0.015†† | 0.540 ± 0.035**††
Relative (mg/g) | 0 ppm | 1.85 ± 0.08* | 1.63 ± 0.05* | 1.61 ± 0.05* | 1.66 ± 0.07
| 300 ppm | 1.57 ± 0.04^#^ | 1.64 ± 0.04† | 1.60 ± 0.02† | 1.59 ± 0.06†
Right Kidney Weight
Absolute (g) | 0 ppm | 1.14 ± 0.04 | 1.31 ± 0.03** | 1.26 ± 0.04 | 1.19 ± 0.04
| 300 ppm | 1.17 ± 0.02 | 1.27 ± 0.02† | 1.23 ± 0.03 | 1.18 ± 0.05
Relative (mg/g) | 0 ppm | 2.66 ± 0.06** | 3.36 ± 0.07** | 3.59 ± 0.04** | 3.42 ± 0.06**
| 300 ppm | 2.83 ± 0.04** | 3.26 ± 0.05**†† | 3.35 ± 0.05**†† | 3.47 ± 0.05**††

Statistical significance for a treatment group indicates a significant pairwise test compared to the respective control group (0/0 or 300/0 ppm). Statistical significance for the 0/0 ppm or 300/0 ppm control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

† Statistically significant at p ≤ 0.05 for pairwise comparisons of 0/0 to 300/20 ppm, 0/0 to 300/40 ppm, and 0/0 to 300/80 ppm using a t-test with a Hommel p value adjustment (body and organ weights); ††p ≤ 0.01.

^#^ Statistically significant at p ≤ 0.05 for pairwise comparisons of 0/0 to 300/0 ppm, 0/20 to 300/20 ppm, 0/40 to 300/40 ppm, and 0/80 to 300/80 pm using a t-test with a Hommel p value adjustment; ^##^p ≤ 0.01.

^a^ Data presented as mean ± SEM.

^b^ Statistical analysis of body and organ weights performed using Jonckheere’s (trend) and Williams’ or Dunnett’s (pairwise) tests.

^c^ Number of animals examined.

With the exception of the 300/0 ppm group, the group mean relative right kidney weights of all exposed groups were significantly greater than that of the 0/0 ppm control group (Table 35; Appendix E). The absolute right kidney weight of the 0/20 ppm group was significantly greater than that of the 0/0 ppm control groups. There were no correlated histological findings to explain the increases in kidney weights. Overall, organ weight changes in the adrenal, heart, pituitary gland, lung, testis, thymus, and thyroid gland were considered secondary to body weight changes (Appendix E).

Clinical chemistry data are presented in Table 36. Compared to the 0/0 ppm control group, urea nitrogen concentrations were significantly increased in the 0/40, 0/80, 300/40, and 300/80 ppm groups. Mild increases in urea nitrogen without concomitant increases in creatinine concentration usually indicate decreased water consumption (i.e., mild dehydration). Triglyceride concentrations were significantly decreased in the 0/20, 0/40, 300/20, 300/40, and 300/80 ppm groups. Cholesterol concentrations were significantly decreased in the 300/20 and 300/80 ppm groups. No differences were observed between groups with and without perinatal exposures.

Table 36 Select Clinical Chemistry Findings for Male Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 2)^a,b^

| Perinatal Exposure | | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 20 ppm | 40 ppm | 80 ppm
n | | 10^c^ | 10 | 10 | 10
Urea Nitrogen (mg/dL) | 0 ppm | 17.0 ± 0.3** | 18.6 ± 0.7 | 20.4 ± 0.7** | 19.8 ± 0.8**
| 300 ppm | 16.4 ± 0.5** | 18.0 ± 0.4* | 20.3 ± 0.7**†† | 22.4 ± 1.4**††
Total Protein (g/dL) | 0 ppm | 6.58 ± 0.06** | 6.13 ± 0.10** | 5.92 ± 0.07** | 5.98 ± 0.07**
| 300 ppm | 6.45 ± 0.07 | 6.15 ± 0.07*†† | 5.96 ± 0.06**†† | 6.32 ± 0.09^#^†
Albumin (g/dL) | 0 ppm | 4.24 ± 0.06** | 4.53 ± 0.10 | 4.61 ± 0.06** | 4.65 ± 0.06**
| 300 ppm | 4.31 ± 0.04** | 4.60 ± 0.07**†† | 4.51 ± 0.07*† | 4.91 ± 0.06**^#^††
Globulin (g/dL) | 0 ppm | 2.34 ± 0.05** | 1.60 ± 0.06** | 1.31 ± 0.07** | 1.33 ± 0.06**
| 300 ppm | 2.14 ± 0.06** | 1.55 ± 0.07**†† | 1.45 ± 0.05**†† | 1.41 ± 0.10**††
A/G Ratio | 0 ppm | 1.82 ± 0.06** | 2.87 ± 0.13** | 3.60 ± 0.18** | 3.55 ± 0.16**
| 300 ppm | 2.03 ± 0.05** | 3.02 ± 0.13**†† | 3.14 ± 0.12**†† | 3.64 ± 0.27**††
Triglycerides (mg/dL) | 0 ppm | 98.8 ± 6.1 | 58.4 ± 4.3** | 64.2 ± 4.5** | 73.1 ± 6.9
| 300 ppm | 93.3 ± 7.9* | 59.9 ± 4.6*†† | 67.5 ± 7.0†† | 62.2 ± 5.0*††
Cholesterol (mg/dL) | 0 ppm | 132.4 ± 5.4 | 114.3 ± 5.1 | 117.9 ± 4.9 | 120.7 ± 3.6
| 300 ppm | 132.6 ± 4.6 | 105.8 ± 4.1**†† | 118.9 ± 4.1 | 115.1 ± 3.9†
Alanine Aminotransferase (IU/L) | 0 ppm | 44.70 ± 2.62** | 76.40 ± 5.25** | 65.90 ± 2.85** | 74.00 ± 3.64**
| 300 ppm | 51.20 ± 2.25** | 67.00 ± 2.17**†† | 68.50 ± 7.95**†† | 70.00 ± 4.49**††
Alkaline Phosphatase (IU/L) | 0 ppm | 170.1 ± 4.9** | 238.7 ± 10.8** | 246.8 ± 14.8** | 304.8 ± 15.7**
| 300 ppm | 173.4 ± 6.6** | 241.4 ± 6.8**†† | 263.5 ± 13.0**†† | 270.8 ± 11.3**††
Sorbitol Dehydrogenase (IU/L) | 0 ppm | 9.4 ± 0.8** | 15.3 ± 1.3** | 12.7 ± 1.2* | 16.8 ± 0.9**
| 300 ppm | 9.8 ± 0.6** | 13.6 ± 1.3*† | 18.3 ± 3.5*† | 17.1 ± 1.9**††
Bile Salt/Acids (μmol/L) | 0 ppm | 28.4 ± 4.9 | 29.6 ± 4.2 | 48.2 ± 10.5 | 32.6 ± 4.3
| 300 ppm | 28.0 ± 2.0* | 44.4 ± 6.3*† | 41.8 ± 3.6*† | 40.6 ± 4.5*

Statistical significance for a treatment group indicates a significant pairwise test compared to the respective control group (0/0 or 300/0 ppm). Statistical significance for the 0/0 or 300/0 ppm control group indicates a significant trend test.

* Statistically significant at p ≤ 0.05; **p ≤ 0.01.

† Statistically significant at p ≤ 0.05 for pairwise comparisons of 0/0 to 300/20, 0/0 to 300/40, and 0/0 to 300/80 using a Wilcoxon rank-sum test with a Hommel p value adjustment; ††p ≤ 0.01.

^#^ Statistically significant at p ≤ 0.05 for pairwise comparisons of 0/0 to 300/0, 0/20 to 300/20, 0/40 to 300/40, and 0/80 to 300/80 using a Wilcoxon rank-sum test with a Hommel p value adjustment.

^a^ Data presented as mean ± SEM.

^b^ Statistical analysis performed by Jonckheere’s (trend) and Shirley’s or Dunn’s (pairwise) tests (unless otherwise noted).

^c^ Number of animals examined.

In all exposed groups except the 300/0 ppm group, the globulin concentrations were significantly decreased compared to the 0/0 ppm control group; the degree of decrease in the globulin concentration resulted in significant decreases in total protein concentration in these groups. Albumin concentrations were significantly increased in all male groups, except the 0/20 and 300/0 ppm groups. The combination of these protein changes resulted in significant increases in the albumin:globulin (A/G) ratios in all groups except the 300/0 ppm group.

ALT, ALP, and SDH activities were significantly increased in all exposed groups except the 300/0 ppm group, and bile acid concentrations were significantly increased in the 300/20 and 300/40 ppm groups, compared to the 0/0 ppm control group.

Liver: A spectrum of nonneoplastic hepatocellular lesions morphologically similar to those observed in the male and female 16-week interim evaluation of the first study also occurred in the male 16-week interim of the second study. The incidences of hepatocyte hypertrophy, hepatocyte cytoplasmic alteration, and hepatocyte single cell death were significantly increased in all exposed groups except 300/0 ppm, compared to the 0/0 ppm control group (Table 37). The incidences of hepatocyte necrosis in the 0/40 ppm group and pigment in the 0/40, 0/80, 300/40, and 300/80 ppm groups were significantly increased.

Table 37 Incidences of Nonneoplastic Liver Lesions in Male Rats at the 16-week Interim of the Two-year Feed Study of Perfluorooctanoic Acid (Study 2)

| Perinatal Exposure | | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 20 ppm | 40 ppm | 80 ppm
n | | 10^a^ | 10 | 10 | 10
Hepatocyte, Cytoplasmic Alteration^b^ | 0 ppm | 0** | 10** (1.0)^c^ | 10** (1.8) | 10** (2.0)
| 300 ppm | 0** | 9** (1.2) | 10** (1.7) | 10** (1.9)
Hepatocyte, Hypertrophy | 0 ppm | 0** | 10** (1.0) | 10** (1.0) | 10** (1.2)
| 300 ppm | 0** | 9** (1.1) | 10** (1.1) | 10** (1.2)
Hepatocyte, Single Cell Death | 0 ppm | 0** | 7** (1.0) | 9** (1.0) | 10** (1.0)
| 300 ppm | 0** | 5** (1.0) | 8** (1.0) | 10** (1.0)
Necrosis | 0 ppm | 1* (1.0) | 1 (1.0) | 6* (1.0) | 4 (1.5)
| 300 ppm | 0 | 2 (1.0) | 3 (1.0) | 1 (1.0)
Pigment | 0 ppm | 0** | 2 (1.0) | 8** (1.0) | 9** (1.0)
| 300 ppm | 0** | 3 (1.0) | 7** (1.0) | 10** (1.0)

Statistical significance for a treatment group indicates a significant pairwise test compared to the respective control group (0/0 or 300/0 ppm). Statistical significance for the 0/0 or 300/0 ppm control group indicates a significant trend test.

Pairwise comparisons across perinatal exposures (0/20 vs. 300/20, 0/40 vs. 300/40, and 0/80 vs. 300/80 ppm) did not show any statistically significant differences.

* Significantly different (p ≤ 0.05) from the 0/0 or 300/0 ppm control by the Poly-3 test; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

### Two-year Study in Males (Study 2)

Survival in treated groups was similar to that of the control groups (Table 38, Table 39; Figure 7). There were no treatment-related clinical observations in any of the exposed groups (Appendix E).

Table 38 Survival of Male Rats Following Postweaning-only Exposure in the Two-year Feed Study of Perfluorooctanoic Acid (Study 2)

| 0/0 ppm | 0/20 ppm | 0/40 ppm | 0/80 ppm
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 7 | 6 | 8 | 3
Natural Deaths | 7 | 2 | 7 | 10
Animals Surviving to Study Termination | 36 | 42 | 35^a^ | 37^a^
Percent Probability of Survival at End of Study^b^ | 72.0 | 84.0 | 70.0 | 74.0
Mean Survival (days)^c^ | 683.5 | 721.5 | 675.4 | 668.8
Survival Analysis^d^ | p = 0.733 | p = 0.160N | p = 0.856 | p = 0.882N

^a^ Includes one animal that died naturally during the last week of the study.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and study termination).

^d^ The result of the life table trend test (Tarone) is in the 0/0 ppm column, and the results of the life table pairwise comparisons (Cox) with the 0/0 ppm control group are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

Table 39 Survival of Male Rats Following Perinatal and Postweaning Exposure in the Two-year Feed Study of Perfluorooctanoic Acid (Study 2)

| 300/0 ppm | 300/20 ppm | 300/40 ppm | 300/80 ppm
Animals Initially in Study | 50 | 50 | 50 | 50
Moribund | 9 | 8 | 6 | 4
Natural Deaths | 6 | 4 | 6 | 7
Animals Surviving to Study Termination | 35^a^ | 38 | 38 | 39
Percent Probability of Survival at End of Study^b^ | 70.0 | 76.0 | 76.0 | 78.0
Mean Survival (days)^c^ | 692.2 | 700.8 | 707.1 | 699.9
Survival Analysis^d^ | p = 0.429N | p = 0.507N | p = 0.486N | p = 0.387N

^a^ Includes one animal that died naturally during the last week of the study.

^b^ Kaplan-Meier determinations.

^c^ Mean of all deaths (uncensored, censored, and study termination).

^d^ The result of the life table trend test (Tarone) is in the 0/0 ppm column, and the results of the life table pairwise comparisons (Cox) with the 0/0 ppm control group are in the exposed group columns. A lower mortality in an exposure group is indicated by N.

Figure 7

Kaplan-Meier Survival Curves for Male Rats Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 2)

At study termination, group mean body weights for the 0/20, 0/40, 0/80, 300/0, 300/20, and 300/40 ppm groups were within 10% of the 0/0 ppm or 300/0 ppm control group, respectively (Table 40, Table 41; Figure 8, Figure 9). The terminal mean body weight of the 300/80 ppm group was 13% less than that of the 0/0 ppm control group.

Table 40 Mean Body Weights and Survival of Male Rats Following Postweaning-only Exposure in the Two-year Feed Study of Perfluorooctanoic Acid (Study 2)

Day | 0/0 ppm | | 0/20 ppm | | | 0/40 ppm | | | 0/80 ppm
Day | Av. Wt. (g) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 51.9 | 25 | 53.6 | 103.3 | 25 | 54.4 | 104.7 | 25 | 53.7 | 103.5 | 25
8 | 81.6 | 25 | 82.6 | 101.2 | 25 | 84.4 | 103.4 | 25 | 82.7 | 101.3 | 25
15 | 124.5 | 25 | 123.6 | 99.2 | 25 | 126.7 | 101.7 | 25 | 124.6 | 100.1 | 25
22 | 170.3 | 25 | 169.9 | 99.8 | 25 | 173.1 | 101.7 | 25 | 170.4 | 100.1 | 25
29 | 217.1 | 25 | 215.0 | 99.0 | 25 | 214.7 | 98.9 | 25 | 210.2 | 96.8 | 25
36 | 262.1 | 25 | 255.4 | 97.4 | 25 | 249.6 | 95.2 | 25 | 242.9 | 92.7 | 25
43 | 296.4 | 25 | 284.2 | 95.9 | 25 | 273.7 | 92.3 | 25 | 266.5 | 89.9 | 25
50 | 321.2 | 25 | 302.1 | 94.1 | 25 | 289.1 | 90.0 | 25 | 283.6 | 88.3 | 25
57 | 341.3 | 25 | 316.8 | 92.8 | 25 | 307.7 | 90.2 | 25 | 293.3 | 85.9 | 25
64 | 356.8 | 25 | 329.7 | 92.4 | 25 | 321.3 | 90.0 | 25 | 307.9 | 86.3 | 25
71 | 374.3 | 25 | 342.7 | 91.5 | 25 | 332.0 | 88.7 | 25 | 318.8 | 85.2 | 25
78 | 385.8 | 25 | 354.7 | 91.9 | 25 | 342.1 | 88.7 | 25 | 329.3 | 85.4 | 25
85 | 395.6 | 25 | 360.0 | 91.0 | 25 | 343.5 | 86.8 | 25 | 337.8 | 85.4 | 25
120 | 431.7 | 25 | 395.5 | 91.6 | 25 | 377.8 | 87.5 | 25 | 365.1 | 84.6 | 25
141 | 447.3 | 25 | 408.2 | 91.3 | 25 | 391.0 | 87.4 | 25 | 376.9 | 84.3 | 25
169 | 463.7 | 25 | 424.5 | 91.6 | 25 | 402.6 | 86.8 | 25 | 384.0 | 82.8 | 25
197 | 484.5 | 25 | 436.2 | 90.0 | 25 | 414.7 | 85.6 | 25 | 400.7 | 82.7 | 25
225 | 498.7 | 25 | 455.8 | 91.4 | 25 | 430.8 | 86.4 | 25 | 408.7 | 81.9 | 25
253 | 508.7 | 25 | 464.6 | 91.3 | 25 | 440.0 | 86.5 | 25 | 419.3 | 82.4 | 25
281 | 519.7 | 25 | 479.3 | 92.2 | 25 | 448.4 | 86.3 | 25 | 430.4 | 82.8 | 25
309 | 528.1 | 25 | 490.1 | 92.8 | 25 | 463.0 | 87.7 | 25 | 437.9 | 82.9 | 25
337 | 536.8 | 25 | 499.5 | 93.1 | 25 | 472.0 | 87.9 | 25 | 443.2 | 82.6 | 25
365 | 549.0 | 25 | 510.4 | 93.0 | 25 | 481.8 | 87.8 | 25 | 454.8 | 82.8 | 25
393 | 553.4 | 25 | 515.3 | 93.1 | 25 | 487.0 | 88.0 | 25 | 452.9 | 81.8 | 25
421 | 555.0 | 25 | 517.0 | 93.2 | 25 | 490.2 | 88.3 | 25 | 459.9 | 82.9 | 25
449 | 562.5 | 25 | 527.7 | 93.8 | 25 | 507.4 | 90.2 | 25 | 475.0 | 84.4 | 25
477 | 572.0 | 25 | 542.9 | 94.9 | 25 | 517.7 | 90.5 | 25 | 486.1 | 85.0 | 25
505 | 581.4 | 25 | 550.4 | 94.7 | 25 | 525.6 | 90.4 | 25 | 493.1 | 84.8 | 25
533 | 586.5 | 25 | 555.6 | 94.7 | 25 | 528.6 | 90.1 | 25 | 501.4 | 85.5 | 25
561 | 591.3 | 25 | 564.3 | 95.4 | 25 | 535.7 | 90.6 | 25 | 507.9 | 85.9 | 25
589 | 591.7 | 25 | 570.1 | 96.3 | 25 | 544.8 | 92.1 | 25 | 515.0 | 87.0 | 25
617 | 597.6 | 25 | 577.3 | 96.6 | 25 | 550.0 | 92.0 | 25 | 519.4 | 86.9 | 25
645 | 598.5 | 24 | 577.5 | 96.5 | 25 | 545.6 | 91.2 | 25 | 527.6 | 88.2 | 25
673 | 594.9 | 23 | 583.0 | 98.0 | 25 | 561.8 | 94.4 | 25 | 532.7 | 89.5 | 25
701 | 605.6 | 23 | 582.7 | 96.2 | 24 | 565.7 | 93.4 | 24 | 535.5 | 88.4 | 24
729 | 604.4 | 22 | 587.0 | 97.1 | 24 | 571.1 | 94.5 | 23 | 541.6 | 89.6 | 23
EOS | 598.3 | 22 | 588.1 | 98.3 | 24 | 578.7 | 96.7 | 21 | 541.3 | 90.5 | 23

EOS = end of study.

Table 41 Mean Body Weights and Survival of Male Rats Following Perinatal and Postweaning Exposure in the Two-year Feed Study of Perfluorooctanoic Acid (Study 2)

Day | 300/0 ppm | | 300/20 ppm | | | 300/40 ppm | | | 300/80 ppm
Day | Av. Wt. (g) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters | Av. Wt. (g) | Wt. (% of Controls) | No. of Litters
1 | 50.7 | 25 | 51.5 | 101.5 | 25 | 50.0 | 98.7 | 25 | 49.8 | 98.1 | 26
8 | 80.0 | 25 | 80.7 | 100.8 | 25 | 78.6 | 98.2 | 25 | 76.9 | 96.1 | 26
15 | 121.9 | 25 | 124.2 | 101.9 | 25 | 121.5 | 99.6 | 25 | 118.2 | 97.0 | 26
22 | 168.8 | 25 | 172.2 | 102.0 | 25 | 169.4 | 100.4 | 25 | 165.4 | 98.0 | 26
29 | 214.2 | 25 | 218.2 | 101.9 | 25 | 211.3 | 98.7 | 25 | 206.7 | 96.5 | 26
36 | 258.1 | 25 | 259.3 | 100.5 | 25 | 249.2 | 96.5 | 25 | 242.5 | 94.0 | 26
43 | 293.1 | 25 | 287.3 | 98.0 | 25 | 277.4 | 94.6 | 25 | 264.9 | 90.4 | 26
50 | 318.1 | 25 | 304.6 | 95.7 | 25 | 295.5 | 92.9 | 25 | 284.5 | 89.4 | 26
57 | 340.2 | 25 | 320.6 | 94.2 | 25 | 308.4 | 90.7 | 25 | 297.9 | 87.6 | 26
64 | 356.3 | 25 | 335.1 | 94.1 | 25 | 320.4 | 89.9 | 25 | 309.8 | 87.0 | 26
71 | 370.8 | 25 | 348.7 | 94.0 | 25 | 330.0 | 89.0 | 25 | 320.5 | 86.4 | 26
78 | 382.0 | 25 | 357.4 | 93.6 | 25 | 342.1 | 89.6 | 25 | 331.3 | 86.7 | 26
85 | 389.6 | 25 | 366.3 | 94.0 | 25 | 351.7 | 90.3 | 25 | 337.5 | 86.6 | 26
120 | 428.9 | 25 | 399.3 | 93.1 | 25 | 383.4 | 89.4 | 25 | 364.7 | 85.0 | 26
141 | 438.5 | 25 | 405.9 | 92.6 | 25 | 390.6 | 89.1 | 25 | 370.1 | 84.4 | 26
169 | 456.8 | 25 | 429.1 | 93.9 | 25 | 410.4 | 89.9 | 25 | 385.9 | 84.5 | 26
197 | 478.1 | 25 | 442.4 | 92.5 | 25 | 424.9 | 88.9 | 25 | 397.1 | 83.1 | 26
225 | 492.1 | 25 | 462.5 | 94.0 | 25 | 442.5 | 89.9 | 25 | 409.8 | 83.3 | 26
253 | 504.5 | 25 | 474.5 | 94.1 | 25 | 450.6 | 89.3 | 25 | 420.9 | 83.4 | 26
281 | 518.9 | 25 | 487.9 | 94.0 | 25 | 463.8 | 89.4 | 25 | 428.1 | 82.5 | 26
309 | 527.9 | 25 | 501.4 | 95.0 | 25 | 477.8 | 90.5 | 25 | 435.8 | 82.6 | 26
337 | 536.5 | 25 | 507.2 | 94.5 | 25 | 484.1 | 90.2 | 25 | 445.4 | 83.0 | 26
365 | 540.6 | 25 | 523.4 | 96.8 | 25 | 498.7 | 92.3 | 25 | 454.7 | 84.1 | 26
393 | 545.1 | 25 | 524.7 | 96.3 | 25 | 502.0 | 92.1 | 25 | 454.0 | 83.3 | 26
421 | 548.2 | 25 | 528.1 | 96.3 | 25 | 506.6 | 92.4 | 25 | 458.6 | 83.7 | 26
449 | 558.7 | 25 | 539.7 | 96.6 | 25 | 525.6 | 94.1 | 25 | 470.1 | 84.1 | 26
477 | 567.7 | 25 | 555.2 | 97.8 | 25 | 531.4 | 93.6 | 25 | 480.0 | 84.6 | 26
505 | 575.4 | 25 | 563.6 | 97.9 | 25 | 541.7 | 94.1 | 25 | 484.1 | 84.1 | 26
533 | 576.2 | 25 | 565.1 | 98.1 | 25 | 550.5 | 95.5 | 25 | 493.2 | 85.6 | 26
561 | 577.2 | 25 | 576.9 | 99.9 | 25 | 560.0 | 97.0 | 25 | 501.2 | 86.8 | 26
589 | 584.0 | 25 | 582.2 | 99.7 | 25 | 558.6 | 95.7 | 25 | 510.6 | 87.4 | 26
617 | 588.5 | 25 | 578.0 | 98.2 | 25 | 570.3 | 96.9 | 25 | 517.2 | 87.9 | 25
645 | 586.5 | 25 | 589.6 | 100.5 | 25 | 572.7 | 97.7 | 25 | 519.2 | 88.5 | 24
673 | 580.6 | 25 | 599.7 | 103.3 | 25 | 572.7 | 98.6 | 25 | 524.8 | 90.4 | 24
701 | 583.6 | 25 | 596.4 | 102.2 | 24 | 575.3 | 98.6 | 24 | 523.2 | 89.7 | 24
729 | 575.6 | 25 | 593.4 | 103.1 | 24 | 575.3 | 99.9 | 24 | 527.6 | 91.7 | 23
EOS | 581.7 | 23 | 586.1 | 100.7 | 24 | 573.2 | 98.5 | 24 | 529.5 | 91.0 | 22

EOS = end of study.

Figure 8

Growth Curves for Male Rats with Postweaning-only Exposure to 0/0, 0/20, 0/40, or 0/80 ppm Perfluorooctanoic Acid in Feed for Two Years (Study 2)

Figure 9

Growth Curves for Male Rats with Perinatal and Postweaning Exposure to 300/0, 300/20, 300/40, or 300/80 ppm Perfluorooctanoic Acid in Feed for Two Years (Study 2)

Group mean feed consumption by exposed groups was within 10% of the 0/0 ppm control group throughout the study (Appendix E). After weaning, PFOA consumption for rats in the 0/20, 0/40, and 0/80 ppm groups and the 300/20, 300/40, and 300/80 ppm groups averaged 1.1, 2.2, and 4.6 mg/kg/day and 1.0, 2.1, and 4.6 mg/kg/day, respectively.

#### Pathology and Statistical Analyses

The morphologic features of the lesions discussed in this section are presented in the Histopathological Descriptions section following the Study 2 results.

Liver: Chronic exposure with and without perinatal exposure resulted in increases in the incidences of hepatocellular neoplasms (Table 42). Significant increases were observed in the incidences of hepatocellular adenoma (including multiple) in the 0/40 and 0/80 ppm groups compared to the 0/0 ppm control group, and in the 300/80 ppm group compared to the 300/0 ppm group (Table 42). The incidence of hepatocellular carcinoma was increased in the 300/80 ppm group; however, the increase was not statistically significant. Significant increases were observed in the incidences of hepatocellular adenoma or carcinoma (combined) in the 0/40, 0/80, and 300/80 ppm groups compared to their respective control group.

Table 42 Incidences of Select Neoplastic and Nonneoplastic Liver Lesions in Male Rats in the Two-year Feed Study of Perfluorooctanoic Acid (Study 2)

| Perinatal Exposure | | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 20 ppm | 40 ppm | 80 ppm
n | | 50^a^ | 50 | 50 | 50
Hepatocyte, Cytoplasmic Alteration^b^ | 0 ppm | 0** | 12** (1.5) | 34** (1.6) | 46** (1.8)
| 300 ppm | 0** | 4 (1.0) | 29** (1.4) | 41** (1.7)
Hepatocyte, Hypertrophy | 0 ppm | 0** | 13** (1.2) | 34** (1.2) | 43** (1.6)
| 300 ppm | 1** (4.0)^c^ | 4 (1.0) | 29** (1.4) | 42** (1.5)
Hepatocyte, Single Cell Death | 0 ppm | 1** (1.0) | 1 (1.0) | 11* (1.7) | 24** (1.3)
| 300 ppm | 1** (4.0) | 3 (2.7) | 5 (1.6) | 29** (1.3)
Necrosis | 0 ppm | 2** (1.5) | 17** (1.2) | 23** (1.4) | 20** (1.3)
| 300 ppm | 1** (1.0) | 11** (1.2) | 14** (1.1) | 21** (1.3)
Pigment | 0 ppm | 0** | 7* (1.4) | 15** (1.1) | 30** (2.0)
| 300 ppm | 0** | 4 (1.3) | 11** (1.4) | 26** (1.4)
Mixed-cell Focus | 0 ppm | 0* | 4 | 9** | 6*
| 300 ppm | 0** | 4 | 4 | 9*
Eosinophilic Focus | 0 ppm | 3 | 6 | 5 | 9
| 300 ppm | 2 | 5 | 1 | 7
Inflammation, Focal | 0 ppm | 15* (1.0) | 19 (1.0) | 18 (1.1) | 24* (1.0)
| 300 ppm | 13** (1.0) | 11 (1.0) | 19 (1.1) | 24* (1.0)
Degeneration, Cystic | 0 ppm | 2* (1.0) | 5 (1.2) | 7 (1.0) | 8 (1.1)
| 300 ppm | 0** | 3 (1.0) | 3 (1.0) | 11** (1.3)
Bile Duct, Hyperplasia | 0 ppm | 24** (1.1) | 3** (1.0) | 3** (1.0) | 1** (1.0)
| 300 ppm | 25** (1.2) | 8** (1.0) | 2** (1.0) | 5** (1.0)
Hepatocellular Adenoma, Multiple | 0 ppm | 0 | 0 | 3 | 3
| 300 ppm | 0 | 0 | 0 | 5
Hepatocellular Adenoma (includes Multiple)^d^
Overall Rate^e^ Litters Rate^f^ Rao-Scott Adjusted Poly-3 Test^g^ | 0 ppm | 0/50 (0%) 0/25 (0%) p < 0.001 | 0/50 (0%) 0/25 (0%) (e) | 7/50 (14%) 6/25 (24%) p = 0.050 | 11/50 (22%) 8/25 (32%) p = 0.010
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | 0/50 (0%) 0/25 (0%) p < 0.001 | 1/50 (2%) 1/25 (4%) p = 0.564 | 5/50 (10%) 5/25 (20%) p = 0.070 | 10/50 (20%) 9/26 (35%) p = 0.006
Hepatocellular Carcinoma^h^
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 0/50 0/25 _^i^ | 0/50 0/25 _ | 0/50 0/25 _ | 0/50 0/25 _
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test) | 300 ppm | 0/50 (0%) 0/25 (0%) p = 0.049 | 0/50 (0%) 0/25 (0%) (e) | 0/50 (0%) 0/25 (0%) (e) | 4/50 (8%) 3/26 (12%) p = 0.236
Hepatocellular Adenoma or Carcinoma (Combined)^j^
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 0/50 (0%) 0/25 (0%) p < 0.001 | 0/50 (0%) 0/25 (0%) (e) | 7/50 (14%) 6/25 (24%) p = 0.050 | 11/50 (22%) 8/25 (32%) p = 0.010
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | 0/50 (0%) 0/25 (0%) p < 0.001 | 1/50 (2%) 1/25 (4%) p = 0.579 | 5/50 (10%) 5/25 (20%) p = 0.077 | 12/50 (24%) 10/26 (38%) p = 0.003

Statistical significance for a treatment group indicates a significant pairwise test compared to the respective control group (0/0 or 300/0 ppm). Statistical significance for the 0/0 or 300/0 ppm control group indicates a significant trend test.

* Significantly different (p ≤ 0.05) from the 0/0 or 300/0 ppm control by the Rao-Scott test; **p ≤ 0.01.

(e) = value of statistic could not be computed.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 2/340 (0.67% ± 1.03%); range: 0% to 2%.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Number of litters with animals with neoplasm per number of litters necropsied.

^g^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the respective control and that exposed group. The Rao-Scott test adjusts the Poly-3 test for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^h^ Historical control incidence: 0/340.

^i^ Not applicable; no neoplasms in group.

^j^ Historical control incidence: 2/340 (0.67% ± 1.03%); range: 0% to 2%.

Chronic exposure with and without perinatal exposure resulted in increases in the incidences of a spectrum of nonneoplastic hepatocellular lesions that in general increased with increasing exposure concentration (Table 42; Appendix E). In general, the spectrum and the histological morphology of these lesions were similar to those that occurred in the female 2-year study.

The incidences of hepatocyte cytoplasmic alteration and hepatocyte hypertrophy were significantly increased in all groups of the chronic study, and in the 300/40 and 300/80 ppm groups of the perinatal and postweaning study. In general, the severity of these lesions tended to be minimum to moderate and were more severe in groups receiving the highest exposure concentrations. Hepatocyte hypertrophy and cytoplasmic alteration generally occurred in the same hepatocytes.

The incidences of hepatocyte single cell death were significantly increased in the 0/40 and 0/80 ppm groups compared to the 0/0 ppm control group and in the 300/80 ppm group compared to the 300/0 ppm group (Table 42). The incidences of hepatocyte necrosis were significantly increased in all postweaning exposed groups compared to their respective controls (Table 42). The incidences of pigment were significantly increased in all exposure groups of the chronic study and in the 300/40 and 300/80 ppm groups of the perinatal and postweaning exposure study (Table 42).

Compared to the 0/0 ppm control group, the incidences of mixed-cell foci of cellular alteration were increased in the 0/40 and 0/80 ppm groups of the postweaning exposure study and in the 300/80 ppm group of the perinatal and postweaning exposure study (Table 42).

The incidences of focal inflammation were significantly increased in the 0/80 and 300/80 ppm groups compared to their respective controls (Table 42).

The incidences of cystic degeneration were significantly increased in the 300/80 ppm group of the perinatal and postweaning exposure study compared to the 300/0 ppm control (Table 42). The incidences of bile duct hyperplasia were significantly less than those of the 0/0 or 300/0 ppm control group in all postweaning exposed groups (20, 40, and 80 ppm) (Table 42).

Pancreas: Chronic exposure with and without perinatal exposure resulted in increased incidences of pancreatic acinar cell neoplasms (Table 43). The incidences of acinar cell adenoma including multiple adenomas were significantly increased in all exposed groups. The incidences of acinar cell adenocarcinomas were increased in all groups; however, the increases were not statistically significant. The incidences of acinar cell adenoma or adenocarcinoma (combined) in all exposed groups of the postweaning studies with and without perinatal exposure were significantly greater than those of the respective control groups. No differences between groups with perinatal and without perinatal exposures were observed.

Table 43 Incidences of Select Neoplastic and Nonneoplastic Pancreas Lesions in Male Rats in the Two-year Feed Study of Perfluorooctanoic Acid (Study 2)

| Perinatal Exposure | | Postweaning Exposure
| Perinatal Exposure | 0 ppm | 20 ppm | 40 ppm | 80 ppm
n | | 50^a^ | 50 | 50 | 50
Acinus, Hyperplasia^b^ | 0 ppm | 18** (2.7) | 32* (3.7) | 37** (3.2) | 31** (3.2)
| 300 ppm | 23* (2.7) | 27 (3.2) | 38** (3.3) | 33 (3.4)
Acinar Cell Adenoma, Multiple | 0 ppm | 2 | 20 | 22 | 26
| 300 ppm | 4 | 18 | 22 | 27
Acinar Cell Adenoma (includes multiple)^d^
Overall Rate^e^ Litters Rate^f^ Rao-Scott Adjusted Poly-3 Test^g^ | 0 ppm | 3/50 (6%) 3/25 (12%) p < 0.001 | 28/50 (56%) 21/25 (84%) p < 0.001 | 26/50 (52%) 20/25 (80%) p < 0.001 | 32/50 (64%) 22/25 (88%) p < 0.001
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | 7/50 (14%) 6/25 (24%) p < 0.001 | 18/50 (36%) 12/25 (48%) p = 0.016 | 30/50 (60%) 21/25 (84%) p < 0.001 | 30/50 (60%) 21/26 (81%) p < 0.001
Acinar Cell Adenocarcinoma (includes multiple)^h^
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 0/50 (0%) 0/25 (0%) p = 0.179 | 3/50 (6%) 3/25 (12%) p = 0.188 | 1/50 (2%) 1/25 (4%) p = 0.527 | 3/50 (6%) 3/25 (12%) p = 0.154
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | 0/50 (0%) 0/25 (0%) p = 0.144 | 2/50 (4%) 2/25 (8%) p = 0.299 | 1/50 (2%) 1/25 (4%) p = 0.559 | 3/50 (6%) 3/26 (12%) p = 0.172
Acinar Cell Adenoma or Adenocarcinoma (Combined)^i^
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 0 ppm | 3/50 (6%) 3/25 (12%) p < 0.001 | 29/50 (58%) 21/25 (84%) p < 0.001 | 26/50 (52%) 20/25 (80%) p < 0.001 | 32/50 (64%) 22/25 (88%) p < 0.001
Overall Rate Litters Rate Rao-Scott Adjusted Poly-3 Test | 300 ppm | 7/50 (14%) 6/25 (24%) p < 0.001 | 20/50 (40%) 13/25 (52%) p = 0.006 | 30/50 (60%) 21/25 (84%) p < 0.001 | 30/50 (60%) 21/26 (81%) p < 0.001

Statistical significance for a treatment group indicates a significant pairwise test compared to the respective control group (0/0 or 300/0 ppm). Statistical significance for the 0/0 or 300/0 ppm control group indicates a significant trend test.

* Significantly different (p ≤ 0.05) from the 0/0 or 300/0 ppm control by the Rao-Scott test; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

^d^ Historical control incidence for all routes of 2-year studies (mean ± standard deviation): 45/340 (12.33% ± 10.07%); range: 0% to 28%.

^e^ Number of animals with neoplasm per number of animals necropsied.

^f^ Number of litters with animals with neoplasm per number of litters necropsied.

^g^ Beneath the control incidence is the p value associated with the trend test. Beneath the exposed group incidence are the p values corresponding to pairwise comparisons between the respective control and that exposed group. The Rao-Scott test adjusts the Poly-3 test (which accounts for differential mortality in animals that do not reach terminal euthanasia) for within-litter correlation. A negative trend or a lower incidence in an exposure group is indicated by N.

^h^ Historical control incidence: 2/340 (0.52% ± 0.85%); range: 0% to 2%.

^i^ Historical control incidence: 45/340 (12.33% ± 10.07%); range: 0% to 28%.

The incidences of acinus hyperplasia were also significantly increased in all postweaning-only exposure groups of the chronic study (Table 43), and in the 300/40 and 300/80 ppm groups of the perinatal and postweaning study, and this lesion is considered a potentially preneoplastic lesion. No differences between groups with perinatal and without perinatal exposures were observed.

## Histopathological Descriptions

In general, the histopathological changes—when present in the liver, pancreas, uterus, kidney, stomach, forestomach, and thyroid gland—were morphologically similar across males and females in the first and second studies.

### Liver

Hepatocellular adenomas were generally discrete, irregularly nodular masses that, at their margins, completely or partially compressed the surrounding normal hepatic parenchyma (Figure 10A). Adenomas were characterized by irregular cords of large, amphophilic to basophilic hepatocytes positioned tangentially to the surrounding normal hepatic parenchyma (Figure 10B). Portal areas were generally not present within adenomas.

Figure 10

Hepatocellular Adenoma in a Male Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 2)

A) The adenoma occurs as a discrete, irregularly nodular mass within the hepatic parenchyma (arrows). B) Higher magnification of panel A. The adenoma is characterized by irregular cords of amphophilic to basophilic hepatocytes positioned tangentially to the surrounding normal hepatic parenchyma. Note the partial compression of the adjacent hepatocytes at the margins (arrows).

Hepatocellular carcinomas were large, irregularly nodular, invasive masses that in some cases lacked distinct borders (Figure 11A). The neoplastic hepatocytes were pleomorphic and generally arranged in irregular clusters and islands. However, in focal areas they formed irregular trabeculae or cords that varied from two to six cells thick; in these areas, the hepatic sinusoids were dilated (Figure 11B). Such patterns are hallmarks of hepatocellular carcinomas.

Figure 11

Hepatocellular Carcinoma in a Female Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 1)

A) The carcinoma occurs as a large, irregularly discrete, pleomorphic, invasive mass that has effaced the hepatic parenchyma (arrows). B) Higher magnification of panel A. The neoplastic hepatocytes are pleomorphic and arranged in irregular clusters and islands with focal areas where they formed irregular trabeculae or cords that varied from two to six cells thick (arrows).

In the male 2-year study, some adenomas (Figure 12) and carcinomas (Figure 13) were largely composed of neoplastic hepatocytes that contained prominent cytoplasmic microvesicular and macrovesicular cytoplasmic vacuoles.

Figure 12

Hepatocellular Adenoma in a Male Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 2)

A) The adenoma occurs as a discrete, irregularly nodular, vacuolated mass within the hepatic parenchyma. B) Higher magnification of panel A. The adenoma is composed of neoplastic hepatocytes that contain prominent cytoplasmic microvesicular and macrovesicular cytoplasmic vacuoles.

Figure 13

Hepatocellular Carcinoma in a Male Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 2)

A) The carcinoma occurs as a large, irregularly nodular, pleomorphic, invasive mass that has effaced the hepatic parenchyma (arrows). B) Higher magnification of panel A. Similar to the adenoma in Figure 12, the carcinoma is composed largely of neoplastic hepatocytes that contain prominent cytoplasmic microvesicular and macrovesicular cytoplasmic vacuoles.

Mixed-cell foci were focal proliferations of hepatocytes that tended to blend with the surrounding normal hepatic parenchyma at their margins (Figure 14A). They were composed of a mixture of eosinophilic to amphophilic hepatocytes mixed with hepatocytes that contained prominent cytoplasmic microvesicular and macrovesicular cytoplasmic vacuoles similar to those that occurred in hepatocellular adenomas (Figure 14B). At times, the distinction between hepatocellular adenoma and mixed-cell focus was not clear-cut and could only be based on lack of compression of the surrounding hepatic parenchyma along the margins of mixed-cell foci. Mixed-cell foci are considered potentially preneoplastic.

Figure 14

Mixed-cell Focus of Hepatocytes from the Liver of a Male Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 2)

A) Mixed-cell focus (MF), characterized by a focal, proliferation of hepatocytes that blends with the surrounding normal hepatic parenchyma at the margins (asterisk). B) Higher magnification of panel A. The MF is composed of a mixture of eosinophilic to amphophilic hepatocytes and hepatocytes that contain prominent microvesicular and macrovesicular cytoplasmic vacuoles similar to the cells that were present in hepatocellular adenomas. Also note how the hepatocytes in the foci blend with the normal hepatocytes (arrows).

Hepatocyte cytoplasmic alteration and hepatocyte hypertrophy were generally colocalized within hepatocytes and were generally of mild to moderate severity. These hepatocyte changes were observed throughout the liver sections but were often most prominent in centrilobular hepatocytes (Figure 15A). Hepatocyte with cytoplasmic alteration appeared granular and hypereosinophilic due to accumulations of eosinophilic granules in the cytoplasm (Figure 15B). Hepatocellular hypertrophy was characterized by hepatocyte enlargement due to either accumulation of eosinophilic granules (when associated with cytoplasmic alteration) or homogenous eosinophilic cytoplasm, in the absence of cytoplasmic alteration.

Figure 15

Hepatocyte Cytoplasmic Alteration and Hypertrophy in a Male Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 2)

A) Affected hepatocytes are enlarged and brightly eosinophilic (arrows). B) Higher magnification of panel A. Note enlarged hepatocytes that have brightly eosinophilic granules (arrows).

Hepatocyte single cell death consisted of randomly distributed, individual, irregularly round hepatocytes that were shrunken and had hypereosinophilic cytoplasm, and pyknotic nuclei with condensed, tortuous chromatin (Figure 16). Some cells were surrounded by a clear space or halo.

Figure 16

Hepatocyte Single Cell Death in a Female Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 1)

A) Affected hepatocytes are randomly distributed, individual, hypereosinophilic hepatocytes (arrows). B) Higher magnification of panel A. Affected hepatocytes are shrunken and have hypereosinophilic cytoplasm and pyknotic nuclei with condensed chromatin (arrows).

Necrosis occurred as variably distributed, (focal, multifocal, diffuse), variably sized, irregular zones of coagulative necrosis in the parenchyma that were often prominent in the centribobular zones (Figure 17). In areas of necrosis, necrotic hepatocytes were swollen, pale, and had lost all cellular detail. Bridging between adjacent centrilobular zones of necrosis was sometimes evident.

Figure 17

Hepatocyte Necrosis in a Female Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 1)

Necrosis consisted of prominent, variably sized, irregular zones of coagulative necrosis (asterisks) that are sharply demarcated from the surrounding unaffected hepatic parenchyma. Compared with the surrounding hepatic parenchyma, in affected areas, the necrotic hepatocytes are swollen, lightly eosinophilic and lack cellular detail.

Hepatocyte pigment was characterized by the presence of fine golden-brown material in both hepatocytes and Kupffer cells (Figure 18). The pigment was considered likely to be lipofuscin due to the lack of staining with the histochemical stains for iron (Perl’s Prussian blue stain) or for bilirubin (Hall’s bilirubin stain).

Figure 18

Hepatocyte Pigment in a Female Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 1)

Hepatocyte pigment is characterized by the presence of fine golden-brown material in both hepatocytes and Kupffer cells (arrows).

Bile duct hyperplasia was multifocal in distribution and consisted of increased numbers of bile duct profiles within the portal areas (Figure 19). The hyperplastic ducts were sometimes surrounded by dense collagen.

Figure 19

Bile Duct Hyperplasia in a Female Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 1)

Bile duct hyperplasia is characterized by increased numbers of bile duct profiles within a portal area (arrows).

Hepatocyte mitoses consisted of increased numbers of hepatocytes in which the nuclei were undergoing mitoses (Figure 20).

Figure 20

Hepatocyte Mitoses in a Female Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 1)

Hepatocyte mitoses are characterized by increased numbers of hepatocytes in which the nuclei were undergoing mitosis (arrows).

### Pancreas

Acinar cell hyperplasias often coexisted in tissue sections with adenomas but were also present in tissue sections that did not have adenomas (Figure 21A). Hyperplasia was morphologically similar to adenomas, which suggested a continuum from hyperplasia to adenoma. The distinction between acinar cell hyperplasia and adenoma was based largely upon size, with acinar cell hyperplasia diagnosed when they were less than 3 mm in the widest diameter.^121^ Acinar cell hyperplasia was characterized by nodular proliferations of rounded clusters of normal-appearing pancreatic acinar cells, and relative normal-appearing acinar architecture (Figure 21B).

Figure 21

Acinar Cell Hyperplasia and Adenoma of the Pancreas in a Male Sprague Dawley Rat Exposed to Perfluorooctanoic Acid for Two Years (Study 2)

A) Acinus hyperplasia (H) and acinus adenoma (A) were nodular lesions that often occurred in the same histological section and were distinguishable only by size. B) Higher magnification of the hyperplasia in panel A. Acinar hyperplasia was characterized by proliferation of normal-appearing pancreatic acinar cells with retention of the normal-appearing acinar architecture. C) Higher magnification of the adenoma in panel A. Acinar cell adenomas were morphologically similar to that of acinar hyperplasia but sometimes compressed the adjacent pancreatic parenchyma.

Acinar cell adenomas occurred as single or multiple discrete, irregularly nodular masses that were more than 3 mm in diameter, and sometimes compressed the adjacent pancreatic parenchyma (Figure 21A). Neoplasm cells were well differentiated and formed small, irregular acini (Figure 21).

Acinar cell adenocarcinomas occurred as invasive, irregular multinodular masses separated by bands of fibrous or connective tissue (scirrhous response) (Figure 22A). The growth patterns within adenocarcinomas were pleomorphic with well to poorly differentiated neoplastic acinar cells that formed sheets, small acini, gland-like structures, and trabeculae (Figure 22B). Islets of Langerhans were absent within the acinar cell neoplasms.

Figure 22

Adenocarcinoma of the Pancreas in a Male Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 2)

A) The pancreas adenocarcinoma occurs as a multinodular masse that has replaced most of the pancreatic parenchyma (arrows). B) Higher magnification of panel A. The pancreas adenocarcinoma is composed of relatively well differentiated acinar cells with retention of the normal-appearing acinar architecture.

### Uterus

Uterine adenocarcinomas were poorly circumscribed, invasive masses that varied in size from small focal lesions to some larger lesions that effaced the entire endometrium and extended into or sometimes through the myometrium (Figure 23A). The neoplastic epithelial cells had multiple morphologies that included solid nests, cords, and papillary or acinar structures (Figure 23B). Typically, the neoplastic epithelial cells had at least some degree of pleomorphism or atypia and mitotic figures were common.

Figure 23

Adenocarcinoma of the Uterus in a Female Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 1)

A) The uterus adenocarcinoma occurs as a highly invasive mass that has completely effaced the architecture of the uterus. B) Higher magnification of panel A.

### Kidney

Kidney papillary urothelial hyperplasia was characterized by minimal to moderate proliferative thickening of the urothelium lining the renal papilla (Figure 24A), which formed variably sized, irregular, papillary protuberances that extended into the lumen of the renal pelvis (Figure 24B). In some cases, the proliferative urothelium extended into the interstitium of the renal papilla itself, forming variably sized, irregular gland-like structures (Figure 24C).

Figure 24

Papilla Urothelial Hyperplasia in the Kidney of a Female Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 1)

A) Papilla urothelial hyperplasia of the kidney is characterized by hyperplasia of the epithelium of the renal papilla in the form of papillary projections into the lumen of the renal pelvis (arrows), or within the interstitium (arrows) of the renal papilla (P). B) Higher magnification of panel A. The hyperplastic epithelium forms papillary projections that protrude into the lumen of the renal pelvis (arrows). C) Higher magnification of panel A. The hyperplastic epithelium forms irregular anastomosing tubule-like structures within the interstitium of the renal papilla (arrows).

Kidney papillary necrosis was characterized by coagulative necrosis of the distal one-third to one-half of the papilla with complete loss of architecture (Figure 25).

Figure 25

Papillary Necrosis in the Kidney of a Female Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 1)

A) Papillary necrosis of the kidney is characterized by necrosis of the distal one-half of the renal papilla (asterisk). B) Higher magnification of the necrotic area in panel A (asterisk) demonstrating coagulative necrosis with complete loss of the architecture of renal papilla.

Tubular mineral was of minimal severity and characterized by the presence of randomly distributed basophilic mineral deposits in the epithelial cells lining the cortical and medullary tubules.

### Forestomach

Forestomach ulceration, epithelial hyperplasia, and inflammation were associated lesions (Figure 26). Ulcers were focal lesions characterized by full-thickness loss of the lining mucosal squamous epithelium and accompanied by variable thickening (up to 6 to 10 cell layers) of the adjacent squamous epithelium (hyperplasia) that extended from the margins, and the presence of a mixed inflammatory cell infiltrates (inflammation, chronic active) within the underlying submucosa, that sometimes extended into the muscularis mucosa below (Figure 26).

Figure 26

Forestomach Ulcer in the Stomach of a Female Sprague Dawley Rat Exposed to Perfluorooctanoic Acid in Feed for Two Years (Study 1)

Forestomach ulcer (asterisk) accompanied by epithelial hyperplasia (arrows) and submucosal inflammation.

### Thyroid Gland

Follicular cell hypertrophy was of minimal to mild severity and diagnosed when the thyroid gland was composed predominantly of small follicles that had minimal amounts of lightly basophilic colloid. Affected follicles were lined by cuboidal rather than flattened epithelial cells. Such small follicles are typically present in the centers of normal thyroid glands and constituted less than 30% of the area of thyroid gland sections among control animals.