# Materials and Methods

## Procurement and Characterization of Perfluorooctanoic Acid

PFOA was obtained from Sigma-Aldrich (St Louis, MO) in a single lot (03427TH). Identity, purity, and stability analyses were conducted under the analytical chemistry laboratory and study laboratory at Battelle (Columbus, OH) (Appendix A). Reports on analyses performed in support of the PFOA studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

PFOA lot 03427TH is a white crystalline solid. The lot was identified using infrared (IR) spectroscopy, ^19^F and ^13^C nuclear magnetic resonance (NMR) spectroscopy, and gas chromatography (GC) with mass spectrometry (MS) detection. The IR and NMR spectra are in good agreement with the structure of PFOA. GC-MS detection confirmed that the primary peak was PFOA.

The purity of lot 03427TH was evaluated using GC with electron capture detection (ECD) and ion chromatography (IC) with conductivity detection. GC-ECD analysis yielded a purity of 98.3% and four impurities with areas greater than or equal to 0.1% of the total peak area. IC with conductivity detection yielded a purity of 98.8% with three impurities with areas greater than 0.1% of the total peak area. GC with electron capture detection (ECD) showed that the impurities are likely fluorinated compounds. GC-MS detection showed that two of the impurities representing approximately 1% of the total area were isomers of PFOA; additional impurities were determined to be perfluorooctenoic acid (0.51%) and a structurally dissimilar fluorinated compound (0.11%). The purity of PFOA evaluated using differential scanning calorimetry (DSC) was 98.96%. Karl Fischer titration performed at Pervalere Life Science, Inc. (Whitesboro, NY) yielded a water content of 0.24%. The overall purity of lot 03427TH was determined to be greater than 98%.

To ensure stability, the test chemical was stored in amber glass bottles at ambient temperature (approximately 25ºC). Periodic analyses of lot 03427TH of the test chemical were performed prior to and during the animal studies by the study laboratory using GC-ECD; no degradation of the test chemical was detected.

## Preparation and Analysis of Dose Formulations

Prior to conducting studies, the homogeneity of PFOA (30 and 300 ppm) in NIH-07 and NTP-2000 formulations was confirmed by the analytical chemistry laboratory using GC-FID. Homogeneity of PFOA in NIH-07 (150 and 300 ppm PFOA) and NTP-2000 (20, 80, 150, 300, and 1,000 ppm PFOA) formulations was also confirmed by the study laboratory using GC-ECD.

Stability studies were performed by the analytical chemistry laboratory at 30 ppm PFOA in NIH-07 and NTP-2000 formulations up to 42 days. On day 42, formulations of NIH-07 were 99% and 91% and formulations of NTP-2000 were 104% and 101% of day 0 when stored refrigerated (approximately 5ºC) or at room temperature (approximately 25ºC), respectively. Hence, formulations of NIH-07 were refrigerated (approximately 5ºC), whereas formulations of NTP-2000 were stored at room temperature (approximately 25ºC).Dosed feed formulations were prepared monthly (Table A-1) for both the 21-week and 2-year studies using two types of feed (NIH-07 and NTP-2000).

Analysis of preadministration and postadministration (animal room) dose formulations of PFOA was conducted every 1–3 months over the course of the study (Table A-3, Table A-4). All preadministration formulations in both the 21-week and 2-year studies were within 10% of the target concentration. All of the postadministration samples collected from feed buckets were within 10% of the target concentration. Of the few postadministration formulation samples collected from residual animal feed bowls, one sample from the 21-week study, and three samples from the 2-year study were lower than 10% of the target concentration (11.5–13.4% below target).

## Animal Source

Time-mated (F_0_) female Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats were obtained from Harlan, Inc. (Madison, WI, or Indianapolis, IN; now Envigo), for the 2-year studies.

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle (Columbus, OH) Animal Care and Use Committee and conducted in accordance with all relevant National Institutes of Health (NIH) and National Toxicology Program (NTP) animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-year Studies

### Exposure Concentration Selection Rationale

Initial design of these studies was based on previous NTP assessments of early developmental exposures influencing carcinogenic activity.^89-91^ This approach uses a matrix-type design that evaluates different gestation/lactation doses. PFOA exposure concentrations were selected based on previous chronic studies^72,74^ and reproductive studies^49^ in the literature, in addition to known sex differences in elimination rates.^22^ Exposure concentrations of 150 or 300 ppm during gestation and lactation (these combined developmental periods are referred to as perinatal exposure in this report) were not expected to negatively affect litter size or survival, but still result in significant internal exposure. Note that the rats were exposed during the period of sexual maturation, which occurs postweaning, in both exposure paradigms.

As noted above, two diets were used in this study: (1) NIH-07 was used during the perinatal phase of the study, and (2) NTP-2000 was used during the postweaning phase of the study. The NIH-07 diet is a higher protein diet that supports reproduction and lactation in rodents, whereas the NTP-2000 diet is a lower protein diet that decreases the incidence of chronic nephropathy in rats.

Due to the known differences in kinetics between male and female rats, females were exposed to higher exposure concentrations (300 or 1,000 ppm) than were males (150 or 300 ppm) in the postweaning period of the first study (Table 1). An interim necropsy at 16 weeks (19 weeks of age) was included to assess toxicity and internal exposure in both males and females. A second study was started that focused entirely on males due to observed toxicity at the 16-week interim, and postweaning exposure concentrations were lowered (Table 2). Only a single perinatal exposure concentration was used (300 ppm) to compare to the unexposed rats during that developmental period because this exposure was well tolerated and postweaning comparisons (e.g., 0/80 versus 300/80) were the main objective of the study.

Table 1 Exposures during Perinatal and Postweaning Periods in Rats in the First Two-year Feed Study of Perfluorooctanoic Acid (Study 1)

Perinatal Exposure | Postweaning Exposure
Feed (ppm) | 0 | 150 | 300 | 1,000
0 | M/F | M | M/F | F
150 | – | M | F | –
300 | – | – | M | F

M = male; F = female.

Table 2 Exposures during Perinatal and Postweaning Periods in Male Rats in the Second Two-year Feed Study of Perfluorooctanoic Acid (Study 2)

Perinatal Exposure | Postweaning Exposure
Feed (ppm) | 0 | 20 | 40 | 80
0 | M | M | M | M
300 | M | M | M | M

M = male.

### Male and Female Rats (Study 1)

F_0_ female rats were 12 weeks old upon receipt. Gestation day (GD) 1 was defined as the first day with evidence of mating; F_0_ females were received on GD 2 and held for 4 days. F_0_ females were randomly assigned to three exposure groups on GD 5; 103 to the 0 ppm group and 36 each to the 150 and 300 ppm groups. Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM (Xybion Medical Systems Corporation, Cedar Knolls, NJ). Exposure of F_0_ females to PFOA in feed began on GD 6.

F_0_ females were quarantined for 36 days after receipt. Ten nonmated females received in the same shipment as the time-mated dams were designated for disease monitoring and were used for gross necropsies 2 days after arrival; samples were collected for serological analyses, and the animals were terminated, necropsied, and examined for the presence of disease or parasites. The health of the F_1_ animals was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All results were negative.

F_0_ females were housed individually during gestation and with their respective litters during lactation. F_0_ females were weighed on GDs 5, 6, 9, 12, 15, 18, and 21 and on postnatal days (PNDs) 1 (with whole litter), 4, 7, 14, and 21. F_1_ pups were weighed on PNDs 4, 7, 14, and 21. The day of parturition was considered PND 0. F_0_ females that did not deliver were euthanized on GD 27 and the uteri were stained for implantations/resorptions. On PNDs 1 and 4, the numbers of litters and pups and sex ratios for each litter were recorded. On PND 4, litters were standardized to eight pups per litter (four males and four females where possible); litters with fewer than eight pups or two pups per sex were removed from the study. During gestation and lactation, feed consumption per cage was measured continuously over 3- or 4-day intervals.

On the day the last litter reached PND 18, litters were randomly selected and assigned to exposure groups for the 2-year study; F_1_ rats from these litters were then randomly selected for use in the 2-year study. On the day the last litter reached PND 21, dams were removed from the cages, and the pups were weaned (PND 21–23). All F_1_ exposure groups consisted of 60 male or 60 female rats with two pups/sex/litter assigned to postweaning exposure groups.

F_1_ pups were housed up to two per cage (males) or four per cage (females). Feed and water were available ad libitum. Feed consumption was measured weekly for 13 weeks and then for a week-long period at 4-week intervals, except that feed consumption was also recorded the week following the 16-week interim evaluation. Cages were changed twice weekly and rotated every 2 weeks. Further details of animal maintenance are given in Table 3. Information on feed composition and contaminants is provided in Appendix B.

Table 3 Experimental Design and Materials and Methods in the Two-year Feed Studies of Perfluorooctanoic Acid

Study 1 (Male and Female) | Study 2 (Male)
Study Laboratory
Battelle (Columbus, OH) | Same as Study 1
Strain and Species
Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats | Same as Study 1
Animal Source
Harlan, Inc. (Madison, WI), now Envigo | Harlan, Inc. (Indianapolis, IN), now Envigo
Time Held Before Studies
4 days (F_0_ females) | Same as Study 1
Average Age When Studies Began
12 to 13 weeks (F_0_ females) | 12 to 14 weeks (F_0_ females)
Date of First Exposure
September 19, 2008 (F_0_ females) October 27, 2008 (F_1_ males) October 28, 2008 (F_1_ females) | June 19, 2009 (F_0_ females) July 27, 2009 (F_1_ males)
Duration of Exposure
GD 6 to PND 21 (F_0_ females) 21 weeks (F_1_ males—study stopped) 107 weeks (F_1_ females) | GD 6 to PND 21 (F_0_ females) 107 weeks (F_1_ males)
Date of Last Exposure
October 27, 2008 (F_0_ females) March 18, 2009 (F_1_ males) November 12, 2010 (F_1_ females) | July 27, 2009 (F_0_ females) August 12, 2011 (F_1_ males)
Necropsy Dates
Interim evaluation: February 12 (F_1_ males) or 13 (F_1_ females), 2009 Core: November 10 through 12, 2010 (F_1_ females) | Interim evaluation: November 11, 2009 (F_1_ males) Core: August 8 through 12, 2011 (F_1_ males)
Average Age at Necropsy
Interim evaluation: 19 weeks (F_1_ males and females) Core: 24 weeks (F_1_ males—euthanized early) Core: 110 weeks (F_1_ females) | Interim evaluation: 19 weeks (F_1_ males) Core: 109 to 110 weeks (F_1_ males)
Size of Study Groups
F_0_ females: 103 (0 ppm group) or 36 (150 and 300 ppm groups) F_1_ rats: 60 males and 60 females | F_0_ females: 147 F_1_ males: 60
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights | Same as Study 1
Animals per Cage
F_0_ females: One (plus litter) F_1_ rats: Two (males) or four (females) | F_0_ females: One (plus litter) F_1_ males: Two
Method of Animal Identification
F_0_ females: Tail marking with permanent pen F_1_ rats: Tail tattoo | Same as Study 1
Diet
NIH-07 meal feed (perinatal phase) or irradiated NTP-2000 wafer diet (chronic phase) (Zeigler Brothers, Inc., Gardners, PA), available ad libitum, changed every 3 days | Same as Study 1
Water
Tap water (Columbus municipal supply) via automatic watering system (Edstrom Industries, Inc., Waterford, WI), available ad libitum | Same as Study 1
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed and sanitized at least once weekly (during gestation) or twice weekly; rotated every 2 weeks after weaning | Same as Study 1
Bedding
Irradiated Sani-Chips^®^ hardwood chips (P. J. Murphy Forest Products Corp., Montville, NJ), changed once weekly (during gestation) or twice weekly | Same as Study 1
Rack Filters
Spun bonded polyester (Snow Filtration Co., Cincinnati, OH), changed every 2 weeks | Same as Study 1
Racks
Stainless steel (Lab Products, Inc.), changed and rotated every 2 weeks | Same as Study 1
Animal Room Environment
Temperature: 72° ± 3° F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour | Same as Study 1
Exposure Concentrations
F_0_ females: 0, 150, or 300 ppm F_1_ males: 0/0, 0/150, 0/300, 150/150, or 300/300 ppm F_1_ females: 0/0, 0/300, 0/1,000, 150/300, or 300/1,000 ppm | F_0_ females: 0 or 300 ppm F_1_ males: 0/0, 0/20, 0/40, 0/80, 300/0, 300/20, 300/40, or 300/80 ppm
Type and Frequency of Observation
F_0_ females: Observed twice daily. Body weights were recorded on GDs 5, 6, 9, 12, 15, 18, and 21 and on PNDs 1 (with litters), 4, 7, 14, and 21. Feed consumption was measured from GD 6 to PND 21. F_1_ rats: Observed twice daily. Clinical observations were recorded at 4-week intervals beginning during study week 5 and again prior to termination. Body weights were recorded on PNDs 4, 7, 14, and 21; weekly for 13 weeks, then every 4 weeks. Feed consumption was recorded weekly for 13 weeks, then for 1 week every 4 weeks. Body weights and clinical observations were also recorded 2 weeks after the interim evaluation and feed consumption was also recorded 1 week after the interim evaluation. | Same as Study 1
Method of Euthanasia
Carbon dioxide | Same as Study 1
Necropsy
Necropsies were performed on all F_1_ rats. Organs weighed at the interim evaluation were right adrenal gland, heart, right kidney, liver, lung, pituitary gland, spleen, right testis, thymus, thyroid gland, and uterus. | Necropsies were performed on all F_1_ rats. Organs weighed at the interim evaluation were right adrenal gland, heart, right kidney, liver, lung, pituitary gland, spleen, right testis, thymus, and thyroid gland.
Clinical Pathology
At the 16-week interim, blood was collected from the retroorbital plexus of 10 interim male and female rats per exposure group for clinical chemistry analyses. Clinical chemistry: albumin, urea nitrogen, creatinine, creatine kinase, glucose, total protein, alanine aminotransferase, alkaline phosphatase, sorbitol dehydrogenase, cholesterol, triglycerides, and bile acids | At week 16, blood was collected from the retroorbital plexus of the interim male rats for clinical chemistry analyses. Clinical chemistry: Same as Study 1
Histopathology
Complete histopathology was performed on all F_1_ female rats and male rats at the 16-week interim and on all remaining F_1_ rats at the end of the study. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle (interim evaluation only) skin, spleen, stomach (forestomach and glandular), testis with epididymis (interim evaluation only), thymus, thyroid gland, trachea, urinary bladder, and uterus. An additional extended evaluation of the uterus was performed which included all remaining cervical, vaginal, and uterine tissue remnants. | At the interim evaluation, the liver was the only organ examined in all exposure groups. Complete histopathology was performed on all remaining F_1_ males at the end of the study. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, esophagus, eyes, Harderian gland, heart, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung, lymph nodes (mandibular and mesenteric), mammary gland, nose, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder. The liver was examined in the remaining exposure groups at the interim evaluation.
Internal Dose Assessment
At the interim evaluation, PFOA concentrations were determined in plasma from blood collected from the retroorbital plexus and in liver samples collected from 10 males and 10 females per exposure group. | Maternal plasma and fetal (pooled by litter) PFOA concentrations were measured at GD 18; maternal plasma and whole pup PFOA concentrations were measured at PND 4. PFOA plasma concentrations were also measured in 10 males per exposure group at the interim evaluation.
Liver Enzyme Concentrations
Two, 1 g liver samples were collected from five males and five females per exposure group at the interim evaluation for determination of acyl-CoA oxidase and aromatase activity. | Same as Study 1, except from 10 males per exposure group

### Male Rats (Study 2)

F_0_ female rats were 11 to 13 weeks old upon receipt. GD 1 was defined as the first day with evidence of mating; F_0_ females were received on GD 2 and held for 4 days. F_0_ females were randomly assigned to two exposure groups on GD 5 with 147 going to each of the 0 and 300 ppm groups. Randomization was stratified by body weight that produced similar group mean weights using PATH/TOX SYSTEM. Exposure of F_0_ females to PFOA in feed began on GD 6.

F_0_ female rats were quarantined for 37 days after receipt. Ten nonmated females received in the same shipment as the time-mated dams were designated for disease monitoring and were used for gross necropsies 2 days after arrival; samples were collected for serological analyses, and the animals were terminated, necropsied, and examined for the presence of disease or parasites. The health of the F_1_ animals was monitored during the study according to the protocols of the NTP Sentinel Animal Program (Appendix C). All results were negative.

F_0_ females were housed individually during gestation and with their respective litters during lactation. F_0_ females were weighed on GDs 5, 6, 9, 12, 15, 18, and 21 and on PND 1 (with whole litter), 4, 7, 14, and 21. F_1_ pups were weighed on PNDs 4, 7, 14, and 21. The day of parturition was considered PND 0. F_0_ females that did not deliver were euthanized on GD 27 and the uteri were stained for implantations/resorptions. On PNDs 1 and 4, the numbers of litters and pups and sex ratios for each litter were recorded. On PND 4, litters were standardized to eight pups per litter (four males and four females where possible); litters with fewer than eight pups or two pups per sex were removed from the study. During gestation and lactation, feed consumption per cage was measured continuously over 3- or 4-day intervals.

Select litters were removed on GD 18 and PND 4 to quantify PFOA plasma and tissue concentrations. On GD 18, blood was collected from the retroorbital sinus of randomly selected dams (n = 5 per exposure group). Blood samples were collected into tubes containing ethylene diamine tetraacetic acid (EDTA), centrifuged, and the plasma harvested. Each dam’s fetuses were collected, pooled by litter, and flash frozen in liquid nitrogen. On PND 4, dams with unacceptable litters from the 0 ppm (n = 5) and 300 ppm (n = 4) groups were selected for biological sampling. Plasma was collected in the same manner as for GD 18. Up to four pups were collected from each dam (two per sex when possible) and flash frozen in liquid nitrogen. All samples were stored frozen between −30°C and −15°C before shipment on dry ice to Battelle’s Chemistry Technical Center (CTC) for analysis.

On the day the last litter reached PND 18, litters were randomly selected and assigned to exposure groups for the 2-year study and then F_1_ males from these litters were randomly selected for use in the 2-year study. On the day the last litter reached PND 21, dams were removed from the cages, and the pups were weaned (PND 21–23). All F_1_ exposure groups consisted of 60 males.

F_1_ males were housed up to two per cage. Feed and water were available ad libitum. Feed consumption was measured weekly for 13 weeks and then for a week-long period at 4-week intervals, except that feed consumption was also recorded the week following the 16-week interim evaluation. Cages were changed and rotated every 2 weeks. Further details of animal maintenance are given in Table 3. Information on feed composition and contaminants is provided in Appendix B.

### Clinical Examinations and Pathology (Studies 1 and 2)

During the 2-year studies, all animals in both studies were observed twice daily. Individual body weights of F_1_ pups were recorded on day 1 (postweaning), weekly for the first 13 weeks, at 4-week intervals thereafter, and again prior to termination. Clinical observations were recorded at 4-week intervals beginning during study week 5 and again prior to termination. As an exception to the 4-week intervals, body weights and clinical observations were recorded 2 weeks after the week 16 interim evaluation and data were recorded again 3 weeks later, resulting in one 5-week and one 3-week interval.

Ten rats were selected from each exposure group for interim evaluation at 16 weeks. Body weights were collected, as were blood samples for clinical chemistry determinations and plasma PFOA concentrations. Rats were anesthetized with 70% CO_2_ and 30% O_2_, and blood was taken from the retroorbital plexus and placed into tubes containing EDTA for plasma or into serum separator tubes for clinical chemistry. Clinical chemistry parameters were analyzed using a Cobas c501 Chemistry Analyzer (Roche Diagnostics, Indianapolis, IN). The clinical chemistry parameters that were measured are listed in Table 3. Plasma, approximately 1 mL, was collected in the morning and stored frozen between −30°C and −15°C until transferred to Battelle’s CTC for PFOA concentration analysis. Two, 1 g sections of liver were collected from 5 males and 5 females (Study 1) and 10 males (Study 2) per exposure group. One sample was immediately homogenized, snap frozen in liquid nitrogen, stored between −80°C and −60°C, and analyzed for the determination of acyl-CoA oxidase activity. The second sample was flash frozen in liquid nitrogen, stored, and analyzed for determination of aromatase activity. Acyl-CoA oxidase activity was used as a marker of PPARα induction, as PFOA is expected to be an inducer. Liver homogenates were centrifuged, and the supernatant added to 96-well plates along with palmitoyl-CoA solution. Kinetic reactions were analyzed by measuring absorbance at 502 nm for 5 minutes. Liver aromatase activity was evaluated to provide insight into potential endocrine-related lesions such as Leydig cell hyperplasia and/or neoplasia. Microsomal suspensions were prepared from liver samples and were incubated with radiolabeled androst-4-ene-3,17-dione and β-NADPH solutions for 1 hour. Samples were centrifuged, the aqueous layer was mixed with scintillation cocktail, and radioactivity was counted using a liquid scintillation counter (Beckman Coulter, Brea, CA). Another section of liver, approximately 100 mg, was collected from 10 males and 10 females (Study 1) and 10 males (Study 2) and stored frozen between −30°C and −10°C until transferred to Battelle’s CTC for PFOA concentration analysis. The parameters measured are listed in Table 3.

For determination of internal dose, plasma and liver homogenate samples were analyzed using validated analytical methods that included protein precipitation and liquid chromatography (LC) tandem mass spectrometry (MS/MS) as described in Dzierlenga et al.^17^ The concentration in plasma was expressed as ng/mL and in tissues as ng/g. Fetal and pup homogenate (Study 2) were analyzed using methods similar to those for liver analysis.

Complete necropsies were performed on all F_1_ rats. At the 16-week interim evaluations, the right adrenal gland, heart, right kidney, liver, lung, pituitary gland, spleen, right testis, thymus, thyroid gland, and uterus (Study 1) were weighed. At necropsy, all organs and tissues were examined for grossly visible lesions, and all major tissues were fixed and preserved in 10% neutral buffered formalin (except eyes and testes, which were initially fixed in Davidson’s solution or modified Davidson’s solution, respectively), processed and trimmed, embedded in paraffin, sectioned at a thickness of 4 to 6 μm, and stained with hematoxylin and eosin (H&E) for microscopic examination. For all paired organs (e.g., adrenal gland, kidney, ovary), samples from each organ were examined. In the original evaluation of the uterus, a transverse section through each uterine horn, approximately 0.5 cm cranial to the cervix, was collected for histopathology evaluation. For the extended evaluation of the uterus, all remaining cervical, vaginal, and uterine tissue remnants stored in 10% neutral buffered formalin were trimmed longitudinally, embedded, sectioned, and stained with H&E. Tissues examined microscopically are listed in Table 3. Complete microscopic examinations were performed on all F_1_ females and interim males in Study 1 and on all F_1_ males at the end of Study 2. At the interim evaluation of Study 2, the liver was the only organ examined in all exposure groups.

Microscopic evaluations were completed by the study laboratory pathologist, and the pathology data were entered into the Toxicology Data Management System. The report, slides, paraffin blocks, residual wet tissues, and pathology data were sent to the NTP Archives for inventory, slide/block match, wet tissue audit, and storage. The slides, individual animal data records, and pathology tables were evaluated by a Quality Assessment (QA) pathologist at a pathology laboratory independent of the study laboratory. The individual animal records and tables were compared for accuracy, the slide and tissue counts were verified, and the histotechnique was evaluated. For the 2-year studies, a QA pathologist evaluated slides from all neoplasms and all potential target organs, which included kidney, liver, pancreas, pancreatic islets, stomach (forestomach and glandular), testes, thyroid gland, and uterus.

The QA report and the reviewed slides were submitted to the NTP Pathology Working Group (PWG) coordinator, who reviewed the selected tissues and addressed any inconsistencies in the diagnoses made by the laboratory and QA pathologists. Representative histopathology slides containing examples of lesions related to chemical administration, examples of disagreements in diagnoses between the laboratory and QA pathologists, or lesions of general interest were presented by the coordinator to the PWG for review. The PWG consisted of the QA pathologist and other pathologists experienced in rodent toxicologic pathology. When the PWG consensus diagnosis differed from that of the laboratory pathologist, the diagnosis was changed. Final diagnoses for reviewed lesions represent a consensus between the laboratory pathologist, reviewing pathologist(s), and the PWG. Details of these review procedures have been described, in part, by Maronpot and Boorman^92^ and Boorman et al.^93^ For subsequent analyses of the pathology data, the decision whether or not to evaluate the diagnosed lesions for each tissue type separately or combined was based generally on the guidelines of McConnell et al.^94^

## Statistical Methods

### Survival Analyses

The probability of survival was estimated by the product-limit procedure of Kaplan and Meier^95^ and is presented graphically. Animals surviving to the end of the observation period are treated as censored observations, as are animals dying from unnatural causes within the observation period. Animals dying from natural causes are included in analyses but are treated as uncensored observations. Dose-related trends and pairwise dose-related effects on survival are assessed using a Cox Proportional Hazards Model^96^ with a random litter effect. All reported p values for the survival analyses are two-sided.

### Calculation of Incidence

Incidences of neoplastic and nonneoplastic lesions are presented as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. For calculation of incidence rates, the denominator for most neoplasms and all nonneoplastic lesions is the number of animals where the site was examined microscopically. However, when macroscopic examination was required to detect neoplasms in certain tissues (e.g., mesentery, pleura, peripheral nerve, skeletal muscle, tongue, tooth, and Zymbal’s gland) before microscopic evaluation, the denominators consist of the number of animals that had a gross abnormality. When neoplasms had multiple potential sites of occurrence (e.g., leukemia or lymphoma), the denominators consist of the number of animals on which a necropsy was performed. These statistical analyses also give the survival-adjusted neoplasm rate for each group and each site-specific neoplasm. This survival-adjusted rate (based on the Poly-3 method described below), used in tables presented in this Technical Report, accounts for differential mortality by assigning a reduced risk of neoplasm, proportional to the third power of the fraction of time on study, only to site-specific, lesion-free animals that do not reach terminal euthanasia.

### Analysis of Neoplasm and Nonneoplastic Lesion Incidences

Statistical analyses of neoplasm and nonneoplastic lesion incidences considered two features of the data. Some animals did not survive the entire 2 years of the study, so survival differences between groups had to be taken into account. Also, up to two animals per sex were randomly selected from each litter to participate in the study. The statistical analysis of lesion incidences used the Poly-3 test to account for survival differences, with a Rao-Scott adjustment for litter effects, as described below.

The Poly-k test^97-99^ was used to assess neoplasm and nonneoplastic lesion prevalence. This test is a survival-adjusted quantal-response procedure that modifies the Cochran-Armitage linear trend test to take survival differences into account. More specifically, this method modifies the denominator in the quantal estimate of lesion incidence to approximate more closely the total number of animal years at risk. For analysis of a given site, each animal is assigned a risk weight. This value is one if the animal had a lesion at that site or if it survived until terminal euthanasia; if the animal died prior to terminal euthanasia and did not have a lesion at that site, its risk weight is the fraction of the entire study time that it survived, raised to the kth power.

This method yields a lesion prevalence rate that depends only on the choice of a shape parameter for a Weibull hazard function describing cumulative lesion incidence over time.^97^ Unless otherwise specified, a value of k = 3 was used in the analysis of site-specific lesions. This value was recommended by Bailer and Portier^97^ following an evaluation of neoplasm onset time distributions for a variety of site-specific neoplasms in control F344 rats and B6C3F_1_ mice.^100^ Bailer and Portier ^97^ showed that the Poly-3 test gave valid results if the true value of k was anywhere in the range from 1 to 5. A further advantage of the Poly-3 method is that it does not require lesion lethality assumptions. Variation introduced by the use of risk weights, which reflect differential mortality, was accommodated by adjusting the variance of the Poly-3 statistic as recommended by Bieler and Williams.^101^ Poly-3 tests used the continuity correction described by Nam.^102^

Littermates tend to be more like each other than like fetuses/pups in other litters. Failure to account for correlation within litters leads to underestimates of variance in statistical tests, resulting in higher probabilities of Type I errors (“false positives”). Because up to two pups per sex per litter were present in the core study, the Poly-3 test was modified to accommodate litter effects using the Rao-Scott approach.^103^ The Rao-Scott approach accounts for litter effects by estimating the ratio of the variance in the presence of litter effects to the variance in the absence of litter effects. This ratio is then used to adjust the sample size downward to yield the estimated variance in the presence of litter effects. The Rao-Scott approach was implemented in the Poly-3 test as recommended by Fung et al.,^104^ formula ₸_RS2_.

Tests of significance included pairwise comparisons of each dosed group with control groups and a test for an overall dose-related trend. Continuity-corrected Rao-Scott-adjusted Poly-3 tests were used in the analysis of lesion incidence and reported p values are one sided. The significance of lower incidences or decreasing trends in lesions is represented as 1–p with the letter N added (e.g., p = 0.99 is presented as p = 0.01N). For neoplasms and nonneoplastic lesions observed without litter structure (e.g., at the interim evaluation), Poly-3 tests that included the continuity correction, but without adjustment for potential litter effects, were used for trend and pairwise comparisons to the control group.

To evaluate incidence rates by litter, the proportions of litters affected by each lesion type were tested among groups. Cochran-Armitage trend tests and Fisher exact tests^105^ were used to test for trends and pairwise differences from the control group, respectively.

### Analysis of Continuous Variables

Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey,^106^ for small samples (n < 20), and Tukey’s outer fences method,^107^ for large samples (n ≥ 20), were examined by NTP personnel and implausible values were eliminated from the analysis. Organ and interim sacrifice body weight measurements, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^108^ and Williams.^109,110^ For sets of pairwise comparisons across perinatal exposure groups at fixed or increasing postweaning exposures, t-tests were used with a Hommel procedure^111^ to adjust for multiple comparisons.

Clinical chemistry, parent compound, liver enzyme data, litter sizes, pup survival, implantations, number of resorptions, and proportions of male pups per litter, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^112^ (as modified by Williams^113^) and Dunn.^114^ For all quantitative endpoints unaffected by litter structure, Jonckheere’s test^115^ was used to assess the significance of the dose-related trends and to determine, at the 0.01 level of significance, whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than would be a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). For sets of pairwise comparisons across perinatal exposure groups at fixed or increasing postweaning exposures, a Wilcoxon rank-sum test was used with a Hommel procedure^111^ to adjust for multiple comparisons.

Postweaning body weights were measured on two pups per sex per litter in the 2-year study; more than two pups per sex per litter were possible in preweaning body weight measurements. The analyses of pup body weights and body weights adjusted for litter size (described below) of these animals took litter effects into account using a mixed model, where litters were the random effects. To adjust for multiple comparisons in these models, a Dunnett-Hsu adjustment was used.^116^ Dam body weights during gestation, as well as dam body weights during lactation, were analyzed with the parametric multiple comparison procedures of Dunnett^108^ and Williams,^109,110^ depending on whether Jonckheere’s test indicated the use of a trend-sensitive test. P values for these analyses are two-sided.

### Analysis of Gestational and Fertility Indices

Dose-related trends in gestational and fertility indices were tested using Cochran-Armitage trend tests. Pairwise comparisons of each dosed group with the control group were conducted using the Fisher exact test. P values for these analyses are two-sided.

### Body Weight Adjustments

Preweaning pup body weights were adjusted for live litter size as follows: A linear model was fit to body weights as a function of dose and litter size. The estimated coefficient of litter size was then used to adjust each pup body weight based on the difference between its litter size and the mean litter size. Prestandardization PND 4 body weights were adjusted for PND 1 litter size, and body weights measured between PND 4 poststandardization and PND 21 were adjusted for PND 4 poststandardization litter size. Following adjustment, body weights were analyzed with a linear mixed model with a random litter effect.

### Testing Effects of Perinatal and Postweaning Exposures

Trend and pairwise testing were performed to assess effects of postweaning exposure at given concentrations of perinatal exposure, perinatal exposure effects at given concentrations of postweaning exposure, and combined effects of perinatal and postweaning exposures.

For the 16-week interim evaluation in males and females and the two-year study in females (Study 1), the following comparisons were performed:

- For the groups without perinatal exposure, trend and pairwise comparisons were made to the 0/0 ppm control group for postweaning exposures. For males, this involved the 0/0, 0/150, and 0/300 ppm groups. For females, this involved the 0/0, 0/300, and 0/1,000 ppm groups.
- Trend and pairwise comparisons were made to the 0/0 ppm control group at increasing concentrations of both the perinatal and postweaning exposures. For males, this involved the 0/0, 150/150, and 300/300 ppm groups. For females, this involved the 0/0, 150/300, and 300/1,000 ppm groups.
- For a given postweaning exposure, a series of pairwise comparisons were made between perinatal exposures. For males, this involved comparing the 0/150 to the 150/150 ppm group and the 0/300 to the 300/300 ppm group. For females, this involved comparing the 0/300 to the 150/300 ppm group and the 0/1,000 to the 300/1,000 ppm group.

For the 16-week interim evaluation in males and the two-year study in males (Study 2), the following comparisons were performed:

- For the groups without perinatal exposure, trend and pairwise comparisons were made to the 0/0 ppm control group for postweaning exposures. This involved the 0/0, 0/20, 0/40, and 0/80 ppm groups.
- For animals with a 300 ppm perinatal exposure, trend and pairwise comparisons were made to the 300/0 ppm group for postweaning exposures. This involved the 300/0, 300/20, 300/40, and 300/80 ppm groups.
- For a given postweaning exposure, a series of pairwise comparisons were made between perinatal exposures. This involved comparing the 0/0 to the 300/0 ppm group, 0/20 to the 300/20 ppm group, the 0/40 to the 300/40 ppm group, and the 0/80 to the 300/80 group.
- Pairwise comparisons were made of the 0/0 to the 300/20 ppm group, 0/0 to the 300/40 ppm group, and 0/0 to the 300/80 ppm group.

### Historical Control Data

The concurrent control group represents the most valid comparison to the treated groups and is the only control group analyzed statistically in NTP bioassays. However, historical control data are often helpful in interpreting potential treatment-related effects, particularly for uncommon or rare neoplasm types. For meaningful comparisons, the conditions for studies in the historical control database must be generally similar. Significant factors affecting the background incidences of neoplasms at a variety of sites are diet, sex, strain/stock, and route of exposure. The NTP historical control database contains all 2-year studies for each species, sex, and strain/stock with histopathology findings in control animals completed within the most recent 5-year period^117-119^ including the concurrent control for comparison across multiple technical reports. Due to the sectioning of residual tissues for the uterus, the historical control for this organ consists of three studies at this time: indole-3-carbinol, 2-hydroxy-4-methoxybenzophenone, and this study. In general, the historical control database for a given study includes studies using the same route of administration, and the overall incidence of neoplasms in control groups for all routes of administration are included for comparison, including the current study.

## Quality Assurance Methods

The 2-year studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^120^ In addition, as records from the 2-year studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Technical Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Technical Report.